# Appendix D Human Cancer Study Tables

This appendix contains background information related to the cancer assessment on ortho-toluidine in humans including (1) detailed data information on study design, methods, and findings for the cohort studies (Table D-1) and case-control studies (Table D-2), (2) detailed information on the quality assessment of the individual studies (Table D-3) and (3) background carcinogenicity information on co-exposures in the cohort studies (Table D-4).

## D.1 Methodologies and Study Characteristics of the Selected Epidemiological Studies and Identification of Cancer Endpoints

The data from the eight cohort studies and two nested case-control studies (as delineated in Table 3-1) were systematically extracted from relevant publications, as described in the study protocol, and are summarized in the tables below.

Table D-1 Cohort Studies of ortho-Toluidine Exposure: Study Characteristics and Overall Findings

| Study Characteristics and Overall Findings
Case and Pearson (1954) : U.K. Dyeworkers
Related Reference | Case et al. (1954)
Geographic Location | United Kingdom
Population Characteristics
Exposed cohort and ascertainment | [underlined: Eligibility criteria for exposed cohort:] Workers without contact with auramine, benzidine, or α- or β-naphthylamine and who worked at least 6 months between 1910 and 1952 (referred to as nominal roll) [underlined: Exposed cohort:] All male workers who had contact (manufacture or use) with magenta (N = 85) at 21 British chemical factories [underlined: Total cohort:] Male workers (4,622) at 21 firms who had contact with aniline, benzidine, α- or β- naphthylamine from 1910 to 1952 [underlined: Follow-up:] 1921–1952 Loss to follow-up: Not reported
Reference population | General population (men): 15,875 deaths due to urinary bladder cancer in Wales and England (1921–1952)
All-cause and all-cancer mortality | Not reported
Study Design and Analytical Methods/Control for Confounding | Historical cohort study on urinary bladder cancer mortality Expected number of cases based on mean rate of male deaths from bladder cancer in Wales and England (up to 1952). Comparative composite cohort analysis, which accounts for age Excluded workers with exposure to benzidine, α- naphthylamine, or β-naphthylamine
Exposure Data and Information Assessment
Exposure: levels and co-exposures | Magenta manufacturing: levels and types of magenta NR Possible (depending on process): ortho-nitrotoluene, formaldehyde, aniline: levels NR
Exposure assessment | Exposure inferred via manufacturing process of magenta
Assessment: other exposure | Not reported
Disease assessment | Firm, hospital and death certificates, and coroner’s records and confirmed by other sources [underlined: Missing data:] Authors note that cases from earlier time points might have been missed
Pira et al. (2010) : Italian Dyeworkers
Related Reference | Decarli et al. (1985); Piolatto et al. (1991); Rubino et al. (1982)
Geographic Location | Italy
Population Characteristics
Exposed cohort and ascertainment | [underlined: Eligibility criteria:] Worked at least 1 year from 1922–1972 and were alive in 1946 [underlined: Exposed cohort:] 47 male workers involved only in the manufacture of fuchsin or ortho-toluidine (last update) [underlined: Total cohort:] 906 male dyestuff workers exposed to aromatic amines from 1922 to 1972; 2003 update on 590 [underlined: Follow-up:] 1951–2003; censored at age 85 [underlined: Loss to follow-up:] total cohort: 112 (12.4%) lost to follow-up before 1989, <4% after 1989
Reference population | 1951–1980: national mortality rates 1981–2003: regional mortality rates
All-cause and all-cancer mortality | Total cohort only All causes SMR = 1.50 (1.36–1.66); 394 All cancers SMR = 2.11 (1.80–2.46); 163
Study Design and Analytical Methods/ Control for Confounding | Historical cohort mortality study SMR and CI calculated using Poisson distribution for observed deaths and adjusted for age (in 5-year age groups) and for 5-year calendar period Workers exposed to benzidine and/or α- or β-naphthylamine were excluded from cohort.
Exposure Data and Information Assessment
Exposure: levels and co-exposures | ortho-Toluidine: levels not reported ortho-Toluidine production section: potentially exposed to ortho-nitrotoluene, 4,4'-methylene bis(2-methylaniline): levels NR Fuchsin and safranine T production section: potentially exposed to 2,5-diaminotoluene, aniline, and aminoazotoluene as well as dye products: levels NR
Exposure assessment | Exposure for each person was assessed by linking individual records with knowledge of chemical processes
Assessment: other exposure | Personnel and factory records
Disease assessment | Death certificates from regional registration offices
Ott and Langner (1983) : U.S. Dyeworkers
Related Reference | None
Geographic Location | United States
Population Characteristics
Exposed cohort and ascertainment | [underlined: Eligibility criteria] Employed as of 1940 or hired subsequently, without high exposure to arsenicals, vinyl chloride, or asbestos [underlined: Exposed cohort]: Bromindigo and thioindigo subcohort; 117 male workers [underlined: Total cohort:] 342 male workers assigned to 3 aromatic amine-based dye production areas; 275 did not have exposure to arsenicals, vinyl chloride, or asbestos [underlined: Follow-up:] 1940–1975 [underlined: Loss to follow-up:] NR; 124 left company, but followed via Social Security
Reference population | U.S. mortality rates for whites
All-cause and all-cancer mortality | Bromindigo and thioindigo subcohort All causes SMR = [0.79 (0.56–1.09)]; 36 All cancers SMR = [1.5 (0.81–2.56)]; 12
Study Design and Analytical Methods/ Control for Confounding | Historical cohort mortality study SMR based on Poisson distribution assumptions Expected numbers: mortality rates for whites (5-yr interval) Person-years accumulated on a month-by-month basis from date of eligibility Excluded individuals with high exposure to arsenicals, vinyl chloride, or asbestos
Exposure Data and Information Assessment
Exposure: levels and co-exposures | ortho-Toluidine: Breathing zone and area measurements in the 1940’s Air <0.5 ppm Urine – undetected to 1.7 ppm Nitrobenzene, 4-chloro-ortho-toluidine, 4-chloro-acetyl-ortho-toluidine, 1, 2-dihydroacenaphthylene, 2-aminobenzoic acid, thioindigo dyes: levels NR Odor of nitrobenzene reported (threshold levels for odor is 5 ppb/volume)
Exposure assessment | Exposure assessed via work history; all jobs held in production areas of interest and dates of employment used to calculate person-years of employment in each area
Assessment: other exposure | Work history
Disease assessment | Vital status determined by record search performed by Social Security Administration Underlying causes of death were coded according to the Seventh or Eighth Revision of the International Classification of Diseases (lCD), and were grouped for statistical purposes by categories used in the Eighth Revision
Stasik (1988) : 4-COT Production Workers
Related Reference | Stasik et al. (1985)
Geographic Location | Germany
Population Characteristics
Exposed cohort and ascertainment | [underlined: Eligibility criteria:] Workers with higher exposure employed before 1970 [underlined: Exposed subcohort]: 116 higher exposed 4-chloro-ortho-toluidine production and processing workers [underlined: Total cohort:] 335 male 4-chloro-ortho-toluidine production and processing workers employed between 1929 and 1982 [underlined: Follow-up]: 1967–1985 [underlined: Loss to follow-up:] Not reported
Reference population | Incidence (sex and age-specific) using non-contiguous regional rates Earlier publication: mortality study: national and regional rates
All-cause and all-cancer mortality | Subcohort All-causes SMR = 1.12 (0.68–1.73); 19 All-cancers SMR = 1.45 (0.47-3.38); 5 (regional mortality rates)
Study Design and Analytical Methods/ Control for Confounding | Historical cohort study of bladder cancer incidence; post-hoc analysis initiated by findings of cluster of bladder cancer (2 cases) after completion of mortality study Earlier study: historical cohort mortality study SIR: expected rates were calculated by multiplying person years at risk by age-specific bladder cancer incidence (regional)
Exposure Data and Information Assessment
Exposure: levels and co-exposures | Duration of higher exposure to 4-chloro-ortho-toluidine (before 1970); 14.0 years (median); total exposure duration (before and after 1970); 25.5 years (median) 4-chloro-ortho-toluidine, N-acetyl-ortho-toluidine 6-chloro-ortho-toluidine Benzidine and β-naphthylamine were not used in the plant
Exposure assessment | Exposure classification based on employment status, i.e., production or processing worker Information on duration of employment of cases, latency, age at beginning of employment
Assessment: other exposure | Smoking status known for bladder cases
Disease assessment | Bladder cancer incidence cases: hospital and clinical records Histopathological diagnosis made (when possible) according to WHO classification Mortality: source not reported, ICD-9 codes Information on age at diagnosis of bladder cancer
Carreón et al. (2014) : U.S. Rubber Chemical Workers
Related Reference | Carreón et al. (2010); Hanley et al. (2012); Markowitz and Levin (2004); Prince et al. (2000); Ward et al. (1991); Ward et al. (1996)
Geographic Location | United States
Population Characteristics
Exposed cohort and ascertainment | [underlined: Eligibility criteria:] Employed for 1 day or more at the plant between 1946 and 2006 [underlined: Exposed cohort:] Groups of workers definitely, probably, or probably not exposed to o-toluidine, classification varies by publication [underlined: Total cohort:] 1,875 (majority male) chemical plant workers [underlined: Follow-up:] Incidence: 1976–2007 [underlined: Mortality:] 1946–1988 (Carreón et al. 2010) [underlined: Loss to follow-up:] 33 workers died and 30 were otherwise lost to follow-up prior to earliest start of cancer registry (1976)
Reference population | [underlined: Incidence rates]: New York State excluding NYC (local), Pennsylvania, California, Ohio, Texas, Florida State cancer registries [underlined: Mortality]: United States mortality (national) [underlined: Internal:] Lowest exposure group
All cause and all-cancer mortality | Definitely exposed workers All-causes SMR = 0.96 (0.7–1.2); 65 All-cancers SMR = 1.1 (0.66–1.8); 17
Study Design, Analytical Methods/Control for Confounding | Historical cohort study on bladder cancer: incidence and mortality Life table methods: SIR and SRR, stratified by age and calendar year, for probability of exposure, exposure duration, cumulative rank, and time since first exposure categories. SMR (2010) – probability of exposure Cox proportional hazards regression for cumulative rank (continuous, categorical) adjusted for sex, race, age at diagnosis and birth year Smoking: indirect methods to adjust and Monte Carlo sensitivity analysis using data on subset of smokers
Exposure Data and Information Assessment
Exposure: levels and co-exposures | TWA Breathing zone concentrations: Rubber Chemical dept 1976–2004 (Hanley et al. 2012) [underlined: Range, ppm (GM range, ppm]) o-Toluidine: ND–1.8 (0.003–0.10) Aniline: 0.026–1.7 (0.0009–0.081) Nitrobenzene: ND–0.16 (0.004–0.038) 4-aminobiphenyl (4-ABP): trace amounts detected in bulk samples Biomonitoring data Ward et al. (1991; 1996) [underlined: Unexposed] [underlined: Exposed] Urine (μg/L)) o-Toluidine: 2.8 98.7^d^ Aniline: 3.9 29.8^d^ Adducts (pg/g Hb) o-Toluidine: 3,515 40,830^d^ Aniline: 3,163 17,441^d^ 4-ABP: 74.5 81.7
Exposure assessment | Workers classified into exposure probability categories and relative exposure ranks based on dept.-job-year combinations. Each dept.-job category was assigned a relative exposure rank for various calendar years. Cumulative rank = (time in each dept. job X exposure rank) summed over all jobs worked Occupational hygiene data used to develop exposure assessment. Missing data: none (records available for all workers 1946–2006)
Assessment: other exposure | Smoking histories collected on 18% non-random sample of current and former employees.
Disease assessment | Cases: 6 state cancer registries; company and union medical records Deaths: death certificates in company records or Social Security Administration
Sorahan (2008) : U.K. Rubber Chemical Workers
Related Reference | Sorahan and Pope (1993); Sorahan et al. (2000)
Geographic Location | Wales (UK)
Population Characteristics
Exposed cohort and ascertainment | [underlined: Eligibility criteria]: At least 6 months’ employment between 1955 to 1984 [underlined: Exposed cohort]: 53 male workers with potential exposure to o-toluidine who worked in the “Sopanox” department of a rubber chemical factory. [underlined: Total cohort]: 2,160 male rubber production workers (hourly employees); subcohorts also established for workers exposed to 2-mercaptobenzothiazole (MBT), aniline, and phenyl-β-naphthylamine (PBN) [underlined: Follow-up]: Censored at age 85 Mortality: 1955 to 2005 Incidence: 1971 to 2005 [underlined: Loss to follow-up]: 14 subjects emigrated, 32 untraced
Reference population | [underlined: Mortality]: Serial mortality rates for England and Wales [underlined: Incidence]: expected numbers from national cancer registration [underlined: Internal analysis]: Cohort members not exposed to ortho-toluidine
All-cause and all-cancer mortality | ortho-Toluidine subcohort All-causes SMR = 1.00 [0.60–1.58]; 17 All-cancers SMR = 1.37 [0.60–2.71]; 7
Study Design and Analytical Methods | Historical mortality and morbidity study of bladder cancer External analysis: SMR and SRR using person years at risk Internal analysis: Poisson regression – employment duration was categorized into three levels; combined incidence and mortality Adjusted internal analysis: Controlled for exposure to aniline, MBT and PBN, age and calendar period
Exposure Data and Information Assessment
Exposure: levels and co-exposures | “ortho-Toluidine was used in the Sopanox department from 1936 to 1979; aniline, MBT and PBN not used in this department Overlap of membership in 4 subcohorts (ortho-toluidine, aniline, MBT, and PBN) Levels of co-exposures not reported except for MBT
Exposure assessment | Job History (unique job-department titles) for 1930 to 1988 Cumulative duration of employment in ortho-toluidine-exposed department calculated using 3 time-dependent variables
Assessment: other exposure | JEM created for MBT - cumulative exposure, cumulative duration of exposure for PBN and niline
Disease assessment | Mortality - death certificate from U.K. Office of National Statistics Morbidity - registration of malignant tumors [underlined: External analysis:] SMR limited to underlying cause on death certificate; SIR limited to malignant urinary bladder tumors [ICD-9: 188] [underlined: Internal analysis]: Primary cancer of the urinary bladder mentioned on death certificate or diagnosis of malignant or benign bladder tumor in cancer registries cancer registry data

[ ] = calculated based on observed vs. expected cases, not reported by authors.

NR = not reported; SMR = standardized mortality ratio; CI = confidence interval; ppm = parts per million; ppb = parts per billion; ICD = International Classification of Diseases; SIR = standardized incidence ratio; WHO = World Health Organization; NYC = New York City; TWA = time-weighted average; GM = geometric mean; ND = not detectable; SRR = standardized rate ratio; MBT = 2-mercaptobenzothiazole; PBN = phenyl-β-naphthylamine; JEM = job-exposure matrix.

Table D-2 Case-control Studies of ortho-Toluidine Exposure: Study Characteristics and Findings

| Study Characteristics and Overall Findings
Richardson et al. (2007) : Canadian Case-Control Study
Related References | None
Geographic Location | Canada
Population Characteristics
Cases: selection and ascertainment | [underlined: Cases:] 1,062 males with urinary bladder cancer [underlined: Case eligibility criteria]: Diagnosed with urinary bladder cancer at 20+ yr old, between 1983 and 1990 and returned a lifetime occupational questionnaire; identified from the British Columbia Cancer Registry [underlined: Participation rate:] 60.1% (15,463 of the 25,726 eligible cancer registrants returned a questionnaire). Final number of cases and controls based on those that provided completed occupational histories
Controls: selection and ascertainment | [underlined: Referents:] 8,057 males with other cancer [underlined: Referent eligibility criteria]: All cancers excluding urinary bladder, lung, and unknown sites, diagnosed between 1983 and 1990, and completed lifetime occupational questionnaire; identified from the British Columbia Cancer Registry [underlined: Matching criteria]: Matched on year of birth and year of diagnosis of cases; median matching ratio of controls to cases 7:1
Length of follow-back | Lifetime
Loss to follow-back | 5.6% of cases and 4.3% controls excluded due to incomplete occupational histories
Study Design and Analytical Methods | Population cancer registry-based case-control design Analysis by cumulative exposure and test for linear trend Corrected for multiple comparisons; chemicals selected for further analysis if (a) associated with at least 3 of 9 cases or (b) IARC suspected or known bladder carcinogens [underlined: Confounding]: Ethnicity, marital status, education, questionnaire respondent, alcohol, smoking variables analyzed by backwards stepwise conditional logistic regression
Exposure Data and Information Assessment
Exposure: levels and co-exposures | Not reported
Exposure assessment | Lifetime JEM constructed based on self-reported occupational history and NIOSH NOES (1983–1986) occupational exposure survey using U.S. occupational and industry codes Estimated ever-exposed plus estimated cumulative exposure converted to ordinal scale (0 = no exposure, 1 = low, 2 = medium, 3 = high) Exposure truncated 5 yr before diagnosis
Assessment of co-exposures and other potential confounders | No assessment of occupational co-exposures Assessment of non-occupational co-exposures assessed via questionnaire
Disease assessment | Histologically confirmed urinary bladder cancer (ICD-9) identified from cancer registry
Castro-Jiménez and Orozco-Vargas (2011)
Related References | None
Geographic Location | Colombia
Population Characteristics
Cases: selection and ascertainment | [underlined: Cases:] 85 cases of acute lymphoblastic leukemia [underlined: Case eligibility criteria]: All children <15 years old diagnosed Jan 2000 to Mar 2005 not adopted, living with biological parents, no previous cancer, both parents agree to participate. Identified from hospital registries of 6 tertiary care centers, Colombia
Controls: selection and ascertainment | [underlined: Referents]: 85 matched controls [underlined: Referent eligibility criteria]: Healthy, never diagnosed with cancer, not adopted, living with biological parents. Residents of neighborhoods in which cases lived [underlined: Matching criteria]: Matched on sex and age at diagnosis of cases ±2–3 years; ratio of controls to cases = 1:1
Length of follow-back | (a) 2 years prior to conception; (b) pregnancy to diagnosis of case
Study Design and Analytical Methods | Hospital-based cases; population-based controls [underlined: Confounding:] crude (using age and sex matched cases and controls) and multivariate analysis considering maternal age, education, breastfeeding, periconceptual disease, maternal disease in pregnancy, urban/rural residency, prenatal parental smoking, parental alcohol or drug use, birth weight, gestational age
Exposure Data and Information Assessment
Exposure: levels and co-exposures | List of 13 hydrocarbons or hydrocarbon groups based on IARC classification of known or suspected human carcinogens (Group 2A), including ortho-toluidine; levels not reported
Exposure assessment | JEM based on self-reported parental occupation (industry) and home/environment exposure (questionnaire) ortho-Toluidine exposure assigned by occupational physician based on SIC code for parental occupation and agents observed in NIOSH 1983–6 NOES Survey by SIC code
Assessment of co-exposures and confounders | JEM used to assign exposure by occupational physician based on parental questionnaire data using SIC-coded parental occupation and agents observed in NIOSH 1983–6 NOES Survey
Disease assessment | Cases of acute lymphoblastic leukemia (ICD NR) identified from institutional registers and histologically verified

IARC = International Agency for Research on Cancer; JEM = job-exposure matrix; NIOSH = National Institute for Occupational Safety and Health; NOES = National Occupational Exposure Survey; ICD = International Classification of Diseases; SIC = Standard Industrial Classification; NR = not reported.

## D.2 Assessment of Potential Bias, Analytical Methods, and Other Study Quality Characteristics

Biases in observational studies are often classified into three major categories: (1) selection bias, (2) information bias, and (3) confounding (discussed in Section 3.3.2). Studies with lower potential for bias are generally considered to be the most informative for cancer evaluation. However, the presence of a potential bias in a study does not necessarily mean that the findings of the study should be disregarded. Therefore, an important step in the process of evaluating biases is to determine the probable impact of the described biases on study results—that is, the magnitude of distortion and the direction in which each bias is likely to affect the outcome of interest (if known). The impact of the potential bias or confounding on the study findings is discussed in the cancer assessment (see Section 3.4).

For this review, overall conclusions on the concern for the potential (unlikely/minimal, possible, or probable) of selection and information bias and the adequacy of other quality factors (good, adequate, or limited) for each study were made using the questions and guidelines outlined in the protocol. In some cases, there is inadequate information to evaluate the level of concern. The guidelines describe the ideal methods and design for each study element. The terms used for defining the potential for bias are as follows:

- Unlikely/minimal: Information from study designs and methodologies indicate that the potential for bias is unlikely or minimal and are close to the ideal study characteristics.
- Possible: Study designs or methodologies are close to but less than ideal, recognizing that in observational studies, there is almost always some methodological or informational limitation and thus some potential for certain types of bias.
- Probable: Study designs or methodologies suggest that the potential for a specific type of bias is likely.
- Unknown: Insufficient information is provided to enable an evaluation to be made.

If adequate information is available, each type of bias is also characterized as to whether it is differential or non-differential. Differential (systematic) biases in the selection of study participants or information assessment are related to both exposure and disease status and have the potential to bias findings in one direction or another, whereas non-differential (random) biases, which are not related to both exposure and disease, tend to reduce the precision of the risk estimates and often bias the findings toward the null. For example, occupational cohort studies may have limited exposure data across exposure groups, increasing the potential for nondifferential exposure misclassification, and may also have the potential for a healthy worker (hire or survival) effect, a type of selection bias that tends to bias findings away from finding an effect (if present) in studies where the comparison group comes from the general population.

An overview of the approach and conclusions is discussed in Section 3.3 and details of the quality assessment are provided below in Table D-3.

Table D-3 Summary of Study Quality

Study | Selection Bias Attrition Bias (Loss to Follow-up) | ortho-Toluidine Exposure Assessment: Adequacy | Urinary Bladder Cancer Assessment: Adequacy | Ability to Detect an Effect for Urinary Bladder Cancer and Analytical Methods: Adequacy
Case and Pearson (1954) U.K. dye workers | Selection bias [underlined: Possible:] Healthy worker effect, which would bias positive findings towards the null, is always possible in occupational cohort studies, however, authors did not report all-cause mortality. Loss to follow-up [underlined: Unknown] | Exposure characterization [underlined: Limited:] Exposure inferred from process^a^ Misclassification of workers’ exposure [underlined: Possible (non-differential):] Exposure not assigned at the individual level; exposure category assigned according to production process. | Misclassification of deaths [underlined: Probable (differential):] Urinary bladder cancers identified and cross-verified via multiple sources for cohort, which may differ from assessment of deaths in the general population. Deaths diagnosed outside region may be missed. Misclassification of cases [underlined: Possible (non-differential):] Mortality studies will miss cases that do not result in death, a concern for urinary bladder cancer, which has a higher survival rate. | Ability to detect an effect [underlined: Overall limited:] Statistical power: 8.9% power to detect twofold increase in risk. [underlined: Adequate] probability of moderate or higher exposure, exposure ND but likely high since workers were employed in the early 1900’s. [underlined: Adequate] length of follow-up for total cohort. Analysis [underlined: Limited:] Observed/expected only, using national comparison data.
Pira et al. (2010) Italian dye workers | Selection bias [underlined: Possible:] All-cause mortality not decreased among total cohort but not reported for ortho-toluidine subcohort. Loss to follow-up [underlined: Possible:] 12% of total cohort lost to follow-up before 1989, <4% lost to follow-up after 1989 but no information on loss to follow-up in o-toluidine subcohort or whether loss to follow-up is related to exposure and disease. | Exposure characterization [underlined: Adequate:] Specified as part of process by authors; no quantitative exposure data. Misclassification of workers’ exposure [underlined: Possible (non-differential):] Individual person-years of exposure assigned based on detailed work history; workers did not change departments or jobs. | Misclassification of deaths [underlined: Possible (non-differential):] Diagnosis by death certificates subject to potential misclassification; ICD codes (if used) not stated. Misclassification of cases [underlined: Possible (non-differential)]: Mortality data only. | Ability to detect an effect [underlined: Overall limited:] Statistical power; 11.7% power to detect wofold increase in risk. [underlined: Adequate] probability of moderate or higher exposure. Level of exposure ND but likely high since workers were employed in the early 1900s. [underlined: Adequate] length of follow-up for total cohort. Analysis [underlined: Limited:] External mortality analysis by department only.
Ott and Langner (1983) U.S. dye workers | Selection bias [underlined: Possible:] Statistically non-significant decrease in all-cause SMR <1.0 in subcohort suggests a potential healthy worker effect. Loss to follow-up bias [underlined: Unlikely/minimal]: Follow-up was conducted using company and social security records; no evidence to suggest the potential for bias. | Exposure characterization [underlined: Limited:] Limited quantitative exposure assessment of air and urine at one time point but estimates likely relevant for only some of the workers.^b^ Misclassification of workers’ exposure [underlined: Probable (non-differential):] No information on exposure at the individual subcohort level. Subcohort combined workers making thioindigo dyes with those making bromindigo dyes. o-Toluidine appears to have been used as an intermediate in thioindigo dye production, but its use in four different processes is unclear. Bromindigo dyes were produced in a different section of the building (separated by a firewall) and did not involve o-toluidine. | Misclassification of deaths [underlined: Possible (non-differential):] Diagnosis by death certificates. Misclassification of cases [underlined: Possible (non-differential):] Mortality study only. | Ability to detect an effect [underlined: Overall limited] Statistical power: ~15% power to detect twofold increase in risk. [underlined: Limited] probability of moderate or higher exposure. Only 77% workers were employed <5 years; level of exposure known only for one time period and number/extent of workers exposed to o-toluidine unknown. [underlined: Adequate] length of follow-up for subcohort. Analysis [underlined: Limited:] External mortality analysis by department and duration of employment. Reporting also limited. Urinary bladder cancer (observed/expected) only reported for the entire cohort (since there were 0 cases).
Stasik (1988) 4-COT production workers | Selection bias [underlined: Probable:] Differential bias towards finding an effect. Incidence study was initiated based on findings of 2 urinary bladder cancer cases while conducting a mortality study of these workers. Loss to follow-up bias Unknown | Exposure characterization [underlined: Limited]^c^: No quantitative exposure assessment; not clear if processing workers were exposed to o-toluidine. Misclassification of workers’ exposure [underlined: Probable (non-differential):] no exposure assessment at the individual level. | Misclassification of cases [underlined: Probable (differential):] Poor documentation; cases were identified using unspecified hospitals and other institutes, which may differ from methods used to identify expected cases in regional cancer registry. | Ability to detect an effect [underlined: Overall: Limited] Statistical power: 8.5% power to detect twofold increase in risk. [underlined: Limited] probability of moderate or higher exposure: level/duration exposure ND. [underlined: Limited] follow-up Analysis [underlined: Limited:] External incidence analysis of workers in 4-COT production department included in analysis only if employed prior to 1970. Non-contiguous regional comparison; limited data on cancer endpoints.
Carreón et al. (2014); Carreón et al. (2010) (mortality) NIOSH (U.S.) rubber chemical workers | Selection bias [underlined: Unlikely/minimal] in analyses using internal controls, possible in external analysis. Statistically non-significant decrease in all-cause mortality among definitely exposed workers suggests a potential healthy worker effect, which would bias towards the null. Loss to follow-up bias [underlined: Unlikely/minimal:] Multiple sources of data used to ascertain vital status at end of follow-up period. | Exposure characterization [underlined: Good:] Extensive quantitative measurement of ortho-toluidine in air. o-Toluidine and o-toluidine Hb adducts measured in sample of workers. Misclassification of workers’ exposure [underlined: Unlikely/minimal (non-differential):] Workers grouped according to definitely (high/moderate), probably (low/regular), probably (low/irregular), and probably not exposed based on updated detailed occupational histories (including jobs and dept.), exposure characterization of work areas/processes by investigators and company plus biological monitoring (described above). | Misclassification of cases [underlined: Unlikely/minimal (non-differential):] Incident cases identified and cross-verified via multiple sources including cases who moved from the NY to Pennsylvania, California, Ohio, Texas, and Florida state cancer registries. Any cases who moved elsewhere would be missed. Misclassification of deaths [underlined: Possible (non-differential):] Death certificates, company records or SSA used to identify deaths. | Ability to detect an effect [underlined: Overall good:] Statistical power approx. 93% for incidence and approx. 11% for mortality to detect twofold increased risk among definitely exposed workers. [underlined: Good] probability of moderate or higher exposure: based on extensive industrial hygiene and biomonitoring data. [underlined: Good] length of follow-up Analysis [underlined: Good:] SIR and SRR analyzed by exposure probability, duration of employment, time since first employment and cumulative exposure (lagged and unlagged) ranked categories. HR for cumulative exposure also analyzed by Cox regression for ranked and continuous measures of exposure. SMR analyzed only by 2010 exposure probability categories. No formal methods for controlling for confounding from co-exposures or smoking but biomonitoring data provide adequate data to evaluate (see Table D-2) and smoking information on subset of workers.
Sorahan (2008) U.K. rubber chemical workers | Selection bias [underlined: Unlikely/minimal] in analyses using internal controls, possible in external analysis. All-cause mortality not reported for o-toluidine subcohort. Loss to follow-up bias [underlined: Unlikely/minimal:] 2% (emigration + not traced) for mortality; 3% for incidence. | Exposure characterization [underlined: Adequate:]^d^ no quantitative exposure data. Misclassification of workers’ exposure [underlined: Possible (non-differential):] Person-years at risk in o-toluidine department based on individual work histories. | Misclassification of cases [underlined: Unlikely/minimal (non-differential):] Cases identified via national regional cancer registry using ICD-8, 9, and 10 coding). Misclassification of deaths [underlined: Possible (non-differential):] National death registry used. | Ability to detect an effect [underlined: Overall adequate:] Statistical power: 17.3% power to detect twofold increase in risk. [underlined: Adequate] probability of moderate or higher exposure: level/duration exposure ND but levels likely to be high. [underlined: Adequate] length of follow-up for total cohort. Analysis [underlined: Good:] Included external analysis and internal RR analysis by duration of exposure, adjusted for 3 other exposures.
Richardson et al. (2007) Canadian Case-control study | Selection bias [underlined: Possible:] Use of cancer cases as controls may bias towards the null if o-toluidine is a risk factor for those cancers, but unknown if o-toluidine causes cancers at other sites. Participation rate 60% which may increase potential for bias. | Exposure characterization [underlined: Limited:] Study is population-based; JEM is limited because exposure classification by industry and occupation based on a (separate) qualitative walk-through exposure survey in one calendar year. No information on specific jobs. Exposure misclassification [underlined: Probable (non-differential):] Cumulative exposure is the product of the probability of exposure, based on the limited JEM, and duration of employment based on self-reported occupational history, which may have been subject to recall error. | Misclassification of cases [underlined: Unlikely/minimal (non-differential):] Cases and controls identified via cancer registry. | Ability to detect an effect [underlined: Overall limited] Statistical power to detect twofold increase in risk could not be calculated (larger number of exposed cases [39] than most cohort studies). Exposure to o-toluidine rare among study participants (~3.6% cases, exposure prevalence not reported among controls). [underlined: Unknown] probability of moderate or higher levels of exposure: levels/duration exposure ND but likely to be imprecise over lifetime Analysis [underlined: Limited]: ORs adjusted for demographic/lifestyle factors but no control for potential confounding by co-exposures; analysis by 3 categories of exposure level but categories likely to be imprecise.

HWE = healthy worker (hire or survival) effect; JEM = job-exposure matrix; ICD = International Classification of Diseases; ND = not determined; OR = odds ratio; RR = relative risk; SIR = standardized incidence ratio; SMR = standardized mortality ratio; SRR = standardized rate ratio.

^a^ o-Toluidine exposure can be inferred among the magenta production group via knowledge of the processes used in the UK Howe (1977) (also see Appendix C).

^b^ Inadequate data on the thioindigo and bromindigo dye manufacturing process were provided to determine the probability or levels of potential exposure to ortho-toluidine, and it is not used in conventional methods of making these specific dyes (see Section 2); however, ambient and urine levels of ortho-toluidine were reported in only one (1940s) survey.

^c^ ortho-Toluidine is a precursor in the synthesis of 4-chloro-ortho-toluidine (by acetylation of ortho-toluidine to producing N-acetyl-o-toluidine and further chlorination and hydrolysis to produce 4-chloro-ortho-toluidine) and would be expected to occur in comparable amounts relative to the product, based on the amount of feedstock (see Section 2); however, no detailed data on the process, or qualitative or quantitative data on levels of ortho-toluidine were provided.

^d^ ortho-Toluidine is the principal precursor in the synthesis of Sopanox (ortho-tolylbiguanide) where it is reacted with dicyanamide and hydrochloric acid; workers in the Sopanox department reportedly had “appreciable” exposure to ortho-toluidine Sorahan and Pope (1993).

^e^ Number of exposed controls were not provided but were estimated from odds rations and number of exposed cases.

## D.3 Background Carcinogenicity Information on Co-exposure of Interest

Table D-4 Carcinogenicity Information on Co-exposures of Interest^a^

Co-exposure | Studies | Comments | Cancer Evaluation | Urinary Bladder Cancer Evaluation
N-acetyl-o-toluidine | Stasik (1988) ^b^ | – | No evaluation | –
o-Aminoazotoluene | Pira et al. (2010) ^b^ | No human data | IARC- Group 2B | Limited evidence in animals
2-Aminobenzoic acid | Ott and Langner (1983) ^b^ | Insufficient data in experimental animals for evaluation | IARC- Group 3 | –
4-Aminobiphenyl | Carreón et al. (2014) ^b^ | – | IARC- Group 1 RoC- RAHC | IARC/RoC Sufficient evidence in humans
Aniline | Pira et al. (2010) ^c^ Sorahan (2008) ^c^ Carreón et al. (2014) ^c^ | – | IARC- Group 3 | Not a target site in experimental animals; no evidence from human studies
4-Chloro-acetyl-ortho-toluidine | Ott and Langner (1983) ^b^ | – | No evaluation | –
4-Chloro-ortho-toluidine | Ott and Langner (1983) ^b^ Stasik (1988) ^c^ | – | RoC- RAHC IARC- Group 2A | IARC/RoC Limited evidence in humans
6-Chloro-ortho-toluidine | Stasik (1988) ^c^ | – | No evaluation | –
2,5-Diaminotoluene | Pira et al. (2010) ^c^ | No human data Insufficient data in experimental animals for evaluation | IARC- Group 3 | –
1,2-Dihydroacenaphthylene | Ott and Langner (1983) ^b^ | – | No evaluation | –
Formaldehyde | Case and Pearson (1954) ^b,e^ | – | IARC- Group 1 RoC- Known to be a human carcinogen | Not a target site in humans or experimental animals
Fuchsin (New Magenta)/Magenta III^e^ | Case and Pearson (1954) ^c,e^ Pira et al. (2010) ^c^ | IARC: Magenta production is a known human bladder carcinogen (Group 1); IARC could not separate effects of magenta from its co-exposures (which include ortho-toluidine) Magenta I inadequate studies in experimental animals CI Basis Red 9 (IARC/RoC) Sufficient evidence of carcinogenicity in experimental animals (not urinary bladder) | Magenta (not defined) IARC- Group 2B CI basic red 9 (Magenta 0/para-magenta) RoC- RAHC | –
4,4-Methylene-bis (2-methylaniline) | Pira et al. (2010) ^c^ | No human data | RoC- RAHC IARC- Group 2B | Not a target site in experimental animals
2-Mercaptobenzothiazole | Sorahan (2008) ^c^ | – | Not evaluated | Increased risk in Sorahan study, which is diminished after controlling for exposure to ortho-toluidine ; no independent evidence in other epidemiological studies (Collins et al. 1999; Veys 1996)
Nitrobenzene | Ott and Langner (1983) ^b^ Carreón et al. (2014) ^c^ | No human data | RoC- RAHC IARC- Group 2B | Not a target site in experimental animals
ortho-Nitrotoluene | Case and Pearson (1954)^b,d^ Pira et al. (2010)^c^ | No human data | RoC- RAHC IARC- Group 2A | Not a target site in experimental animals
Phenyl-β-naphthylamine | Sorahan (2008) ^c^ | – | IARC- Group 3 | Increased risk in Sorahan study, which is diminished after controlling for exposure to ortho-toluidine; no independent evidence
Safranine T | Pira et al. (2010) ^c^ | – | No evaluation | –
Thioindigo dyes | Ott and Langner (1983) ^c^ | – | No evaluation | –
1-Tolylbiguanidine (“Sopanox”) | Sorahan (2008) ^c^ | – | No evaluation | Product in ortho-toluidine dept; no independent evidence

IARC = International Agency for Research on Cancer; Group 1 = carcinogenic to humans; Group 2A = probably carcinogenic to humans; Group 2B = possibly carcinogenic to humans; Group 3 = not classifiable as to its carcinogenicity in humans; RoC = Report on Carcinogens; RAHC = reasonably anticipated to be a human carcinogen.

^a^ Carcinogenicity information is reported for co-exposures where there were more than trace amounts of exposure to a chemical (unless it was a known human bladder carcinogen); carcinogenicity information was obtained from IARC and RoC evaluations or from literature searches (in the absence of an IARC or RoC evaluation).

^b^ Little evidence of exposure.

^c^ Probably exposed.

^d^ According to Howe (1977), U.K. magenta was prepared by condensing ortho-toluidine with formaldehyde in the presence of ortho-nitrotoluene as an oxidizing agent.