# Appendix C Background Exposure Information on Epidemiological Studies

The available epidemiological studies evaluating potential exposure to ortho-toluidine and cancer include workers in industries manufacturing either (1) dyestuffs, (2) synthesis of 4-chloro-ortho-toluidine, or (3) certain rubber chemicals (see Section 1.4). These occupational settings also involve potential exposure to other substances. Many of the studies do not have detailed information on exposure to ortho-toluidine or other co-exposures; however, some of this information can be inferred from knowledge of the manufacturing process, or dye chemistry. In order to provide background information for interpreting these epidemiological studies, the nature of the potential for exposure to ortho-toluidine and to other intermediates or end products in these manufacturing processes is discussed below.

## C.1 Manufacture of Dyestuffs

The review of epidemiological studies of dyestuffs manufacture (see Section 3) with potential exposure to ortho-toluidine includes four different cohorts ([1] Case et al. (1954) and Case and Pearson (1954), [2] Rubino et al. (1982), [3] Stasik (1988), and [4] Ott and Langner (1983)) that examined the incidence of urinary bladder cancer in relation to manufacturing processes that potentially involved exposure to ortho-toluidine. Occupational exposure to ortho-toluidine can be inferred from knowledge of dye production processes in dye worker cohort studies where very few or no quantitative data are available on exposure to ortho-toluidine (Freeman 2012). In general, exposure to ortho-toluidine was more likely to have occurred in manufacturing facilities prior to the adoption of formal regulations regarding building ventilation and personal protective equipment (e.g., adoption of OSHA regulations in the mid-1970s).

### C.1.1 Aniline Production in Great Britain: Case et al. (1954) and Case and Pearson (1954)

Case et al. (1954) and Case and Pearson (1954) reported findings of urinary bladder cancer among dyestuff workers, employed from 1910 to 1952 at 21 firms in Great Britain Although the authors do not mention exposure to ortho-toluidine in their study, potential exposure might have occurred among both aniline and magenta manufacturing workers (see below) based on the production processes of the first half of the 20th century. The benzene preparations used in the early part of the 20th century varied in purity and often contained toluene. Crude benzene was marketed in preparations identified based on the percentage that distills before 100°C is reached as 90s (75% benzene, 24% toluene, 1% xylene), 50s (50% benzene, 40% toluene, 10% xylene), and 30s (10% benzene, 60% toluene, 30% xylene) (Cain and Thorpe 1905). When the crude benzene preparations were subjected to the processes of nitration and reduction, a mixture of aniline and toluidines (ortho-, meta-, and para- in the approximate proportions 15:9:1) resulted. The probability of exposure to ortho-toluidine among aniline manufacturing workers must be considered as low because of the uncertainty about the degree of purity of the benzene, especially as it might have changed over the 42 years of exposure covered by these studies.

Figure C-1

Synthesis of Aniline from Benzene and Mixed Isomers of Toluidine from Toluene by Successive Nitration and Reduction Reactions

### C.1.2 Magenta Manufacturing in Great Britain: Case et al. (1954), Pira et al. (2010)

The studies of dyestuff manufacture and use workers by Case et al. (1954) and Case and Pearson (1954) covered the period of 1910 to 1952 and included manufacture of magenta and other dyes. (Magenta III, also called “New Fuchsin” or new magenta, III is the product generally produced in the United Kingdom (Figure C-2).

Figure C-2

Structure of Magenta III

In the United Kingdom, the process for manufacturing magenta, resulting mainly in the production of magenta III, involved condensation of ortho-toluidine and formaldehyde in the presence of ortho-nitrotoluene (Howe 1977). One can reasonably infer that workers in the study by Case et al. (1954) and Case and Pearson (1954) were exposed to ortho-toluidine (see Section 3).

A sub-cohort of dyestuff workers engaged in manufacture of fuchsin or ortho-toluidine was included in the bladder cancer mortality study reported by Pira et al. (2010) (see Section 3). Earlier studies of dyestuff workers from the same plant were published by Rubino et al. (1982) and Piolatto et al. (1991); the latter publication reported findings for magenta and Safranine T manufacturing workers combined. Safranine T workers had potential co-exposures to 2,5-diaminotoluene and aminoazotoluene; Pira et al. (2010) reported estimates that appear to be specific for ortho-toluidine and magenta manufacturing workers. The process for making ortho-toluidine and 4,4'-methylene bis(2-methylaniline) as precursors for fuchsin (identified as New Fuchsin by Rubino et al. 1982) are shown in Figure C-3. ortho-Toluidine was used as a precursor for the production of New Fuchsin (Figure C-4). Rubino et al. (1982) reported that the ortho-toluidine production department was housed in a different building within the factory area from the building in which New Fuchsin was produced. The process for producing the fuchsin dye was described as involving heating a mixture of ortho-toluidine, 4,4'-methylene bis(2-methylaniline), and aniline with a step at the end of the process for the recovery of excess ortho-toluidine.

Figure C-3

Synthesis of ortho-Toluidine and 4,4'-Methylene bis(2-methylaniline) for Production of Fuchsin (New Fuchsin)

Figure C-4

Synthesis of New Fuchsin from ortho-Toluidine, 4,4'-Methylene bis(2-methylaniline), and Aniline

### C.1.3 Manufacture of Dyes and Dye Intermediates in the United States: Ott and Langner (1983)

Ott and Langner reported that U.S. dye production workers employed in the bromindigo and thioindigo production area of a manufacturing facility between 1914 and 1958 were potentially exposed to ortho-toluidine. Industrial hygiene measurements taken at the plant during the mid-1940s for ortho-toluidine in breathing zone or area samples were consistently <0.5 ppm, and results of medical surveillance that included measurement of ortho-toluidine in urine ranged from less than the limit of detection of 0.3 ppm up to 1.7 ppm. ortho-Toluidine was included in a list of raw materials and intermediate products for production of thioindigo, which consisted of four alternately run batch processes involving manufacture of the following dyes: thioindigo (pink B), scarlet G, red 3B, and red 2B; however, no other details on the chemistry of these processes were reported that would indicate which process(es) involved exposure to ortho-toluidine. ortho-Toluidine might have been used to make intermediates, e.g., anthranilic acid or ortho-nitrobenzoic acid, that can be used in the manufacture of thioindigoid dyes (Freeman 2012). In addition to ortho-toluidine, raw materials and intermediate products for the four thioindigo processes included 1,2 dihydroacenaphthylamine, sodium nitrite, chloroacetic acid, 4-chloro-ortho-toluidine, 4-chloro-acetyl-ortho-toluidine, thioindoxyl, chlorosulfonic acid, ethanol, and 2-aminobenzoic acid.

## C.2 Manufacture of Other Intermediates

The chemical intermediate 4-chloro-ortho-toluidine (4-COT) can be used in the production of dyes and pigments and of the pesticide chlordimeform. Stasik (1988) studied a facility in Germany that produced and processed 4-COT, but the author did not report the end use for that product. Possible exposure to ortho-toluidine existed for a sub-cohort of 4-chloro-ortho-toluidine production and processing workers from that cohort (see Section 3). 4-Chloro-ortho-toluidine is produced by acetylation of ortho-toluidine to yield N-acetyl-ortho-toluidine, followed by chlorination to yield chloro-N-acetyl-ortho-toluidines, which are hydrolyzed to yield 4-chloro-ortho-toluidine (see Figure C-5). 6-chloro-ortho-toluidine originates from chlorination in the 6-position of N-acetyl-ortho-toluidine (simultaneous with chlorination in the 4 position) and carries over to the hydrolysis step, creating 6-chloro-ortho-toluidine as a by-product (Freeman 2012).

Figure C-5

Chemistry Associated with Synthesis of 4-Chloro-ortho-toluidine

## C.3 The Rubber Chemical Industry and Exposure to ortho-Toluidine

The major source of information on exposure to ortho-toluidine in the rubber chemical production industry is from the cohort studied by Carreón et al. (2014) and earlier by Carreón et al. (2010) and Ward et al. (1991) (see Section 3). Exposure data for the workers in this cohort have been reported by Ward et al. (1996), Ruder et al. (1992), Teass et al. (1993) and Hanley et al. (2012). The exposure data reported by Hanley et al. (2012) are discussed below. Additional information was obtained from the studies by Sorahan and Pope (1993), Sorahan et al. (2000), and Sorahan (2008) of the rubber industry in the United Kingdom.

### C.3.1 Manufacture of a Rubber Antioxidant in the United States: Hanley et al. (2012)

The subcohort studied by Carreón et al. (2014; 2010) (Section 3) was also the subject of a retrospective exposure assessment, which was described in the publication by Hanley et al. (2012). Workers were engaged (1) from 1957 onwards in the production of rubber antioxidants from ortho-toluidine, aniline, hydroquinone, toluene or xylene, and a proprietary catalyst; phenol and diphenylamine were the reaction byproducts, and (2) from the mid-1950s to either 1970 or 1994, depending on the product, the production of accelerants from nitrobenzene, aniline, and benzothiazole. 4-aminobiphenyl was a suspected contaminant in some of the process chemicals and was found in trace amounts (<1 ppm) in 3 of 9 bulk samples of process chemicals (Ward et al. 1991). Both antioxidants and accelerators were produced and packaged in parallel operations in the same rooms of the plant’s rubber chemicals department (Hanley et al. 2012). The highest breathing zone exposures to ortho-toluidine were measured for the antioxidant process and for maintenance (see Figure 1-4), with measurements for all departments ranging from 0.020 to 0.37 ppm (N = 45). The geometric mean for company-collected TWA breathing zone samples from the rubber chemicals department (see Figure 1-5) were highest in 1976 to 1979 (0.1 ppm, N = 30), and declined to 0.015 ppm (N = 200) in 1980 to 1994 and 0.0028 ppm (N = 127) in 1995 to 2004. Ambient air levels of aniline in the rubber chemicals were approximately half of those for ortho-toluidine, and nitrobenzene levels were almost all non-detectable. Biomonitoring data for ortho-toluidine, aniline, and 4-aminobiphenyl in urine and Hb adducts collected in 1990 (Ward et al. 1996), which would integrate ambient and dermal exposure, indicated that exposure to ortho-toluidine was approximately 3–4 times that of aniline. Hanley et al. (2012) identified a number of changes or procedures from the beginning of rubber chemical manufacture in 1954 through 1988 that had the potential to impact exposure to ortho-toluidine and other chemicals. The major change that potentially increased exposure was a steady increase in chemical use, including ortho-toluidine, for production of rubber chemicals from 1960 to 1970. Changes that could potentially reduce exposure included (1) initiation of an air monitoring program in 1975–1976, (2) replacement of a manual charging operation for adding chemicals with an automated premix reactor feed system in 1978, (3) establishment of a company policy for personal protective equipment in or around 1980, and (4) various changes in shower and laundry facilities, material recycling, leak protection, and automated bagging during the 1990s.

Although quantitative exposure data were not available for individual workers, Hanley et al. (2012) were able to assign them to one of three categories (i.e., “definitely exposed,” “probably exposed,” or “probably not exposed”) based on the departments in which the individuals had worked using updated information from “a plant walkthrough, interviews with employees, management and union representatives, and review of records.” The same categories had been used to categorize exposure for the earlier study by Ward et al. (1991), but the assessment by Hanley et al. (2012) involved several changes in assignments by departments. In the expanded and updated analysis conducted by Carreón et al. (2014), exposure rank estimates based on department, job and year, multiplied by duration of exposure, enabled NIOSH industrial hygienists, blinded to case status, to assign cumulative exposure ranks to 225 department-job classifications (Carreón et al. 2014).

Table C-1 Exposure Classifications Used in NIOSH Rubber Chemical Cohort Studies (Carreón et al. 2014; Carreón et al. 2010; Hanley et al. 2012; Ward et al. 1991)

Exposure Category | Ward et al. (1991) | | Carreón et al. (2010) | | Carreón et al. (2014)
Exposure Category | Job Title | Total (N) | Job Titles | Total (N) | Job Titles | Total (N)
Definitely exposed | Ever employed: 1946–1988 Rubber chemical dept. | 708 | Ever employed: 1946–1988 Rubber chemical dept., maintenance, laboratory (inc. quality control, R&D) | 962 | Ever employed: 1946–2006 Dept.-jobs with moderate/high exposure e.g., rubber chemical, maintenance | 900
Possibly exposed | Ever employed: 1946–1988: Maintenance, shipping/packaging/warehouse, janitorial, yard work Never in rubber chemicals dept. | 288 | Ever employed: 1946–1988 Shipping/packaging/warehouse, janitorial, yard work Temporary assignment from headquarters, none assigned depts. Never in rubber chemicals, maintenance, or laboratory depts. | 187 | Ever-employed: 1946–2006 Probably exposed low/regular e.g., shipping, warehouse, lab | 195
Possibly exposed | Ever employed: 1946–1988: Maintenance, shipping/packaging/warehouse, janitorial, yard work Never in rubber chemicals dept. | 288 | Ever employed: 1946–1988 Shipping/packaging/warehouse, janitorial, yard work Temporary assignment from headquarters, none assigned depts. Never in rubber chemicals, maintenance, or laboratory depts. | 187 | Probably exposed low/irregular e.g., nurse, supervisor, janitor | 155
Probably not exposed | Never employed in above depts. All work prior to Jan 1, 1957 | 753 | Never in above depts. All work prior to Jan 1, 1957 | 600 | Never employed 1946–2006 in depts. with direct exposure to ortho-toluidine, aniline, or nitrobenzene, e.g., secretary, accountant All work prior to Jan 1, 1957 | 562

### C.3.2 Manufacture of a Rubber Antioxidant in the United Kingdom: Sorahan and Coworkers

Sorahan and Pope (1993), Sorahan et al. (2000), and Sorahan (2008) studied a cohort of workers at a chemical production factory that manufactured and used 2-mercaptobenzothiazole (MBT) and phenyl-β-naphthylamine (PBN) along with vulcanization inhibitors and accelerators, antioxidants, and other proprietary products for the rubber industry in the United Kingdom (see Section 3). Exposure to ortho-toluidine occurred from 1936 to 1979, in the department manufacturing ortho-tolylbiguanide (also called Sopanox), which was produced by reacting ortho-toluidine with dicyanamide in the presence of hydrochloric acid. No information was provided on exposure levels. Exposure to aniline, MBT, and PBN occurred in other departments; however, some workers switched departments.