# Appendix B Regulations and Guidelines

## B.1 Regulations

### B.1.1 U.S. Environmental Protection Agency (EPA)

#### B.1.1.1 Clean Air Act

National Emission Standards for Hazardous Air Pollutants: Listed as a hazardous air pollutant.

#### B.1.1.2 Comprehensive Environmental Response, Compensation, and Liability Act

Reportable quantity (RQ) = 100 lb.

#### B.1.1.3 Resource Conservation and Recovery Act

Listed Hazardous Waste: Waste codes for which the listing is based wholly or partly on the presence of o-toluidine or o-toluidine hydrochloride = U222, U328, K112, K113, K114.

Listed as a hazardous constituent of waste.

### B.1.2 Occupational Safety and Health Administration (OSHA)

This legally enforceable PEL was adopted from the 1968 ACGIH TLV-TWA shortly after OSHA was established. The PEL may not reflect the most recent scientific evidence and may not adequately protect worker health.

Permissible exposure limit (PEL) = 5 ppm.

Potential for dermal absorption.

## B.2 Guidelines

### B.2.1 American Conference of Governmental Industrial Hygienists (ACGIH)

Threshold limit value – time-weighted average (TLV-TWA) = 2 ppm.

Potential for dermal absorption.

### B.2.2 National Institute for Occupational Safety and Health (NIOSH)

Immediately dangerous to life and health (IDLH) limit = 50 ppm.

Listed as a potential occupational carcinogen.

Potential for dermal absorption.