# 6 Overall Cancer Evaluation – Synthesis of Human, Animal, and Mechanistic Data

This section synthesizes the information from cancer and toxicological studies in experimental animals and human epidemiological studies and applies the RoC listing criteria to that body of knowledge to reach a preliminary listing recommendation.

‘Pentachlorophenol and by-products of its synthesis’ was defined as the substance under evaluation for the RoC because commercially available pentachlorophenol is a mixture of chemicals that are formed during the synthesis process and thus an integral part of human exposure to the primary chemical. The primary by-products are a mixture of isomers of higher chlorinated dibenzo-p-dioxins and dibenzofurans (hexa-, hepta-, octa-) and hexachlorobenzene. People exposed to pentachlorophenol have greater serum levels of these higher chlorinated dioxins than unexposed people (Collins et al. 2008; Collins et al. 2007; Dahlgren et al. 2007; McLean et al. 2009b). Therefore, the cancer evaluation is for this complex mixture.

Exposure to pentachlorophenol and by-products of its synthesis (hereinafter referred to as pentachlorophenol) is associated with an increased risk of NHL in studies in humans and is a multi-site carcinogen in animals. From the available cancer evidence in experimental animals, the observed carcinogenicity cannot be explained by the presence of by-products alone. The epidemiological studies cannot separate effects of pentachlorophenol from any effects of its by-products. Dioxin (specifically 2,3,7,8-tetrachlorodibenzo-p-dioxin) (Cogliano et al. 2011) has been linked to NHL in humans and it is reasonable that dioxin-like activity may contribute to the carcinogenicity of NHL observed in the cancer studies of exposure to pentachlorophenol. It is plausible that both pentachlorophenol and some of the by-products contribute to tumor formation in this complex mixture.

The mechanisms responsible for the carcinogenic effects of pentachlorophenol are not completely understood but what is known is supportive of the carcinogenicity of pentachlorophenol. Pentachlorophenol is associated with multiple mechanisms of carcinogenesis, including metabolism to genotoxic metabolites, oxidative damage, inflammation, cytotoxicity and sustained cell proliferation, immunosuppression, interference with gap junctional intercellular communication, and inhibition of apoptosis (see Section 5). All these mechanisms are relevant to humans.

## 6.1 Cancer Studies in Humans

There is limited evidence for the carcinogenicity of pentachlorophenol from studies in humans. An association of exposure to pentachlorophenol and NHL was observed in several studies of different occupational populations with differing co-exposures and in different geographical areas (see Section 3.4); however, the strength of the evidence varied among the studies. A statistically significant, exposure-response relationship with cumulative dermal exposure was observed in the most informative study, a large cohort study of Canadian sawmill workers (Demers et al. 2006). This finding is supported by the observation of an increased risk of NHL in a cohort study of Michigan pentachlorophenol-production workers (Collins et al. 2009b), the highest risks of NHL were observed among workers with higher surrogates for pentachlorophenol exposure (e.g., measures of exposure to chlorinated dioxin by-products of pentachlorophenol synthesis). The evidence from the other studies (Hardell et al. 1994; Hardell et al. 2002; Kogevinas et al. 1995; Ruder and Yiin 2011), most of which had methodological limitations, is considered to be more limited. Some studies also found an association between exposure to pentachlorophenol and multiple myeloma, soft tissue sarcoma, or kidney cancer; however, the evidence is either limited to one study or is not consistent across studies. Overall, the evidence from the epidemiological studies suggests that a causal relationship between exposure to pentachlorophenol and NHL is credible. However, because the evidence is based on a small number of high-quality studies with relatively moderate risk estimates, alternative explanations, such as chance, bias, or confounding, cannot be adequately excluded.

## 6.2 Studies in Experimental Animals

There is sufficient evidence of the carcinogenicity of pentachlorophenol from studies in experimental animals. Dietary exposure caused statistically significant increases for malignant or a combination of malignant and benign liver and adrenal gland tumors in male and female B6C3F_1_ mice, vascular tumors (hemangiosarcoma) in female mice, and mesothelioma and nasal tumors in male F344 rats (see Section 4). Pentachlorophenol caused liver tumors in mice, and dioxin-like components contributed to carcinogenicity; less pure technical grade pentachlorophenol, which has a higher total TEQ amount than Dowicide EC-7, had more tumors at the same exposure concentration than Dowicide EC-7.

## 6.3 Mechanistic Data

Although the mechanisms by which pentachlorophenol causes cancer in animals and potentially in humans are not known, the available data support biological plausibility and human relevance. Little information is known about the pathogenesis of NHL, but proposed mechanisms include metabolism to genotoxic and mutagenic metabolites, immunosuppression, DNA damage and chromosome breakage, and inhibition of apoptosis. Pentachlorophenol exposure has been shown to be associated with all of these mechanisms.

### Metabolism

Metabolism and toxicokinetic studies show considerable interspecies variation, which may account for differences in carcinogenicity and tissue endpoints reported in the mouse, rat, and human. Oxidative and reductive dechlorination of pentachlorophenol leading to potentially reactive metabolites, tetrachlorohydroquinones and semiquinones, followed by glucuronidation/sulfation is the primary metabolic pathway in rodents. These metabolites and/or glucuronidated forms have been detected in the serum and urine of rodents. Differences in liver tumor formation in the mouse (liver tumors) vs. the rat (no liver tumors) are likely due to differences in disposition and metabolism. Evidence from comparative metabolism studies in rodents supports this theory. Greater amounts of oxidative and direct DNA liver damage occurred in the mouse than in the rat with pentachlorophenol exposure (Lin et al. 2002). Limited information is available on metabolism in humans; primarily free and glucuronide-conjugated pentachlorophenol has been detected in urine when pure pentachlorophenol was administered orally to human volunteers, but there was no evidence of tetrachlorohydroquinone or tetrachlorophenol in urine (Braun et al. 1979; Uhl et al. 1986). However, tetrachlorohydroquinone has been identified in the urine of exposed workers (Ahlborg et al. 1974). Other studies have shown that human liver microsomes or yeast transformed with human cytochrome P450 3A4 can metabolize pentachlorophenol to tetrachlorohydroquinone (Juhl et al. 1985; Mehmood et al. 1996) and pentachlorophenol glucuronide in vitro (Lilienblum 1985).

### Metabolites and Genotoxicity

Pentachlorophenol genotoxicity is most likely mediated by its metabolites, primarily tetrachlorohydroquinone and tetrachlorobenzoquinone. The tetrachlorohydroquinone and tetrachlorobenzoquinone metabolites of pentachlorophenol were positive for DNA damage and DNA adducts, and tetrachlorohydroquinone was positive for mutations. These metabolites can form free radicals and through redox cycling generate reactive oxygen species. Metabolism can occur in the liver and also in extrahepatic sites. Activation of pentachlorophenol by peroxidase or myeloperoxidase activity in lymphocytes and in bone marrow presents a plausible mechanism for cancers of white blood cells such as NHL, lymphomas, and multiple myelomas. Peroxidases can metabolize pentachlorophenol to phenoxyl free radicals, preferentially forming O-bonded C8-dG DNA adducts at these sites resulting in DNA damage. This hypothesis is supported by the genotoxicity profile of pentachlorophenol. Pentachlorophenol caused adducts, mutations, DNA damage, and chromosomal aberrations in experimental conditions with metabolic activation (e.g., presence of exogenous or endogenous metabolic enzymes). Pentachlorophenol was not mutagenic or genotoxic without metabolic activation in most of the standard in vitro assays. DNA adducts were found in primary cells exposed to pentachlorophenol and in the livers of rats and mice exposed to pentachlorophenol; the predominant adduct was the oxygen-bonded C8-dG adduct. These results are supported by evidence of DNA strand breaks with human primary and cancer cell lines exposed to pentachlorophenol. There was evidence that pentachlorophenol caused DNA damage (strand breaks) as measured by the comet assay in several human cancer cell lines and fibroblasts (Stang and Witte 2010), lymphocytes (Michałowicz and Majsterek 2010; Stang and Witte 2010), and nasal mucosal cells (Tisch et al. 2005) with the addition of metabolic activation.

Karyotypic instability in the form of chromosomal breaks and translocations are found in NHL, multiple myeloma, and soft tissue sarcoma. There is limited evidence of an increase in acentric and dicentric chromosomal aberrations indicating chromosomal breakage in peripheral lymphocytes of workers exposed to pentachlorophenol (Bauchinger et al. 1982).

### Immunosuppression

NHL is associated with immunosuppressive conditions (Filipovich et al. 1980; Hardell and Axelson 1998), and pentachlorophenol exposure specifically has been associated with cellular and humoral immunodeficiencies in humans (Daniel et al. 2001b). Some studies in rodents indicate that the dioxin by-products (particularly the hexa- and hepta-substituted congeners) in the technical grade formulations are responsible for suppression of humoral immunity (Kerkvliet et al. 1985b)and 2,3,7,8-TCDD itself has been associated with an increased risk of NHL in humans (IARC 2012).

### Inhibition of Apoptosis

Pentachlorophenol is an inhibitor of apoptosis, which may lead to accumulation of malignant cells. Inhibition of apoptosis also has been associated with tumor promotion, and interference with intercellular communication through gap junctions has been linked to the apoptotic process. In addition, several studies suggest that pentachlorophenol is also a non-mutagenic liver tumor promoter in mice, inhibits enzymes involved in metabolism, inhibits gap junction intercellular communication, and inhibits apoptosis.

## 6.4 NTP Listing Recommendation

The complex mixture, pentachlorophenol and by-products of its synthesis, is reasonably anticipated to be a human carcinogen based on limited evidence from studies in humans showing that a causal relationship between exposure to pentachlorophenol and NHL is credible, but alternative explanations, such as chance, bias, and confounding, cannot be adequately ruled out. This conclusion is supported by sufficient evidence in experimental animals and supporting mechanistic evidence.