# 5 Mechanistic Data and Other Relevant Effects

This section reviews data related to identifying and evaluating putative mechanisms for the potential carcinogenicity of pentachlorophenol and by-products of its synthesis including genetic and related effects and mechanistic considerations. The primary purpose is to identify potential mechanisms of action of carcinogenicity, review the strength of evidence for potential mechanisms, and discuss any key issues that address the relevance of carcinogenic effects observed in experimental animals to effects in humans.

## 5.1 Genetic and Related Effects

Pentachlorophenol has been tested in several short-term assays to evaluate mutagenicity and other potential genotoxic effects. The data presented here comes from primary peer-reviewed papers as well as from review articles (IARC 1999; Seiler 1991; USEPA 2010). Chemical purity is included if indicated by the authors; however, often only the source of purchase was indicated with no mention of purity, so the material tested is at least assumed to be technical grade or better.

In vitro studies include assays for mutagenicity and DNA damage in bacteria (Section 5.1.1) and assessments of several types of cytogenetic effects in non-mammalian eukaryotes (Section 5.1.2) and cultured mammalian cells (Section 5.1.3). Pentachlorophenol-induced oxidative DNA damage and DNA and protein adduct formation are discussed in Section 5.1.4. In vivo studies include evaluations of cytogenetic effects in rodents (Section 5.1.5) and in workers occupationally exposed to pentachlorophenol (Section 5.1.6). Studies on the genotoxicity of some pentachlorophenol metabolites are described in Section 5.1.7. An overall assessment of the genotoxicity of pentachlorophenol is presented in the final section (Section 5.1.8). Summary tables of genotoxicity studies on pentachlorophenol and its metabolites are given in Table 5-1 and Table 5-2, respectively. The data for all of the genotoxicity studies discussed in Section 5.1 are provided in Appendix E.

Table 5-1 Summary of Pentachlorophenol Genotoxicity Information

Effect | In Vitro | | In Vivo
Effect | −S9 | +S9 | Rodents | Humans
Mutation Bacteria Yeast Drosophila Mammalian cells | − + − − | ±^a^ | +
DNA damage Bacteria Yeast Drosophila Mammalian cells | ± + − ± | + +
Chlorophenol-DNA adducts | + | − | +
Chromosomal aberrations | ± | + | − | ±
Sister chromatid exchange | ± | − | + | −
Micronucleus induction | | | −

+ = Positive; (+) = weakly positive; ± = both positive and negative; − = negative studies.

^a^ Positive only in S. typhimurium TA98 with phenobarbital/benzoflavone-induced rat liver.

Table 5-2 Summary of Genotoxicity Data for Pentachlorophenol Metabolites^a^

Effect Metabolite | Result
Mutation Tetrachlorohydroquinone Tetrachlorocatechol | + −
DNA damage Tetrachlorohydroquinone Tetrachlorocatechol Tetrachlorobenzoquinones | +^b^ ±^c^ +^b^
DNA adducts Tetrachlorohydroquinone Tetrachlorobenzoquinones | +^d^ +

+ = Positive; − = negative; ± = both positive and negative study results were reported.

^a^ Unless noted otherwise, all studies were in vitro with no exogenous metabolic activation S9 added.

^b^ Positive in both rodent and human cells.

^c^ Positive in human peripheral lymphocytes; negative in hamster V79 cells.

^d^ Positive in both in vitro and in vivo studies.

### 5.1.1 In Vitro Studies in Bacteria

Pentachlorophenol induced mutation in bacteria only under specific conditions. It was reported to be mutagenic by one laboratory, but only in Salmonella typhimurium strain TA98, using the preincubation protocol, with the addition of phenobarbital/benzoflavone-induced rat liver metabolic activation S9 (Nishimura et al. 1982a; Nishimura and Oshima 1983). Although reported by Gopalaswamy and Nair (1992) as weakly mutagenic in an assay using Aroclor-induced rat S9, that study’s lack of control data and methodological issues limit its usefulness. All other available Salmonella mutation assays, i.e., a total of 15 combinations of tester strains (TA98 and all others), using plate incorporation and preincubation protocols, both with and without the addition of S9 metabolic activation (rat or hamster) reported in Appendix E, were negative (for details of studies, see Appendix E, Table E-1). It is unclear whether the type of S9 affects the mutagenicity of pentachlorophenol in bacterial mutation assays because a study designed to compare the effects of five different induced rat liver S9 activation mixtures on the mutagenic potential of pentachlorophenol in bacterial strain TA98 reported all tests as negative; however, that study did not include phenobarbital/benzoflavone-induced S9 (Markiewicz et al. 1996). A limitation of the Markiewicz et al. (1996) study, which used the plate incorporation protocol, was that no toxicity was reported for pentachlorophenol even at the highest dose tested (100 µg/plate), while the study that reported mutagenic activity in TA98 observed cytotoxicity at pentachlorophenol doses greater than 16 µg/plate. The only other study that reported cytotoxic effects due to pentachlorophenol treatment was Haworth et al. (1983)/ NTP (1999) which, for all four strains tested using the preincubation protocol, reported total toxicity at 30 µg/plate without S9 but no toxicity at the highest dose (30 µg/plate) tested in the presence of rat or hamster S9.

There is some indication that pentachlorophenol causes DNA damage in bacteria. DNA damage following exposure to pentachlorophenol was reported in Bacillus subtilis but not in Escherichia coli (polA-) (Ozaki et al. 2004; Waters et al. 1982). However, in a different approach to DNA damage assessment, induction of prophage λ, due to DNA strand breaks, was observed in E. coli both with and without the addition of rat liver S9 metabolic activation (DeMarini et al. 1990).

Results of mutagenicity and DNA damage in all bacteria studies are summarized in Appendix E, Table E-1.

### 5.1.2 In Vitro Studies in Non-mammalian Eukaryotes

Studies in yeast have shown that exposure to pentachlorophenol induces both mutations and DNA damage. Mutations were induced in Saccharomyces cerevisiae MP-1 cultures (Fahrig et al. 1978), and DNA damage was reported in three different strains of S. cerevisiae: D4 (both ade2 and trp5), MP-1 (trp5), and D3 (Fahrig 1974; Fahrig et al. 1978; IARC 1999; Waters et al. 1982). Although the studies assessing mutation and DNA damage were each limited to one treatment dose, the consistency of results across studies supports the ability of pentachlorophenol to induce these effects in yeast.

Pentachlorophenol-induced genotoxicity has been reported in non-mammalian eukaryotes. Effects include induction of DNA damage and micronucleus induction in mussels and snails (Pavlica et al. 2001; Pavlica et al. 2000). In addition, in the onion Allium sp., increases in chromosomal aberrations and micronuclei were observed following exposure to pentachlorophenol (Ateeq et al. 2002; Pavlica et al. 1998; Repetto et al. 2001). In contrast to these positive results, no induction of sex-linked recessive lethal mutations or aneuploidy was observed in germ cells of the fruit fly Drosophila melanogaster following exposure of adult males to pentachlorophenol in feed (Ramel and Magnusson 1979; Vogel and Chandler 1974). The small number of chromosomes counted in three broods (around 600 each) by Vogel and Chandler (1974) limits the utility of that study, but similar results were reported by Ramel and Magnusson, who evaluated 73,000 flies treated with 400-ppm pentachlorophenol and found no non-disjunction or sex chromosome loss in the germ cells of treated Drosophila males (see Appendix E, Table E-2).

Pentachlorophenol was also reported to induce point mutations in zebrafish (Yin et al. 2006).

### 5.1.3 In Vitro Studies in Mammalian Cells

There is evidence that exposure to pentachlorophenol in vitro induces DNA damage in cultured rodent and human cells, but it did not induce mutations in mammalian cells (see Appendix E, Table E-3). In several studies using the comet assay, pentachlorophenol induced statistically significant increases in DNA damage in cells with endogenous metabolic capability, e.g., peripheral blood lymphocytes, Hep-G2, and epithelial (mucosal) nasal conchae (Michałowicz 2010; Michałowicz and Majsterek 2010; Stang and Witte 2010; Tisch et al. 2005) and in metabolically incompetent cultured cells in the presence of exogenous metabolic activation, e.g., human fibroblasts, HeLa cells, and V79 cells (Stang and Witte 2010). A weak positive result for DNA damage was observed in a precipitation assay in mouse C3H10T1/2 embryonic fibroblast cells in the presence of phenobarbital/ hydrocortisone-induced metabolic activation S9; no DNA damage was observed in this assay in the absence of S9 (Wang and Lin 1995). Pentachlorophenol induced DNA damage in the one study that tested Chinese hamster lung (V79) cells in the presence of S9, but was negative in all studies that tested the cells without S9; results were negative in Chinese hamster ovary (CHO) cells in the absence of S9, but were not tested in the presence of S9 (Dahlhaus et al. 1996; Ehrlich 1990; Stang and Witte 2010).

Mutagenicity assays in V79 cells reported negative results with pentachlorophenol, but treatments were only performed in the absence of S9 metabolic activation (Jansson and Jansson 1986). Another study reported negative results when using a hepatocyte-mediated assay (not S9), but the information available was limited to that provided in a review paper (Hattula and Knuutinen (1985) cited by IARC (1999)).

In considering the implications of the results from genotoxicity assays, it is important to consider the metabolic capability of the cells tested. In contrast to primary cell cultures, most secondary cell lines (e.g., V79) have greatly reduced or absent endogenous metabolic capability, so assays performed without adding S9 generally only identify direct-acting genotoxicants.

There is some evidence of induction of chromosomal damage and apoptosis in mammalian cells treated with pentachlorophenol in vitro. Induction of chromosomal aberrations was reported in V79 cells, both with and without the addition of mouse-derived S9, but only at the highest dose tested (Ishidate 1988). A small but statistically significant (pairwise for high dose as well as for trend test) induction of chromosomal aberrations was also observed in CHO cells in the presence of S9, but results were negative without S9 (Galloway et al. 1987; NTP 1999). No induction of chromosomal aberrations was observed in cultured human lymphocytes in the absence of S9; the assay was not conducted with S9. Weak induction of sister chromatid exchanges SCE was observed in CHO cells (significant at 3 µg/mL, p < 0.05), but not in human lymphocytes, treated with pentachlorophenol in the absence of S9 activation; no induction of SCE was observed in CHO cells in the presence of S9 at concentrations up to 100 µg/mL pentachlorophenol and the lymphocyte treatments were not conducted with S9 (Galloway et al. 1987; NTP 1999; Ziemsen et al. 1987). Apoptosis was observed in two studies in which human lymphocytes and human Jurkat T cells were exposed to pentachlorophenol in culture (Michałowicz and Sicińska 2009; Wispriyono et al. 2002).

### 5.1.4 Oxidative DNA Damage and DNA and Protein Adducts

Exposure to pentachlorophenol can result in oxidative DNA damage and formation of DNA adducts both in vitro and in vivo (see Appendix E, Table E-4 and Table E-5). Adducts were formed in vitro in studies using calf thymus DNA, fetal quail and rat hepatocytes, and human hepatoma (HepG2) cells (Dubois et al. 1997; van Ommen et al. 1986a). DNA or nucleoside adducts were induced in calf thymus DNA following co-administration of pentachlorophenol and horseradish peroxidase or myeloperoxidase (from human lymphocytes) or when tested with an excess of deoxyguanosine (dG); formation of adducts was specific to dG as no adducts were detected with deoxyadenosine, deoxycytidine, or thymidine (Dai et al. 2005; Dai et al. 2003). Several in vivo studies reported that oxidative DNA (8-OH-dG) adducts were formed in the livers in mice and rats exposed to pentachlorophenol by gavage or in their food (Lin et al. 2002; Sai-Kato et al. 1995a; Tasaki et al. 2013; Umemura et al. 1999; Umemura et al. 1996). Protein adducts were reported in vitro (binding to microsomal protein from induced rats) as well as in vivo in liver nuclei and cytosol in rats and mice treated by gavage (Tsai et al. 2002; van Ommen et al. 1986a).

Studies of DNA adduct formation have been used to identify specific chemical structures that result after pentachlorophenol exposure and to construct potential chemical pathways in the formation of reactive intermediates (Dai et al. 2005; Dai et al. 2003). For example, it has been shown that peroxidase-treated pentachlorophenol reacts with deoxyguanosine (dG) to yield the C8-dG oxygen (O) adduct, suggesting an intermediate radical for covalent bond formation (Figure 5-1).

Figure 5-1

Scheme of Pentachlorophenol Adduct Formation: Reactivity of Phenoxyl Radical toward dG (Modified from Dai et al. (2005); Dai et al. (2003))

### 5.1.5 In Vivo Studies in Rodents

There is limited evidence of genetic effects resulting from in vivo pentachlorophenol exposure in rodents. In the available studies, increases in response were reported for mRNA level changes, unscheduled DNA (UDS) repair, and sister chromatid exchange (SCE) (see Appendix E, Table E-6). In C57BL/6 mice (p53^+/+^) treated with pentachlorophenol in the diet, there was a significant decrease in CYP2B10 levels, but a significant increase in NQ01 mRNA levels. In the knockout mouse (p53^-/-^), pentachlorophenol caused a non-significant increase in CYP2B10 levels and a significant increase in NQ01 mRNA levels (Tasaki et al. 2013). Taken together, these results suggest that the chemical affects gene expression. A significant increase in unscheduled DNA repair was observed in hepatocytes of rats given one intraperitoneal (i.p.) injection of pentachlorophenol, although the results should be interpreted with caution since the study was limited to a single dose (10 mg/kg) administered in just two rats (sex not reported) (Monteith 1992). A significant induction of SCEs in male rat hepatocytes was reported following i.p. injection (10 mg/kg) of pentachlorophenol. In the same study, there was no increase in chromosomal aberrations in the hepatocytes of male rats treated with 10 mg/kg pentachlorophenol i.p. for five days; however, the study was limited by the use of only one dose and treatment regimen (Daimon et al. 1997). From the described studies in rodents, the observations of DNA damage and repair (SCEs and UDS), decreased CYP2B10, and increased MNQ01 mRNA and UDS levels, support an assertion of in vivo effects due to pentachlorophenol treatment.

Pentachlorophenol induced DNA damage, measured as increased levels of 8-oxodeoxyguanosine (8-OH-dG), in the liver, but not the kidney or spleen, of exposed mice and rats, indicating formation of reactive oxygen intermediates in the liver (Lin et al. 2002; Sai-Kato et al. 1995a; Umemura et al. 1999; Umemura et al. 1996). In the Sai-Kato et al. (1995a) study, when pentachlorophenol treatment in mice was preceded by administration of antioxidants (vitamin E and diallyl sulfide), liver 8-OH-dG levels were greatly reduced compared with the levels seen in the mice that received pentachlorophenol alone, suggesting protection against oxidative damage induced by pentachlorophenol. In addition, pentachlorophenol-treated animals had a dose-dependent increase in hepatocellular proliferation, an event that has been associated with carcinogenesis.

A weak positive response was noted in the mouse spot test, an assay used to detect genetic alterations, especially point mutations, in somatic cells. Exposure to pentachlorophenol resulted in the appearance of colored spots, caused by gene mutation or recombination, as well as reduction in litter size and loss of offspring before or after birth. No increases in the frequencies of micronucleated polychromatic erythrocytes (reticulocytes) were observed in the bone marrow of male and female CD-1 mice administered pentachlorophenol by gavage up to 120 mg/kg (Xu (1996), as cited in USEPA (2010)) or male B6C3F_1_ mice treated i.p. with up to 100 mg/kg (NTP 1999). Furthermore, no increases in micronucleated polychromatic erythrocytes were seen in male F344/N rats administered up to 50 mg/kg pentachlorophenol i.p. once daily for 3 days (NTP 1999).

### 5.1.6 Studies in Lymphocytes from Occupationally Exposed Workers

Three studies were identified that measured endpoints of genotoxicity in people occupationally exposed to pentachlorophenol, including one study of workers employed in a pentachlorophenol production factory (Bauchinger et al. 1982) and two studies of workers who used pentachlorophenol to treat wood (Wyllie et al. 1975; Ziemsen et al. 1987) (see Appendix E, Table E-7 and Table E-8). Based on measurements of pentachlorophenol in the workplace air and in the blood and urine of the study subjects, workers in the production factory had the highest exposure to the chemical. All three studies were limited to small numbers of subjects, particularly the Wyllie et al. (1975) study, which evaluated only six exposed workers. In all three studies, chromosomal aberrations (CA) were measured in the workers’ peripheral blood lymphocytes; Bauchinger et al. (1982) and Ziemsen et al. (1987) also measured sister chromatid exchanges (SCE). Results of the Bauchinger et al. (1982) study provide evidence that pentachlorophenol induces chromosomal damage in humans, based on observations of statistically significant increases in dicentric chromosomes and acentric fragments in lymphocytes of the exposed workers in the pentachlorophenol-producing factory; the numbers of chromatid-type aberrations (breaks, and exchanges) were also increased over controls, but not with statistical significance. In the wood treatment workers, Wyllie et al. (1975) reported an increase (though not statistically significant) in the percentage of cells with chromosome breaks but, due to the small number of subjects, this study had limited power to detect a definitive effect. No effects were noted in the second wood-treatment plant study (Ziemsen et al. 1987), but exposure levels were much lower (based on serum levels) in that study; data on types of chromosomal damage in workers were reported but the actual number of cells with aberrations (the definitive value for measuring CA) were not, so the percentage of cells with CAs cannot be accurately calculated. No effects on SCE frequencies were reported for pentachlorophenol-exposed workers (Ziemsen et al. 1987). Although the initial statistical analysis for SCEs in the Bauchinger et al. (1982) study showed that exposed production workers had significantly higher values compared with controls, a reanalysis of the data comparing the 22 exposed workers (all smokers) to control group smokers only (9 out of 22) showed no differences in SCE frequencies between the two groups, suggesting that the effect on SCEs was attributable to smoking rather than exposure to pentachlorophenol. However, the exposure-related chromosomal damage in that study was not related to smoking status, as a comparison of the exposed workers (all smokers) with smoking controls showed statistically significant increases in dicentric chromosomes and acentric fragments in lymphocytes of the pentachlorophenol-exposed workers.

### 5.1.7 Genotoxic Effects of Metabolites of Pentachlorophenol

The genotoxicity of several pentachlorophenol metabolites, including tetrachlorohydroquinone, tetrachlorocatechol, tetrachloro-1,4-benzoquinone, and tetrachloro-1,2-benzoquinone has been evaluated in several in vitro studies. A summary table of the results from these studies is provided in Appendix E, Table E-9.

A major pentachlorophenol metabolite, tetrachlorohydroquinone, induced mutations in Chinese hamster lung (V79) cells at the HPRT locus (6-thioguanine resistance) but not at the Na/K-ATPase locus (measured as ouabain resistance) (Jansson and Jansson 1991; Purschke et al. 2002). These results suggest that tetrachlorohydroquinone can cause genetic damage in the form of deletions, which may result in the loss of the HPRT enzyme function and produce a positive result in that assay. Since Na/K-ATPase is necessary for cell viability, ouabain resistance cannot arise from the loss of enzyme function and thus the results would be negative (if enzyme function is unaffected), as reported.

Tetrachlorohydroquinone was also shown to induce single-strand DNA breaks in mammalian (including human) cells in vitro as well as DNA adducts in calf thymus DNA; all of the tests were performed without the addition of exogenous metabolic activation. Ehrlich (1990) reported that, while the parent compound pentachlorophenol did not induce DNA single-strand breaks in CHO cells, the metabolite tetrachlorohydroquinone did so in a dose-dependent manner. Furthermore, tetrachlorohydroquinone induced DNA adducts in human HeLa S3 tumor cells; classes of adducts included both oxidative adducts (8-OH-dG) and adducts induced at apurinic/apyrimidinic sites. In an in vivo study, DNA adducts were induced in the liver of mice exposed to tetrachlorohydroquinone in the diet, but not when treated by i.p. injection (Dahlhaus et al. 1994).

Significant increases in micronucleated V79 cells were reported following treatment with tetrachlorohydroquinone in a study designed to investigate a possible mechanism of action (Jansson and Jansson 1992). When the V79 cells were also treated with DMSO, a hydroxyl radical scavenger, a significant inhibitory effect was observed on the frequency of micronucleated cells induced by tetrachlorohydroquinone. Treatment of cells with ethyl methanesulfonate, a potent alkylating agent, induced micronuclei (levels were similar to those induced by tetrachlorohydroquinone), but the addition of DMSO to the cell cultures resulted in no change, supporting the role of hydroxyl radicals in the tetrachlorohydroquinone-induced chromosomal damage (Jansson and Jansson 1992).

Two other metabolites of pentachlorophenol, tetrachloro-1,4-benzoquinone and tetrachloro-1,2-benzoquinone, induced DNA damage in vitro in human fibroblasts (comet assay) and V79 cells (alkaline elution assay) (Dahlhaus et al. 1996; Purschke et al. 2002). The metabolite tetrachlorocatechol induced DNA damage, as measured by the comet assay, in cultured human peripheral blood lymphocytes (Michałowicz and Majsterek 2010) Tetrachlorocatechol was reported to be negative in tests for DNA damage and mutagenicity in V79 cells, although it was only tested in the absence of metabolic activation (Dahlhaus et al. 1996; Jansson and Jansson 1991).

### 5.1.8 Synthesis of Results

The available in vitro studies report that pentachlorophenol induces genotoxic effects in a variety of test systems. It was mutagenic (possibly via its metabolites) in studies in yeast and zebrafish, but in bacteria it induced mutations only in the presence of exogenous metabolic activation (S9), and in most bacterial studies it was nonmutagenic, with or without S9. Pentachlorophenol induced DNA damage in yeast, invertebrates, and plants as well as in human lymphocytes and nasal concha cells, without the addition of S9. In the only rodent assay in which DNA damage was investigated in the presence of S9, pentachlorophenol was weakly positive; it gave negative results in all in vitro rodent cell studies conducted without S9. Three studies evaluated chromosomal aberrations (CAs) in mammalian cells and each reported positive results in the presence of S9; one study also reported induction of CAs by pentachlorophenol without S9. Induction of sister chromatid exchanges (SCE) by pentachlorophenol was tested in two studies; it was judged to be weakly positive in one study without the addition of S9, but negative in the only study that tested in the presence of S9.

In vivo, pentachlorophenol induced SCEs in rat hepatocytes and gave a weak positive result in the mouse spot test, but negative results were obtained in all rodent tests for micronucleus or chromosomal aberration induction. In contrast with the rodent findings, a study in peripheral blood lymphocytes from workers exposed to pentachlorophenol showed some evidence of chromosomal damage, although results were based on a small number of workers. DNA adducts were induced in the liver of both rats and mice exposed to pentachlorophenol, apparently due to formation of reactive oxygen species; increased hepatocellular proliferation in these animals may also be related to carcinogenicity.

The body of evidence indicates that pentachlorophenol causes oxidative DNA damage, based on findings in cultured cells with endogenous or exogenous metabolic activation as well as in animals. Pentachlorophenol metabolites cause DNA damage (including oxidative damage) and mutation, in cultured cells or exposed animals. Overall, this suggests that the metabolism of pentachlorophenol, whether by endogenous or exogenous enzymes, results in the production of reactive metabolites that could play a role in the mechanism of carcinogenesis.

## 5.2 Mechanistic Considerations

Carcinogenesis is a complex disease process with an extensive list of possible mechanisms; however, most can be grouped into a limited number of categories (Guyton et al. 2009). Chemicals may be categorized according to their “mode of action” represented by the key events associated with the toxic effect. These events may include, but are not limited to, DNA reactivity (covalent binding), gene mutation, chromosomal breakage, aneuploidy, enzyme-mediated effects on DNA damage or repair, epigenetic effects, altered or disrupted cell signaling, immune response modulation, inflammation, cytotoxicity, and compensatory cell proliferation, mitogenicity, chronic metabolic or physiologic overload, nutrient deficiency, and interference with intercellular communication. It is important to recognize that chemicals can act through multiple toxicity pathways and mechanisms to induce cancer or other health effects, and the relative importance of the various pathways may vary with life stage, genetic background, and dose. Thus, it is unlikely that for any chemical a single mechanism or mode of action will fully explain the multiple biological alterations and toxicity pathways that can cause normal cells to transform and ultimately form a tumor.

Pentachlorophenol exposure was associated with liver and adrenal gland tumors in male and female B6C3F_1_ mice, malignant vascular tumors (hemangiosarcoma) in female mice, benign skin tumors (papillomas) in mice, mesothelioma and nasal tumors in male F344 rats, and liver tumors in female Wistar rats (see Section 4). In humans, there is evidence that pentachlorophenol exposure may be associated with non-Hodgkin lymphoma, multiple myeloma, and soft tissue sarcoma (see Section 3). The mechanisms responsible for the carcinogenic effects of pentachlorophenol are complex and poorly understood. Although the available data indicate that multiple mechanisms are involved, none have been defined sufficiently to identify key events or temporal relationships (USEPA 2010). A further complication is the presence of various by-products of its synthesis in technical grade and most other formulations (see Section 1). The by-products include several carcinogenic chemicals including other chlorophenols, dibenzo-p-dioxins, and dibenzofurans. Numerous studies suggest that metabolism to genotoxic metabolites, oxidative damage and inflammation, induction of stress genes, cytotoxicity, immunosuppression, and interference with gap junctional intercellular communication and apoptosis are likely involved (Dorsey et al. 2006; Dorsey et al. 2002; Dorsey et al. 2004; Goodman 2001; Mirvish et al. 1991; Sai et al. 2001; Sai et al. 2000; Zhu and Shan 2009). Section 5.2.1 compares carcinogenic effects in experimental animals exposed to analytical grade or technical grade pentachlorophenol to determine if the various carcinogenic effects can be attributed to pentachlorophenol, its by-products, or a combination of the two. Sections 5.2.2 to 5.2.6 discuss the possible modes of action for the reported carcinogenic effects including lymphoma/hematopoietic neoplasms in humans, liver and vascular tumors in mice, mesothelioma in rats, and skin tumors in mice. No mechanistic data were identified for adrenal gland tumors in mice, nasal tumors in rats, or soft tissue sarcoma and kidney cancer in humans; however, the identified genotoxic and nongenotoxic mechanisms likely contribute to the neoplastic effects in those tissues.

### 5.2.1 Relative Contribution of Pentachlorophenol and Its By-products to Liver Tumors

Conclusions reached from cancer studies in experimental animals are from different grades of pentachlorophenol containing different amounts of by-products. A comparison of available cancer studies from individual by-products will aid in elucidation of possible mechanisms of carcinogenicity. Some of these by-products are dioxins and furans that have been assigned dioxin-like equivalency factors (TEFs), which rank biological potencies relative to 2,3,7,8-tetrachlorodibenzo-p-dioxin.

For some of the by-products, cancer studies were available and most of the studies had liver tumors in mice as a common endpoint for comparison across studies. To inform an assessment of experimental animal cancer data, this discussion will focus primarily on pentachlorophenol cancer studies in mice (NTP 1989) using technical grade pentachlorophenol and Dowicide EC-7 with specific emphasis on mouse liver tumors. Studies chosen for comparison were of high quality (chemicals assessed for purity, adequate number of animals on study, adequate duration of observation period, and comprehensive histopathologic evaluation of tissues).

Cancer studies of pentachlorophenol exposure in rats and mice were presented and discussed in Section 4 and included studies with different grades of pentachlorophenol: pure pentachlorophenol (99%), Dowicide EC-7 (90%), and technical grade pentachlorophenol (86%). The NTP conducted two feeding studies in mice using different pentachlorophenol preparations—(1) Dowicide EC-7 and (2) technical grade pentachlorophenol— and one dermal study in transgenic mice using 99% pentachlorophenol (Section 4, Table 4-3, Table 4-4, Table 4-5, Table 4-6, and Table 4-7). Based on the chemical analyses in the NTP reports, the by-products present in these test articles include polychlorophenols, hexachlorobenzene (HCB), dioxins and furans, and hydroxydiphenyl ethers (Table F-1). Unless specifically noted, individual chemical isomers were not identified and 2,3,7,8-tetrachlorodibenzo-p-dioxin (TCDD) was not identified in these preparations of pentachlorophenol. However, other dioxin and furan by-products are present. Total dioxin-like equivalents (Van den Berg et al. 2006) were calculated and these values compared with induction of liver tumors by TCDD (NTP 1982). A number of assumptions are made in these comparisons: it is assumed that exposure in gavage studies is similar to exposure in diet, and it is assumed that toxicity of isomers in studies under comparison is similar. Available cancer studies in experimental animals of by-products present in the grades of pentachlorophenol tested were: trichlorophenol, hexachlorobenzene (HCB), hexachlorodibenzo-p-dioxin (HxCDD) and TCDD; no cancer studies were located on tetrachlorophenol. These studies are compared with the results for liver tumors in mice (NTP 1989). No liver tumors were identified in the dietary study in rats with pure pentachlorophenol (NTP 1999); however, hepatic nodules were noted in rats in a feed study using technical grade pentachlorophenol (Mirvish et al. 1991) with TCDD/TCDF contamination. The results in rats are discussed in the next section.

#### Trichlorophenol (2,4,6-TCP)

Trichlorophenol concentrations in the bulk pentachlorophenol chemical preparations were similar between the technical grade (0.01%) and the Dowicide EC-7 (0.007%) (Table F-1) and were much lower than the 5,000-ppm concentration in feed that produced liver tumors in both sexes of mice in the bioassay of 2,4,5-trichlorophenol (NCI 1979) (Table F-2). Therefore, trichlorophenol would not be expected to contribute to tumorigenicity of the pentachlorophenol preparations.

#### Hexachlorobenzene (HCB)

Liver tumors in mice were reported in the HCB cancer studies of Cabral et al. (1977) and are summarized in Table F-3. In comparing the data on liver tumors in Section 4, Table 4-3 to the data on HCB alone, HCB could not independently account for the liver tumors in mice because HCB was present in greater amounts with Dowicide EC-7 (65 ppm of HCB), which had fewer liver tumors than technical grade pentachlorophenol (50 ppm of HCB) at the same exposure concentration in feed. In addition, HCB would be present in the mixture at lower concentrations than those that induced liver tumors. In the Cabral et al. (1979) study using Swiss male mice, the lowest concentration of HCB that increased liver neoplasms was 100 ppm; whereas, the 50-ppm group did not. The 200-ppm group also had liver neoplasms but had poor survival due to toxicity. In the technical grade pentachlorophenol, HCB is present at 50 ppm (Table F-1). In a 200-ppm technical grade formulation, HCB would be present at 0.01 ppm, or 1000-fold lower than the dose that induced liver tumors in the male Swiss mice. Therefore, it is unlikely the HCB contributed directly to liver tumor formation in the pentachlorophenol preparations.

#### Dioxin-like By-products and Cancer Promotion

Available data indicate that carcinogenic potency as well as toxicity of dioxin and dioxin-like chemicals are proportional to affinity for the cytoplasmic aryl hydrocarbon receptor (AhR), a cytoplasmic transcription factor that has been characterized in humans and in rodents. This receptor is conserved in vertebrate animals and has equivalent functions in humans and in experimental animals. Evidence suggests that carcinogenicity of dioxins and furans acts through similar mechanisms and requires initial binding to the AhR. Binding, nuclear translocation, coupling with aryl hydrocarbon nuclear translocator (ARNT) forming a AhR/ARNT heterodimer leads to activation of TCDD-responsive genes, some of which have a global effect on cell-cycle regulation, cell growth, apoptosis, immune surveillance, metabolism, and disruption of hormone and growth factor signal transduction pathways. All of these factors have a role in the promotion of cancer. AhR-mediated induction of CYP1A1 and CYP1A2 genes occurs with similar potencies in human and rodent cells, but the role of induction of these genes in carcinogenesis is unclear. No specific gene has been shown to have a definitive role in the mechanism of carcinogenesis by dioxin. Experimental data indicate that 2,3,7,8-TCDD and probably other polychlorinated dioxins and furans are not direct-acting genotoxic agents and most likely act as tumor promoters through activation of the AhR and disruption of cellular homeostasis (Barouki et al. 2012; IARC 1997).

Dioxin by-products of pentachlorophenol synthesis are primarily a mixture of isomers of hexa-, hepta-, and octadibenzo-p-dioxins. These dioxin congeners have been shown to be long-lived in the body and provide a congener pattern for previous exposure to pentachlorophenol. Cancer studies of dioxin and dioxin-like chemicals have primarily focused on 2,3,7,8-TCDD and a limited amount of data are available on carcinogenicity of other congeners of dioxin.

According to the chemical analysis from the NTP studies, HxCDD is present at a low concentration of the bulk chemical in the technical grade preparation (10.1 ppm) and in the Dowicide EC-7 preparation (0.9 ppm) (Table F-1). NTP has tested two HxCDD isomers in rats and mice in a two-year bioassay. HxCDD (mixture of 1,2,3,6,7,8- and 1,2,3,7,8,9-HxCDD isomers) was tested by gavage in mice for carcinogenicity (NTP 1980b) (Table F-4), and the results for liver tumors were compared with the NTP studies of technical grade pentachlorophenol and Dowicide EC-7 in feed (McConnell et al. 1991; NTP 1989) (see Appendix F, Table F-5). Liver neoplasms were induced in the HxCDD gavage study as well as in the pentachlorophenol technical grade and Dowicide EC-7 feed studies in male mice. At equal doses of pentachlorophenol, a greater incidence of liver neoplasia occurred with technical grade pentachlorophenol than with Dowicide EC-7 and a liver tumor response occurred with HxCDD alone at greater concentrations than found in either of the pentachlorophenol preparations. Although there may be a cancer effect of the HxCDD, it does not account for the greater incidence of liver tumors observed with technical-grade pentachlorophenol or Dowicide EC-7 exposure.

While HxCDD is present in many of the pentachlorophenol formulations, it is not the only dioxin-like chemical present in pentachlorophenol formulations. Activation of aryl hydrocarbon receptor (AhR) can occur with a number of dioxin-like compounds and their relative potency with regard to toxicity and carcinogenicity in relation to TCDD has been determined (Van den Berg et al. (2006), Table F-6). Technical grade pentachlorophenol induced liver aryl hydrocarbon hydroxylase activity, a marker for the AhR-dependent enzyme, and CYP1A1 to a much greater extent (at least 10-fold greater in male mice) than did Dowicide EC-7 or pure pentachlorophenol in the 6-month subchronic feed study (NTP 1989). Liver tumor incidence was higher with technical grade pentachlorophenol than with Dowicide EC-7, a purer grade of pentachlorophenol (NTP 1989) (Table F-5). Given that AhR-dependent enzymes have been induced with technical grade pentachlorophenol, it is likely that there are multiple mechanisms involved in liver carcinogenesis following exposure to technical grade pentachlorophenol and that by-products of synthesis play an important role in the carcinogenicity of pentachlorophenol.

In order to further assess the role of the dioxin-like by-products in the carcinogenicity of the different pentachlorophenol products tested, dioxin-like equivalents (TEQs) were calculated for the NTP feed studies in mice for technical grade and Dowicide EC-7 and compared with available liver cancer bioassay data (NTP 1982) for TCDD. Dioxin-like equivalencies rank biological potencies of dioxin and furan isomers relative to 2,3,7,8-tetrachlorodibenzo-p-dioxin. Table F-7 and Table F-8 list dioxin equivalent calculations for the feed preparations for the high doses used in those studies. Calculations are based upon the ‘worst case’ scenario, i.e., high dose of technical grade pentachlorophenol at 200 ppm and Dowicide EC-7 at 600 ppm; and if ppm are reported as <10 or if 10 is the level of detection then 10 is used. Table F-9 and Table F-10 list doses of TCDD by gavage for hepatocellular carcinoma in mice (NTP 1982).

For technical grade pentachlorophenol at 100 and 200 ppm, TEQ concentrations are above 0.5 μg/kg/week, which when given as TCDD alone caused liver tumors. However, the TEQ of 200-ppm Dowicide EC-7 was less than the concentration of TCDD that induced liver tumors. Since exposure to Dowicide EC-7 resulted in increased liver tumors compared with controls, it would appear that pentachlorophenol, possibly in concert with other by-products, contributed directly to the liver tumor response. No 2-year dietary cancer studies were available using 99% pure pentachlorophenol in mice; however, a 6-month cancer study in Tg•AC mice (dermal application) was positive for papillomas and gave a positive effect of dose on tumor multiplicity, lending support to the hypothesis that pure pentachlorophenol has a role in the pathogenesis of cancer in the mouse. However, this model has been questioned as neoplasms can be induced by non-carcinogenic treatments, such as skin irritation and wounding (Fuhrman et al. 2005). It would also appear that dioxin-like components contributed as well since the less pure technical grade pentachlorophenol had more liver tumors at the same exposure concentration (200 ppm) than the Dowicide EC-7 that was of higher purity.

In summary, it can be concluded from the data in these studies that pentachlorophenol causes liver tumors in mice and that dioxin-like by-products also have an apparent contribution to liver tumor formation. Most likely, multiple mechanisms are involved in this complex mixture and the contribution of other by-products to tumor formation cannot be ruled out. Importantly, technical grade pentachlorophenol used in these studies has levels of by-products similar to those found in commercial use, and the TEQ value for dioxin-like by-products in technical grade pentachlorophenol is within the range of TCDD liver carcinogenicity.

#### TCDD/TCDF Contamination and Rat Liver Tumors

It is unusual for technical grade preparations of pentachlorophenol to have 2,3,7,8-TCDD (TCDD) as a by-product of its synthesis. However, 2,3,7,8-TCDD and 2,3,7,8-TCDF were tested for and found in a technical grade pentachlorophenol preparation from a U.S. supplier that was used in a rat cancer study (Mirvish et al. 1991) (see Section 4). No other chemicals related to pentachlorophenol synthesis that were analyzed for and detected by HPLC analysis in other studies contained 2,3,7,8-TCDD. MCR-Wistar rats, both sexes, were exposed to 500-ppm technical grade pentachlorophenol (86% pure technical grade pentachlorophenol with 25 μg/kg feed of 2,3,7,8-TCDD and 670 μg/kg feed of 2,3,7,8-tetrachlorodibenzofuran [TCDF]) for 88 weeks and compared with pooled control groups (pelleted and powered control feed groups, without pentachlorophenol). No liver tumors were reported in the control groups (males 0/9; females 0/18) and in the treated males (0/5), but a significant number of liver adenomas were noted in the female rats (6/9, p = 0.0003, one-sided Fisher’s exact test, calculated by NTP). Several points support TCDD/TCDF induction of liver tumors in female rats. (1) In two other chronic feed studies in rats using purified pentachlorophenol (99%) with no measurable dioxin or furans, no liver tumors were detected. (2) TCDD has been shown to induce liver tumors in female rats by gavage (0.5 μg/kg bw/wk) at less than the estimated dose of TCDD in the pentachlorophenol feed preparation. (3) In a timed gavage study of TCDD over 13-week intervals (NTP 1982), liver tumor latency for the appearance of adenomas was comparable to this study (approximately 88 weeks). (4) The TEF factor for TCDF was not taken into account by the study authors in assessing the contribution of TCDD. (5) Other possible dioxin and furan by-products were not investigated; TCDD is usually present with other chlorinated dioxins and dibenzofurans, increasing the total amount of dioxin-like equivalents in the feed. Based on other reports of TCDD in feed studies (Kociba et al. 1978) and by gavage (NTP 1982), it is concluded that the findings of liver tumors in female MCR-Wistar rats in the Mirvish et al. (1991) study can be attributed to dioxin-like activity and it is unlikely that pentachlorophenol induced these tumors.

### 5.2.2 Hematopoietic Neoplasms in Humans

Hematopoietic neoplasms have been associated with pentachlorophenol exposure in humans (see Section 3). Direct DNA adducts and immune suppression are possible mechanisms that have been linked to these malignancies; however, the dioxin by-products present in technical grade pentachlorophenol also suppress the immune system and have been associated with non-Hodgkin lymphoma. Thus, the dioxin by-products likely contribute to the carcinogenic effects of technical grade pentachlorophenol in humans.

Dai et al. (2005; 2003) demonstrated that incubation of pentachlorophenol with horseradish peroxidase or myeloperoxidase from human leukocytes in the presence of excess deoxyguanosine (dG) indicated that the oxygen-bonded C8-dG adduct (see Figure 5-1) was favored over the ortho and para C-adducts. The O-C8-dG adduct did not form when pentachlorophenol was incubated with rat liver microsomes. Prostaglandin H synthase and other peroxidases are known to be important in the metabolic activation of some xenobiotics to toxic or tumorigenic metabolites, particularly in extrahepatic tissues that contain low levels of cytochrome P450 (Eling et al. 1990). Further, the leukemogenic activity of benzene has been linked to peroxidase-catalyzed activation of its phenolic metabolite in bone marrow (Dai et al. 2005; Dai et al. 2003). Peroxidase is known to oxidize pentachlorophenol to phenoxyl radicals (Kazunga et al. 1999), and peroxidases and myeloperoxidases are present in bone marrow and leukocytes. Thus, this adduct could play a key role in pentachlorophenol-mediated hematopoietic malignancies (Dai et al. 2005; Dai et al. 2003).

Immune suppression and immune deficiency, as well as exposure to several immunosuppressive chemicals (e.g., PCBs, chlordane, dioxins, phenoxyacetic acids, organic solvents, chlorophenols, and immunosuppressive drugs) have been linked to an increased risk of non-Hodgkin lymphoma in humans (Filipovich et al. 1980; Hardell 2008; Hardell et al. 1998; Ziegler et al. 1984). The risk of non-Hodgkin lymphoma also increases with age (possibly due to an age-related decline in immune system response) (Hardell et al. 1998). Pentachlorophenol exposure has been associated with cellular and humoral immunodeficiencies in humans (Daniel et al. 1995; Daniel et al. 2001a; Daniel et al. 2001b; McConnachie and Zahalsky 1991). Several studies have demonstrated that pentachlorophenol decreased the tumor-cell killing function of human natural killer cells (Hurd et al. 2012; Nnodu and Whalen 2008; Reed et al. 2004; Taylor et al. 2005). Pentachlorophenol was one of the most effective compounds tested at decreasing natural killer-cell function.

The decreased lytic function was partially attributed to reduced tumor-cell-binding capacity and cell-surface marker expression but did not appear to be related to oxidative metabolism or generation of reactive oxygen species. Lang and Mueller-Ruchholtz (1991) investigated human lymphocyte reactivity after in vitro exposure to technical and analytical grade pentachlorophenol. Lymphokine production and immunoglobulin secretion from mitogen-stimulated cells showed significant dose-dependent suppression after exposure to both grades of pentachlorophenol. The T-helper cell subset was especially sensitive to pentachlorophenol; however, both T-independent and T-dependent humoral responses were markedly suppressed.

The only significant difference observed between analytical and technical grade pentachlorophenol was that following mitogen stimulation, T-lymphocyte blastogenesis was significantly reduced when exposed to the highest concentration (200 μM) of technical grade pentachlorophenol. Following optimal mitogen stimulation, lower doses of technical grade pentachlorophenol actually enhanced mitogen responses whereas higher doses suppressed them. Thus, pentachlorophenol itself was directly immunotoxic to human lymphocytes in vitro. However, some studies reported that technical grade but not analytical grade pentachlorophenol was immunosuppressive in mice (in vivo and in vitro) and that dioxin by-products (particularly some hexa- and hepta- congeners) in the technical grade formulation likely were responsible (Holsapple et al. 1987; Kerkvliet et al. 1982a; Kerkvliet et al. 1982b; Kerkvliet and Brauner 1987; Kerkvliet et al. 1985a; Kerkvliet et al. 1985b; White and Anderson 1985). Kerkvliet et al. (1982b) also reported that splenic tumors were increased when mice exposed to pure pentachlorophenol (low and high dose) were given a secondary challenge with Moloney sarcoma virus (MSV)-transfected sarcoma cells (MSB) and had successfully prevented the growth of the MSB tumor at the site of inoculation (the exact histologic origin of the splenic tumors was not determined).

Mirvish et al. (1991) also reported that technical grade pentachlorophenol acted synergistically with 2-hydroxyethylnitrosourea to induce acute myelocytic leukemia in rats. However, co-administration of methylprednisolone (an immunosuppressant), or Freund’s adjuvant (an immune system stimulant) with 2-hydroxyethylnitrosourea did not affect tumor incidence.

### 5.2.3 Hepatocellular Adenomas and Carcinomas in Mice

Experimental animal data show that pentachlorophenol induced liver tumors in B6C3F_1_ mice but not in Sprague-Dawley or F344 rats. The different responses may be explained by species differences in disposition and toxicokinetics. These differences may result in increased formation of reactive metabolites, DNA and protein adducts, and oxidative damage to DNA in mice compared with rats (Lin et al. 2002; Lin et al. 1997; Lin et al. 1999; Tsai et al. 2001). In addition, several studies suggest that pentachlorophenol is a non-mutagenic liver tumor promoter in mice, inhibits enzymes involved in metabolism, inhibits gap junctional intercellular communication, and inhibits apoptosis (Sai et al. 2001; Sai et al. 2000; Sai et al. 1998; Umemura et al. 2003a; Umemura et al. 1999).

#### Metabolic Activation and Adduct Formation

It is likely that differences in the metabolism of pentachlorophenol are at least partially responsible for the different tumor responses in mice and rats. Pentachlorophenol is not mutagenic or genotoxic itself but can form reactive metabolites that induce a variety of genotoxic effects including adduct formation, mutations, apurinic/apyrimidinic sites, single-strand breaks, and micronuclei (see Section 5.1). Although not completely understood, the most likely mechanism of pentachlorophenol’s genotoxicity involves oxidative dechlorination by liver microsomal cytochrome P450s to form tetrachlorohydroquinone and tetrachlorocatechol (Lin et al. 1997). These quinols can be further oxidized to form their corresponding quinones (tetrachloro-1,4-benzoquinone and tetrachloro-1,2-benzoquinone) via their semiquinone intermediates (see Figure 2-1). These metabolites are strong electrophiles and readily bind to macromolecules.

A series of in vitro and in vivo studies investigated the formation of these chlorinated quinone and semiquinone metabolites and protein adducts in the livers of male Sprague-Dawley rats, male F344 rats, and male B6C3F_1_ mice (Lin et al. 2002; Lin et al. 1997; Lin et al. 1999; Lin et al. 1996; Tsai et al. 2001; 2002). (Waidyanatha et al. 1996; Waidyanatha et al. 1994) also reported dose-related production of quinone and semiquinone adducts in blood proteins (hemoglobin and albumin) in male Sprague-Dawley rats administered pentachlorophenol by gavage. The estimated tissue doses of benzoquinones to liver cytosolic and nuclear proteins in rats and mice are shown in Table 5-3. Estimated daily adduct production rates are shown in Table 5-4. The principal findings from these studies support the role of benzoquinone adducts in mouse liver neoplasms and are as follows:

Table 5-3 Estimated Tissue Doses of Tetrachlorobenzoquinone-derived Electrophiles in Rats and Mice Following a Single Oral Dose of 20 mg/kg Pentachlorophenol

Electrophile | Dose (nM hr ± SE)
Electrophile | Liver Cytosolic Proteins | | Liver Nuclear Proteins
Electrophile | Sprague-Dawley Rat | B6C3F_1_ Mice | Sprague-Dawley Rat | B6C3F_1_ Mice
Cl_4_-1,4-BQ ^a^ | 416 ± 156* | 117 ± 17 | 1.82 ± 0.55 | 4.94 ± 0.51*
Cl_4_-1,2-BQ | nd | 24.2 ± 8.15* | nd | 3.24 ± 0.46*
Total | 416 ± 156* | 141 ± 18.9 | 1.82 ± 0.55 | 8.18 ± 0.68*

* p < 0.05 (significant increase compared with the other species).

Source: Lin et al. (1997).

Cl_4_-1,2-BQ = tetrachloro-1,2-benzoquinone; Cl_4_-1,4-BQ = tetrachloro-1,4-benzoquinone; nd = not detected.

^a^ Includes all monosubstituted and multisubstituted Cl_4_-1,4-BQ-derived quinones.

Table 5-4 Estimated Daily Production of Quinone Adducts Per Unit Dose of Pentachlorophenol in Rats and Mice

Adduct | Sprague-Dawley Rats (pmol/g)/(mg/kg/day) | | B6C3F_1_ Mice (pmol/g)/(mg/kg/day)
Adduct | R _Lo_^a^ | R _Hi_^b^ | R^c^
Cytosolic proteins
Cl_4_-1,4-BQ^d^ | 124 ± 175 | 396 ± 30.7 | 547 ± 11*
Cl_4_-1,2-BQ | nd | nd | 778 ± 25*
Cl_4_-1,4-SQ^e^ | 0.425 ± 0.37 | NA | nd
Cl_4_-1,2-SQ^e^ | 32.5 ± 25.1 | NA | 0.822 ± 0.50
Nuclear proteins
Cl_4_-1,4-BQ^d^ | 30.3 ± 17.4 | 57.2 ± 4.66 | 86.9 ± 3*
Cl_4_-1,2-BQ | nd | nd | 9.6 ± 0.71*
Cl_4_-1,4-SQ^e^ | 0.307 ± 0.21 | NA | nd
Cl_4_-1,2-SQ^e^ | 5.83 ± 3.01 | NA | nd

* p < 0.05 (significant increase compared with the R _Hi_ in rats).

Source: Lin et al. (1999).

Cl_4_-1,2-BQ = tetrachloro-1,2-benzoquinone; Cl_4_-1,4-BQ = tetrachloro-1,4-benzoquinone; Cl_4_-1,2-SQ = tetrachloro-1,2-benzosemiquinone; Cl_4_-1,4-SQ = tetrachloro-1,4-benzosemiquinone; R = estimated daily production of adducts; NA = not available; nd = not detected.

^a^ Daily adduct production at low doses (≤4 to 10 mg/kg).

^b^ Daily adduct production at high doses (≥60 to 230 mg/kg).

^c^ Daily adduct production over the whole dose range (5 to 40 mg/kg).

^d^ Includes all monosubstituted and multisubstituted Cl_4_-1,4-BQ-derived adducts.

^e^ Statistical evaluations of semiquinone adducts were not conducted.

1. pentachlorophenol is metabolized to reactive chlorinated semiquinone and quinone metabolites in rats and mice,
2. these reactive metabolites bind to sulfhydryl groups in liver cytosolic and nuclear proteins but the types and amounts of adducts differ,
3. semiquinone and quinone adducts are capable of further reactions resulting in multi-S-substituted cysteinyl conjugates (up to four per molecule) in blood and liver and may produce macromolecular crosslinks,
4. redox cycling associated with oxidation of tetrachlorohydroquinone and/or reduction of tetrachlorobenzoquinone generates oxygen radicals that can increase the level of oxidative damage to DNA,
5. the daily rate of protein adduct production per unit dose was greater in mice than in rats,
6. mice produced about five times more liver protein-binding species and had a 4-fold greater dose of quinone species to liver nuclei than rats (rats had a greater dose to liver cytosol),
7. adducts arising from tetrachloro-1,4-benzoquinone and tetrachloro-1,2-benzoquinone) occurred in mouse cytosolic and nuclear proteins, but only low levels of one semiquinone adduct (tetrachloro-1,2-benzosemiquinone) were observed in mouse liver cytosolic proteins,
8. adduct production was linearly related to dose in mice except for the semiquinone adduct where less than proportional production occurred at doses >20 mg/kg,
9. production of the tetrachloro-1,2-benzosemiquinone adduct was proportionally greater at low doses in rats and was 40-fold greater than in mice,
10. production of the tetrachloro-1,4-benzoquinone adduct was proportionally greater at high doses in rats but was 2- to 11-fold greater in mice than in rats,
11. types of adducts produced in Sprague-Dawley rats after a single dose (5 to 40 mg/kg) were comparable to those observed in F344 rats fed 60 mg/kg for six months, and
12. rates of adduct elimination were similar in rats and mice.

Thus, both the type and amount of adducts show interspecies differences. Specifically, the increased metabolism and greater dose of quinone species to liver nuclei in mice suggest that mouse liver has a greater risk of hepatic DNA damage (Lin et al. 1997; Tsai et al. 2002). This is supported by data that show greater amounts of both oxidative and direct DNA damage in the liver and increased hepatotoxicity in mice compared with rats (Lin et al. 2002). About 40% of the estimated total dose to mouse liver nuclei was attributed to tetrachloro-1,2-benzoquinone (Table 5-3) (Lin et al. 1999). Since this metabolite did not form adducts with liver or blood proteins in rats, it might play a critical role in pentachlorophenol hepatocarcinogenesis.

The induction of specific P450 isozymes in mice also may play a role in the formation of liver tumors as indicated by in vitro studies that examined the effects of various microsome inducers on pentachlorophenol metabolism in rats and mice (Tsai et al. 2001; van Ommen et al. 1989; van Ommen et al. 1986b). Tsai et al. (2001) demonstrated that increased metabolism was primarily associated with products of tetrachloro-1,4-benzoquinone. The levels of adducts formed by this metabolite were similar in rat liver cytosolic proteins following induction by either phenobarbital or 3-methylcholanthrene (2.4 times control levels). Adduct levels in mouse liver cytosolic proteins were about 2.3 times the control values with phenobarbital-induced microsomes but were much higher following induction by 3-methylcholanthrene (8-fold increase vs. controls). Adduct levels of all other quinone and semiquinone metabolites were not affected by induction. Also, under conditions of oxidative stress, Tsai et al. (2001) speculated that lipid hydroperoxides could mediate the bioactivation of pentachlorophenol to quinones or semiquinones at a much greater rate than P450s, resulting in enhanced toxicity.

If the pentachlorophenol-derived quinones rather than semiquinones are responsible for the carcinogenic effects, the dosing regimens used in the chronic bioassays may have contributed to the negative results in rat liver (Lin et al. 1999). Dose levels in Sprague-Dawley rats (1 to 30 mg/kg) and F344 rats (10 to 60 mg/kg) would favor less than proportional production of reactive quinones and greater than proportional production of semiquinones. Furthermore, liver DNA adduct levels in mice administered 15 mg/kg pentachlorophenol for 7 days were 50-fold greater than observed in F344 rats administered 60 mg/kg for 6 months.

#### Oxidative DNA Damage

In addition to direct DNA adducts formed by reactive metabolites of pentachlorophenol, several studies indicate that oxidative damage likely contributes to the carcinogenic effects of this chemical. Redox cycling of quinones and semiquinones can produce oxidative stress through formation of reactive oxygen species such as superoxide, hydrogen peroxide, and the hydroxyl radical (Zhu et al. 2011b). The most common biomarker of oxidative damage is 8-hydroxy-2'-deoyguanosine (8-OH-dG) and is formed by the interaction of DNA with the hydroxyl radical. Several studies indicate that hydroxyl radicals can be formed by tetrachlorohydroquinone and hydrogen peroxide via a metal-independent semiquinone-mediated organic Fenton reaction (Yin et al. 2013; Zhu et al. 2011a; Zhu et al. 2000; Zhu and Shan 2009; Zhu et al. 2011b).

8-OH-dG lesions were formed in deoxyguanosine and calf thymus DNA incubated with tetrachlorobenzoquinone or tetrachlorohydroquinone (Lin et al. 2001b; Naito et al. 1994; Yin et al. 2013), in human HeLa S3 tumor cells or Chinese hamster V79 cells incubated with tetrachlorohydroquinone (Dahlhaus et al. 1995; Dahlhaus et al. 1996; Lin et al. 2001a) and in the liver of B6C3F_1_ mice following acute (Sai-Kato et al. 1995b) or subacute to subchronic oral exposure (2 to 8 weeks) to pentachlorophenol or tetrachlorohydroquinone (Dahlhaus et al. 1994; Umemura et al. 1999; Umemura et al. 1996). Umemura et al. (2006) reported clear differences in the sensitivity of nrf2-deficient and wild-type ICR mice to pentachlorophenol-induced oxidative stress, thus, indicating that Nrf2 (a transcriptional factor that regulates induction of phase-II and antioxidant enzymes) played a key role in in vivo prevention of pentachlorophenol-induced oxidative stress and cell proliferation. A lack of Nrf2 in mice (nrf2^-/-^) exposed to 1200-ppm pentachlorophenol for 60 weeks resulted in progression of proliferative lesions (cholangiofibromas) to neoplasms (cholangiocarcinomas), which could result from oxidative stress generated through pentachlorophenol metabolism (Tasaki et al. 2014). Lin et al. (2002) also reported 8-OH-dG lesions in the liver of male F344 rats exposed to pentachlorophenol for 27 weeks but not in rats exposed for 1 or 5 days. The increase in 8-OH-dG lesions in rat liver after 27 weeks (2-fold increase vs. controls) was slightly less than that observed in the mouse after 2 to 4 weeks (2.4- to 2.8-fold increase). Sai-Kato et al. (1995b) also reported that 8-OH-dG lesions were not significantly increased in non-target tissues in mice (kidney and spleen). Further, Wang et al. (1997) reported that glutathione was depleted by more than 60% in the livers of mice treated with tetrachlorohydroquinone, thus, reducing protection against reactive oxygen species.

Although 8-OH-dG lesions can lead to point mutations (particularly G:C to T:A transversions) and oncogene activation, Umemura et al. (1999) found no evidence of an initiating effect of pentachlorophenol in mice. Tasaki et al. (2013) also reported that pentachlorophenol exposure significantly increased 8-OH-dG levels and mRNA levels of NAD(P):quinone oxidoreductase 1 (NQO1) in the liver of p53-proficient and -deficient mice without affecting the reporter gene mutation frequency. Thus, pentachlorophenol was shown to be a liver tumor promoter in mice, and the promoting action was related to oxidative stress and compensatory hepatocellular proliferation (Tasaki et al. 2013; Umemura et al. 2003a; Umemura et al. 1999; Umemura et al. 2003b; Umemura et al. 1996). An increase in sustained hepatocyte cell proliferation was observed in parallel with oxidative stress and without overt signs of hepatotoxicity, thus, suggesting that cell proliferation was induced by oxidative stress. Co-treatment of mice with antioxidants prevented oxidative stress and cell proliferation (Sai-Kato et al. 1995b; Umemura et al. 2003a). These data, along with the studies reviewed above, suggest that pentachlorophenol induces less oxidative stress in rat liver than in mouse liver.

#### Inhibition of Gap Junctional Intercellular Communication

Pentachlorophenol inhibits gap junctional intercellular communication in vitro and in vivo and supports the hypothesis that it contributes to tumor promotion via non-mutagenic mechanisms (Sai et al. 2001; Sai et al. 2000; Sai et al. 1998; Vinken et al. 2009b). Inhibition of apoptosis also has been associated with tumor promotion, and gap junctions have been linked to the apoptotic process (Sai et al. 2001). Liver homeostasis (i.e., hepatocellular proliferation, differentiation, and cell death) is mediated via gap junctional intercellular communication by exchanging small molecules and second messengers (Vinken et al. 2009b). A general characteristic of chemicals that alter gap junctional intercellular communication is that the effects are often manifested in a species-specific or tissue-specific manner. These features, combined with a general lack of direct DNA damage, are characteristic of nongenotoxic carcinogens. Many compounds (e.g., phorbol esters, phenobarbital, peroxisome proliferators, dieldrin, and DDT) that are known to suppress gap junctional intercellular communication are tumor promoters or epigenetic carcinogens (Sai et al. 2001; Sai et al. 1998). Therefore, inhibition of gap junctional intercellular communication may be a biological marker for nongenotoxic hepatocarcinogens (Vinken et al. 2009b).

Gap junctions are composed of connexin (Cx) proteins, and epigenetic regulation of connexin expression includes histone acetylation, DNA methylation, and microRNA-related control (Vinken et al. 2009a; Vinken et al. 2009b). Gap junctions occupy about 3% of the hepatocyte membrane surface and are organized in plaques that contain 10 to 10,000 channels. The importance of functional gap junctions in preventing liver cancer was demonstrated when Cx32 knockout mice were shown to be more susceptible to both spontaneous and chemically induced liver cancer than wild-type mice (Temme et al. 1997).

In vitro studies with v-myc-transfected rat liver epithelial cells showed that pentachlorophenol, but not tetrachlorohydroquinone, reversibly inhibited gap junctional intercellular communication prior to inhibition of apoptosis (Sai et al. 2001; Sai et al. 1998). These data were consistent with the hypothesis that gap junctional intercellular communication contributes to the tumor promotion process by increasing proliferation of transformed cells and decreasing programmed cell death. Further, decreased expression of p53 (a key molecule required for apoptosis induction) was observed, but levels of Bcl-2 (an anti-apoptotic factor) were unchanged. These data suggest that the mechanism of pentachlorophenol-mediated inhibition of apoptosis likely involved decreased expression of p53 and provide evidence for a direct role of pentachlorophenol in tumor promotion.

Male B6C3F1 mice exposed to 300-ppm or 600-ppm doses of pentachlorophenol in their diet for 2 weeks also developed a dose-related inhibition of gap junctional intercellular communication in hepatocytes associated with a reduction in Cx32 plaques in the plasma membrane and an increase in cell proliferation (Sai et al. 2000). These effects were prevented when mice were given green tea as their only source of drinking water. Mechanisms contributing to the anti-promoting action of green tea include its antioxidative properties, inhibition of enzymes that degrade connexins, and induction of detoxifying enzymes such as glutathione-S-transferase and sulfotransferases.

#### Mitogenic and Cytotoxic Effects

Allen et al. (2004) reported that prechronic liver lesions in rodents could be used to predict liver carcinogens. In particular, chemicals inducing hepatocellular necrosis, hepatocellular hypertrophy, and hepatocellular cytomegaly in prechronic studies had a high likelihood (89.5% in mice and 64% in rats) of inducing liver neoplasms in a chronic study. Adding increased liver weight increased the percentage of liver carcinogens correctly identified but also increased the number of false positives.

Although there is some evidence that pentachlorophenol is more hepatotoxic in mice than in rats, the data also indicate that the by-products of its synthesis are contributing factors (Kimbrough and Linder 1978; Lin et al. 2002; NTP 1989; NTP 1999). Suzuki et al. (1997) reported that pentachlorophenol caused intermediate cytotoxicity and slight peroxidative damage to isolated rat hepatocytes in vitro. Rats fed technical grade pentachlorophenol at doses of 100 to 500 ppm for eight months had prominent to severe hepatic lesions while purified pentachlorophenol was only mildly hepatotoxic (Kimbrough and Linder 1978). Rats fed diets containing pure pentachlorophenol for 28 days or 2 years had increased liver weights, minimal to mild hepatocyte degeneration, and minimal centrilobular hepatocyte hypertrophy (observed at 28 days or 7 months but not after 2 years). (Dorsey and Tchounwou 2004; 2006) reported that purified pentachlorophenol was acutely toxic in vitro to mouse AML 12 hepatocytes, caused a strong mitogenic response at sublethal concentrations, and induced stress-related gene expression. Stress-activated protein kinases were likely involved in facilitating the mitogenic response. Similar cytotoxic and mitogenic effects also were observed in human liver carcinoma (HepG2) cells (Dorsey et al. 2002). Mice fed purified pentachlorophenol at doses of 300 to 1,200 ppm for 2 to 4 weeks had severe hepatomegaly, hepatocyte swelling, and persistent hepatocyte proliferation, and significant elevation (2- to 3-fold) of serum AST levels; however, there were no extensive necrotic foci (Umemura et al. 1996). Hepatic lesions showed dose-related liver effects in mice (increased liver weights, centrilobular cytomegaly, karyomegaly, and necrosis) exposed to all grades of pentachlorophenol but were more severe in mice fed technical grade pentachlorophenol compared with mice fed EC-7 (a formulation containing less by-products of synthesis) or pure pentachlorophenol (NTP 1989).

### 5.2.4 Vascular Tumors in Mice

No specific mechanistic studies for pentachlorophenol and vascular tumors were identified; however, Cohen et al. (2009) proposed a working mode of action for the induction of hemangiosarcoma in rodents. These authors noted that hemangiosarcomas were more common in mice than in rats (possibly due to lower antioxidant levels) and that most of the chemicals (pentachlorophenol was not included) associated with these neoplasms were non-DNA reactive. The general model included hypoxia, increase in reactive oxygen species, and macrophage activation leading to the release of angiogenic growth factors and cytokines with subsequent stimulation of endothelial cell proliferation. Sustained endothelial cell proliferation could lead to hemangiosarcoma formation.

### 5.2.5 Mesothelioma in Rats

Mesotheliomas of the tunica vaginalis are relatively rare but are seen most frequently in male F344 rats and are causally associated with the high background incidence of Leydig-cell tumors of the testes in this strain (Maronpot et al. 2009). Proliferating Leydig cells result in an altered hormonal milieu in these rats and may contribute to the development of mesotheliomas. In addition, oxidative damage from pentachlorophenol exposure may contribute to the increased incidence of mesothelioma observed in male F344 rats (Lin et al. 2002). Mesothelial cells have low levels of antioxidants and are susceptible to oxidative stress because cellular defenses are more easily depleted. Evidence supporting a possible role of oxidative damage for pentachlorophenol-induced mesothelioma in rats comes from studies with mineral fibers where free radical toxicity and 8-OH-dG lesions are known to be contributing factors (Adachi et al. 1994; Murata-Kamiya et al. 1997). Also, in the NTP (1999) chronic bioassay, mesotheliomas were increased only in rats that were exposed to 1,000 ppm for 1 year and not in rats exposed to 600 ppm for 2 years (see Section 4). These data suggest a possible threshold for oxidative damage that was exceeded only in the stop-exposure study; however, the stop-exposure study did not test at lower doses.

### 5.2.6 Mouse Skin Tumor Models, Tumor Promotion/Enhanced Susceptibility

Two studies investigated the tumor-promoting potential of pentachlorophenol or tetrachlorohydroquinone in a mouse skin carcinogenesis model or in transgenic mice and provide some support for a nongenotoxic mechanism (Chang et al. 2003; Spalding et al. 2000). Chang et al. (2003) demonstrated that both pentachlorophenol and tetrachlorohydroquinone were weak promoters in the CD-1 mouse skin tumor model (dimethylbenz[a]anthracene used as the initiator). Both compounds induced epidermal hyperplasia, a biomarker of tumor promotion, and increased the cell proliferation index. Factors that likely contributed to the promotional effects of these compounds included oxidative stress, epidermal hyperplasia, and inhibition of gap junctional intracellular communication. Although this study demonstrated that pentachlorophenol and tetrachlorohydroquinone were tumor promoters in mouse skin, the authors could not rule out the possibility that these compounds might have had a syncarcinogenic effect. Lin et al. (2004) also demonstrated in vitro that tetrachlorohydroquinone-induced skin tumor promotion reported by Chang et al. (2003) could occur through upregulation of Bcl-2 protein and subsequent inhibition of apoptosis. However, these data are not consistent with Sai et al. (2001) (see Section 5.2.3) who reported inhibition of apoptosis through reduced expression of p53 rather than increased Bcl-2 expression.

Spalding et al. (2000) reported that dietary administration of pentachlorophenol was not active when tested in the haplo-insufficient p53 knockout mouse (p53^+/−^) but did cause papillomas (high-dose only) in transgenic mice that possessed an inducible v-Ha-ras gene (Tg•AC) exposed to pentachlorophenol dermally. The positive response only in the Tg•AC model is consistent with a nongenotoxic mechanism. However, the appropriateness of this model has been questioned, as neoplasms can be induced by non-carcinogenic treatments, such as skin irritation and wounding (Fuhrman et al. 2005). Other studies provided evidence that pentachlorophenol could enhance or inhibit the carcinogenicity of other compounds by inhibiting various enzymes involved in oxidation, epoxidation, sulfation of phenols, and acetylation (Arrhenius et al. 1977; Goodman 2001; Meerman et al. 1983; Moorthy and Randerath 1996). Moorthy and Randerath (1996) demonstrated that pentachlorophenol inhibits epoxide detoxication in vivo and in vitro and glutathione-S-transferase in vitro. Thus, pentachlorophenol exposure could enhance DNA damage caused by chemicals that undergo epoxidation prior to DNA binding. Arrhenius Arrhenius et al. (1977) incubated liver microsomes with pentachlorophenol and reported that electron transport in the cytochrome P450 enzyme system was strongly inhibited. The effect was attributed to pentachlorophenol rather than a metabolite.

### 5.2.7 Synthesis of Mechanistic Data

The carcinogenic actions of pentachlorophenol are not well understood but have been associated with multiple mechanisms including metabolism to genotoxic metabolites, oxidative damage, inflammation, cytotoxicity and sustained cell proliferation, induction of stress genes, immunosuppression, inhibition of enzymes involved in metabolism, interference with gap junctional intercellular communication, and inhibition of apoptosis. All of these mechanisms are relevant to humans; however, there is some controversy over the importance of metabolic activation pathways involving oxidation to tetrachlorohydroquinone, semiquinones, and benzoquinones because the available studies do not conclusively demonstrate that these metabolites are formed in vivo in humans. Furthermore, technical grade pentachlorophenol contains various by-products (e.g., other chlorophenols, dibenzo-p-dioxins, and dibenzofurans) that are carcinogenic and likely contribute to, but are not solely responsible for, the carcinogenic effects observed in humans and experimental animals exposed to pentachlorophenol.

Plausible modes of action contributing to hematopoietic cancers in humans include metabolic activation by peroxidases in bone marrow and lymphocytes to phenoxyl radicals that preferentially form O-bonded C8-dG adducts and immunosuppression. There is an association of non-Hodgkin lymphoma with immunosuppressive conditions, and pentachlorophenol is known to suppress both cellular and humoral immunity. Most studies in rodents indicate that the dioxin by-products (particularly the hexa- and hepta-substituted congeners) in the technical grade formulations are responsible for immunosuppression.

There is some evidence that liver cancer in mice could be caused by direct adduct formation with electrophilic tetrachlorobenzoquinone metabolites and/or oxidative damage to DNA derived from the redox cycling of benzoquinone and semiquinone metabolites. The dioxin by-products also likely contributed to liver tumors in mice. A comparison of rats and mice indicate that key differences in the quantity and quality of benzoquinone liver nuclear protein adducts, hepatotoxicity, and liver DNA damage may partially explain why the mouse is more susceptible than the rat. However, there is strong evidence that pentachlorophenol acts as a liver tumor promoter in mice through a number of mechanisms including oxidative stress without gene mutations, sustained hepatocellular proliferation, inhibition of gap-junctional intercellular communication, and inhibition of apoptosis. Liver tumor promotion also could possibly explain why mice are more susceptible than rats because of the high spontaneous rate of liver tumors in B6C3F_1_ mice.

Very few mechanistic data were available for other tumor sites; however, it is likely that all of the mechanisms discussed above are involved. There is evidence that oxidative DNA damage contributes to mesothelioma in rats. Transgenic mouse skin tumor models may also provide evidence for nongenotoxic mechanisms. Several studies also suggest that pentachlorophenol may enhance or inhibit the carcinogenicity of other xenobiotics by inhibiting key metabolizing enzymes involved in oxidation, epoxidation, sulfation, and/or acetylation.