# 4 Studies of Cancer in Experimental Animals

This section reviews and assesses carcinogenicity studies in experimental animals exposed to pentachlorophenol and by-products of its synthesis. The steps in the cancer evaluation process are (1) identifying and describing the carcinogenicity studies in experimental animals (Section 4.1), (2) assessing the quality of these studies (Section 4.2), (3) synthesizing the findings from these studies (Section 4.3), and (4) reaching a preliminary listing recommendation (Section 4.4).

## 4.1 Identification and Overview of the Studies

Cancer studies in experimental animals were identified by searching databases, comprehensive reviews, and citations from studies retrieved from the literature searches as described in Appendix A. Twelve studies (some studies are reported in multiple publications and some publications report on more than one study) met the inclusion/exclusion criteria requiring that included studies evaluate exposure specifically to pentachlorophenol and/or pentachlorophenol and by-products of its synthesis for long durations (>12 months for rats and mice) or report neoplastic lesions, or non-neoplastic lesions relevant to carcinogenicity (see Appendix D).

The twelve studies were conducted in different species (mice and rats), using different routes of exposure (feed and dermal), different purities of pentachlorophenol (99% pure, technical grade and Dowicide EC-7 grade) and different study designs (standard two-year bioassays, transgenic mice, heterozygous p53 gene knock-out mice, and mechanistic studies). All but one study (Spalding et al. 2000) used a dietary route of exposure. Three studies were two-year NTP carcinogenicity studies that tested 90.4% pure technical grade pentachlorophenol or Dowicide EC-7 in B6C3F_1_ mice (NTP 1989) or 99% pure pentachlorophenol in F344/N rats (Chhabra et al. 1999; NTP 1999). In order to look at the effects of dose intensity, NTP (1999) also conducted a study in rats that included a stop-exposure group exposed to almost twice the concentration of pentachlorophenol for one year and evaluated at two years. Schwetz et al. (1978) tested Dowicide EC-7 in both a carcinogenicity study and a pre-mating to lactation reproductive study in Sprague-Dawley rats.

The study reported in the Mirvish et al. (1991) publication was a co-carcinogen study, in which MRC-W rats were exposed to 2-hydroxyethylnitrosourea in drinking water for 40 weeks and to pentachlorophenol (86% pure technical grade) with 25 μg/kg of 2,3,7,8-tetrachlorodibenzo-p-dioxin (TCDD) and 670 μg/kg 2,3,7,8-tetrachlorodibenzofuran (TCDF) or other chemicals in their feed for 94 weeks. The results reported in this monograph are from control groups from this study of either no treatment or treatment with pentachlorophenol and by-products of its synthesis only.

Three other mouse studies had exposure durations ranging from 10 to 18 months (Boberg et al. 1983; Delclos et al. 1986; Innes et al. 1969). The Innes et al. (1969) study was a screening study that tested Dowicide and many other pesticides or industrial chemicals in two strains of mice, (C57BL/6xC3H/Anf)F_1_ and (C57BL/6xAKR)F_1_, initially by gavage starting at 7 days of age, then in the diet (from weaning at 4 weeks of age through 18 months of age). The Boberg et al. (1983) and Delclos et al. (1986) publications were mechanistic studies that tested the ability of 99% pure pentachlorophenol to inhibit induction of liver tumors by 1'-hydroxysafrole or 4-aminoazobenzene, N, N-dimethyl-4-aminoazobenzene, or N-methyl-4-aminoazobenzene through inhibition of sulfotransferase activity in female CD-1 mice. However, both studies reported data from a pentachlorophenol-only dosed group.

Two short-term (25- to 26-week exposures) carcinogenicity studies tested 99% pure pentachlorophenol in transgenic mice with alterations in either a Ha-ras oncogene (FVB) or in a heterozygous p53 gene knock-out mouse (C57BL/6) as an alternative to conventional 2-year carcinogenicity studies (Spalding et al. 2000).

## 4.2 Assessing the Quality of the Studies

Each of these primary studies was systematically evaluated in a two-step process by first evaluating whether the level of detail reported for key elements of study design, experimental procedures, and cancer endpoints was adequate for evaluating its quality and interpreting results (Table 4-1). Key factors considered in the quality assessment include characterization of the chemistry of the substance, dosing regimen, exposure and observation period, number of animals per exposure group, monitoring of animal health, and assessment for neoplasm endpoints. Details of each study assessment and quality criteria are reported in Appendix D, Table D-1, Table D-2 and Table D-3. The reporting quality of key elements for all twelve studies was considered to be adequate. The two-year carcinogenicity studies by NTP were considered to be the most informative, and specific elements related to study quality and the interpretation of the findings are discussed in Section 4.3.

Table 4-1 Overview of Studies of Exposure to Pentachlorophenol and By-products of Its Synthesis in Experimental Animals

Strain (Sex) | Substance | Experimental Design | Exposure Period/Study Duration | Reference
Rat: Diet
F344/N (M & F) | 99% pure PCP | Carcinogenicity | 2 yr/2 yr | Chhabra et al. (1999); NTP (1999)
F344/N (M & F) | 99% pure PCP | Carcinogenicity | 1 yr/2 yr | Chhabra et al. (1999); NTP (1999)
Sprague-Dawley (M & F) | Dowicide EC-7 | Carcinogenicity and reproductive | M: 22 mo/22 mo F: 24 mo/24 mo | Schwetz et al. (1978)
MRC-W (M &F) | Technical grade PCP | Co-carcinogen | 94 wk/94 wk | Mirvish et al. (1991)
Mouse: Diet
B6C3F_1_ (M & F) | Technical grade PCP | Carcinogenicity | 2 yr/2 yr | McConnell et al. (1991); NTP (1989)
B6C3F_1_ (M & F) | Dowicide EC-7 | Carcinogenicity | 2 yr/2 yr | McConnell et al. (1991); NTP (1989)
(C57BL/6xC3H/Anf)F_1_ (M & F) | Dowicide-7 | Carcinogenicity | 18 mo/18 mo | Innes et al. (1969)
(C57BL/6xAKR)F_1_ (M & F) | Dowicide-7 | Carcinogenicity | 18 mo/18 mo | Innes et al. (1969)
CD-1 (F) | 99% pure PCP | Mechanism^a^ | 12 mo/16 mo | Boberg et al. (1983)
CD-1 (F) | 99% pure PCP | Mechanism^a^ | 10 mo/17 mo | Delclos et al. (1986)
C57BL/6-Trp53(+/−) tm1Dol (M & F) | 99% pure PCP | Short-term p53 (+/−) knock-out carcinogenicity | 26 wk/26 wk | Spalding et al. (2000)
Mouse: Dermal
Tg•AC hemizygous (M & F)^b^ | 99% pure PCP | Short-term transgenic carcinogenicity | 20 wk/20 wk | Spalding et al. (2000)

M = male; F = female.

^a^ PCP inhibiting carcinogenic activation by sulfotransferase.

^b^ Zeta-globin promoted v-Ha-ras on a FVB background.

## 4.3 Assessment of Neoplastic Findings

Findings from feed studies in rats are reported in Table 4-2, feed studies in mice are reported in Table 4-3 and Table 4-4. Findings across all studies for each species are discussed below.

Table 4-2 Studies of Dietary Exposure to Pentachlorophenol and By-products of Its Synthesis in Rats: Tumor Incidence

Reference Strain, Sex Study Duration | PCP Purity | Exposure Duration ppm (# Rats) | Liver (%)^a^ Hepatocellular Adenoma | Nose (%)^a^ Squamous-cell Carcinoma | Multiple Organs Including Tunica Vaginalis (%)^a^ Malignant Mesothelioma | Comments
NTP (1999) F344/N Male 2 yr | 99% pure | [underlined: 2 yr] 0 (50) 200 (50)^b^ 400 (50)^b^ 600 (50)^b^ Trend | – | 1/50 (2.7)^c^ 3/50 (8.1) 1/50 (2.6) 0/50 (0.0) NS | 1/50 (2.6)^e^ 0/50 (0.0) 2/50 (5.1) 0/50 (0.0) NS | Survival was significantly increased compared to concurrent controls at 600 ppm. Body weights were lower than controls at 18 mo but returned to control levels by the end of the study.
NTP (1999) F344/N Female 2 yr | 99% pure | 0 (50) 200 (50)^b^ 400 (50)^b^ 600 (50)^b^ Trend | – | 0/50 [0] 0/50 [0] 0/50 [0] 0/50[\|0] NS | NR (all dose groups) | Survival was the same as concurrent controls. Body weights were lower than controls at 18 mo but returned to control levels by the end of the study.
NTP (1999) F344/N Male 2 yr | 99% pure | [underlined: Stop exposure: 1 yr] 0 (50) 1,000 (50)^b^ | – | 1/50 (2.7)^c^ 5/50 (11.6)^d^ | 1/50 (2.6)^e^ 9/50 (20.6)*^f^ | Survival was significantly increased compared to concurrent controls at 1,000 ppm. Body weights were lower than controls at the end of exposure but returned to control levels by the end of the study.
NTP (1999) F344/N Female 2 yr | 99% pure | [underlined: Stop exposure: 1 yr] 0 (50) 1,000 (50)^b^ | – | 0/50 [0] 1/50 [2] | NR | Survival was the same as concurrent controls. Body weights were lower than controls at 1 yr but returned to control levels by the end of the study.
Mirvish et al. (1991) MRC-W Male 94 wk | 86% pure with 25-ppb TCDD and 670-ppb TCDF | [underlined: 94 wk] 0 (NR) 500 (NR) | 0/9 [0]^g^ 0/5 [0]^g^ | – | – | Maximum mean body weights were similar between controls and exposed. The original number of rats was not reportedg, so survival effects cannot be evaluated. The number of exposed rats was low (5 males and 9 females).
Mirvish et al. (1991) MRC-W Female 94 wk | 86% pure with 25-ppb TCDD and 670-ppb TCDF | [underlined: 94 wk] 0 (NR) 500 (NR) | 0/18 [0]^g^ 6/9 [67] **^g^ | – | –
Schwetz et al. (1978) Sprague-Dawley Male 22 mo | Dowicide EC-7 (90.4% pure PCP) | [underlined: 22 mo] (mg/kg bw/day) 0 (27) 1 (27) 3 (27) 10 (27) 30 (27) | Authors reported that tumor incidences were not significantly different from controls, but incidences of specific tumor types were not reported. | | | Study terminated at 22 mo due to high mortality in control and experimental rats. Effects on body weight were not reported. Incidences of all tumors combined were not significantly increased; No incidences of the specific tumor types were reported but included: pituitary, adrenal, thyroid glands, testes, and pancreas.
Schwetz et al. (1978) Sprague-Dawley Female 24 mo | Dowicide EC-7 (90.4% pure PCP) | [underlined: 24 mo] (mg/kg bw/day) 0 (27) 1 (27) 3 (27) 10 (27) 30 (27) | Authors reported that tumor incidences were not significantly different from controls, but incidences of specific tumor types were not reported. | | | Survival was similar to controls, but body weights of females exposed to 30 mg/kg bw/day were significantly lower than controls. Incidences of all tumors combined were not significantly increased. Specific tumor types reported were mammary gland, pituitary gland, thyroid gland, uterus; no incidences reported.

[ ] Statistical significance calculated by NTP using the Fisher Exact test for pair-wise comparisons.

* p ≤ 0.05; **p ≤ 0.01; ***p ≤ 0.001 (compared with concurrent controls by poly-3 adjusted percent incidence after adjustment for intercurrent mortality).

NS = not significant; NR = not reported.

^a^ (Adjusted tumor percent incidence–adjusted to account for survival) or [non-adjusted tumor percent incidence].

^b^ Doses were based on toxicities from a 28-day feed study that caused lower body weights, increased liver weights, and liver lesions (hepatocyte degeneration and hepatocyte centrilobular hypertrophy) at 800 ppm, but not 400 ppm.

^c^ Historical control levels ranged from 0% to 4% in the testing laboratory.

^d^ Exceeded historical control range.

^e^ Historical control levels ranged from 0% to 8% in the testing laboratory.

^f^ Lesions originated from tunica vaginalis; lesions widely disseminated into the abdominal cavity in one control and 5 animals in the stop-exposure study.

^g^ Denominators are the numbers of rats that survived to 11 weeks.

Table 4-3 Summary of Dietary Pentachlorophenol and By-products of Its Synthesis Studies in Mice: Liver Tumor Incidence

Reference Strain, Sex Study Duration | Purity | Exposure Duration ppm (# Mice) | Hepatocellular Adenoma | Hepatocellular Carcinoma | Combined Neoplasms | Comments
NTP (1989) B6C3F_1_, Male 2 yr | Technical grade (90.4% pure) | [underlined: 2 yr] 0 (35) 100 (50) 200 (50) Trend | 5/32 (27.6)^b^ 20/47 (65.1)** 33/48 (88.5)*** p < 0.001 | 2/32 (11.4)^c^ 10/47 (33.2) 12/48 (39.5)* p = 0.031 | 7/32 (35.8)^d^ 26/47 (75.7)** 37/48 (89.6)*** p < 0.001 | Dose levels were based on liver lesions at 200 ppm from a 6-mo dietary study. Survival was not statistically different between concurrent controls (34%) and exposed groups (48% in low dose and 44% in high dose). Survival of untreated males (34%) was lower than that of untreated males in the Dowicide E-7 study (71%). Body weights of the male exposed groups were similar to the concurrent controls.
NTP (1989) B6C3F_1_, Female 2 yr | Technical grade (90.4% pure) | [underlined: 2 yr] 0 (35) 100 (50) 200 (50) Trend | 3/33 (10.7)^e^ 8/49 (19.5) 8/50 (24.0) p = 0.258 | 0/33 [0]^f^ 1/49 [2] 1/50 [2] [NS] | 3/33 (10.7)^g^ 9/49 (21.4) 9/50 (25.9) p = 0.198 | Dose levels were based on liver lesions at 200 ppm from a 6-mo dietary study. Survival was similar between concurrent controls and exposed groups. Body weight of the high-dose female group was 5% to 13% lower than concurrent controls by 82 wk.
NTP (1989) B6C3F_1_, Male 2 yr | Dowicide EC-7 (91% pure) | [underlined: 2 yr] 0 (35) 100 (50) 200 (50) 600 (50) Trend | 5/35 (20.0)^b^ 13/48 (41.6) 17/48 (53.0)* 32/49 (84.1)*** p ≤ 0.001 | 1/35 (4.0)^c^ 7/48 (20.2) 7/48 (24.1) 9/49 (25.0)* p = 0.080 | 6/35 (24.0)^d^ 19/48 (53.8)* 21/48 (65.5)** 34/49 (87.1)*** p ≤ 0.001 | Survival was similar in exposed groups and untreated controls. Survival of untreated males (71%) was higher than that of untreated males in the technical grade study (34%). Body weights were lower in exposed compared with untreated controls in the high-dose males.
NTP (1989) B6C3F_1_, Female 2 yr | Dowicide EC-7 (91% pure) | [underlined: 2 yr] 0 (35) 100 (50) 200 (50) 600 (50) Trend | 1/34 (3.4)^e^ 3/50 (10.7) 6/49 (15.8) 30/48 (75.0)*** p ≤ 0.001 | 0/34 [0]^f^ 1/50 [2] 0/49 [0] 2/48 [4] [NS] | 1/34 (3.4)^g^ 4/50 (13.8) 6/49 (15.8) 31/48 (77.5)*** p ≤ 0.001 | Survival rates were similar in untreated controls and mid- and high-dose females and were significantly lower for low-dose females compared with controls. Body weights were lower in exposed compared with untreated controls in mid- and high-dose females.
Innes et al. (1969) (C57BL/6xC3H/Anf)F_1_ and (C57BL/6xAKR)F_1_, Male 18 mo | Dowicide-7 | [underlined: 18 mo] (ppm in food) 0 (79–90) 130 (18) | No significant increase at 0.01 significance level | – | – | Mice were originally administered PCP by gavage, then after weaning at 3 weeks were administered PCP in the diet. The dose level was based on the results of a 19-day study. Screening study evaluated multiple chemicals, tumor incidence for individual chemicals not reported; no significant increase in any tumor at p = 0.01 significance level
Innes et al. (1969) (C57BL/6xC3HAnf)F_1_ and (C57BL/6xAKR)F_1_, Female 18 mo | Dowicide-7 | [underlined: 18 mo] (ppm in food) 0 (82–87) 130 (18) | No significant increase at 0.01 significance level | – | – | Mice were originally administered PCP by gavage, then after weaning at 4 weeks were administered PCP in the diet. The dose level was based on the results of a 19-day study. A screening study to evaluate multiple chemicals, tumor incidence for individual chemicals not reported; no significant increase in any tumor at p = 0.01 significance level.
Boberg et al. (1983) CD-1 Female 16 mo | PCP >99% pure | [underlined: 12 mo] 0 (36) 500 (36) | – | – | Liver hepatoma^h^ 0/32 [0] 0/31 [0] | This study examined PCP inhibition of tumor induction by 1'-hydroxysafrole and PCP inhibition of sulfotransferase activity.
Delclos et al. (1986) CD-1 Female 17 mo | PCP >99% pure | [underlined: 10 mo] 0 (35) 500 (35) | – | – | Liver hepatoma 0/20 [0] 0/27 [0] | This study examined PCP inhibition of liver tumor induction by other carcinogens.

[ ] Statistical significance calculated by NTP using the Fisher’s Exact test for pair-wise comparisons or Cochran-Armitage trend test.

p ≤ 0.05; **p ≤ 0.01; ***p ≤ 0.001 (compared with concurrent controls by Fisher’s Exact test for pair-wise comparisons and Cochran-Armitage trend test for trends).

NS = not significant; NR = not reported.

^a^ (Survival adjusted tumor percent incidence) or |non-adjusted tumor percent incidence|.

^b^ Historical control levels ranged from 8% to 15% in the testing laboratory and 0% to 44% in NTP studies.

^c^ Historical control levels ranged from 8% to 28% in the testing laboratory and 8% to 30% in NTP studies.

^d^ Historical control levels ranged from 16% to 40% in the testing laboratory and 16% to 58% in NTP studies.

^e^ Historical control levels ranged from 0% to 8% in the testing laboratory and 0% to 18% in NTP studies.

^f^ Historical control levels ranged from 2% to 8% in the testing laboratory and 0% to 8% in NTP studies.

^g^ Historical control levels ranged from 4% to 17% in the testing laboratory and 2% to 20% in NTP studies.

^h^ Gross observation of liver for hepatic nodules.

Table 4-4 Summary of Dietary Pentachlorophenol and By-products of Its Synthesis Studies in Mice: Blood Vessels (%)^a^ Tumor Incidence

Reference Strain, Sex Study Duration | Purity | Exposure Duration ppm (# Mice) | Hemangioma | Hemangiosarcoma | Combined Neoplasms^b^ | Comments
NTP (1989) B6C3F_1_, Male 2 yr | Technical grade (90.4% pure) | [underlined: 2 yr] 0 (35) 100 (50) 200 (50) Trend | 1/36 [3] 0/49 [0] 2/49 [4] [NS] | 0/35 [0] 2/49 [4] 1/49 [2] [NS] | 1/35 (3.8) 2/49 (8.3) 3/49 (11.4) NS | See Table 4-3
NTP (1989) B6C3F_1_, Female 2 yr | Technical grade (90.4% pure) | [underlined: 2 yr] 0 (35) 100 (50) 200 (50) Trend | 0/35 [0] 0/50 [0] 0/50 [0] | 0/35 (0.0)^c^ 3/50 (6.8) 6/50 (17.1)* p = 0.024 | – | See Table 4-3
NTP (1989) B6C3F_1_, Male 2 yr | Dowicide EC-7 (91% pure) | [underlined: 2 yr] 0 (35) 100 (50) 200 (50) 600 (50) Trend | 1/35 [3] 0/50 [0] 1/50 [2] 2/49 [4] [NS] | 0/35 (0.0) 4/50 (13.2) 2/50 (6.7) 3/49 (8.6) p = 0.411 | 1/35 (4.0) 4/50 (13.2) 3/50 (10.0) 5/49 (14.3) p = 0.200 | See Table 4-3
NTP (1989) B6C3F_1_, Female 2 yr | Dowicide EC-7 (91% pure) | [underlined: 2 yr] 0 (35) 100 (50) 200 (50) 600 (50) Trend | 0/35 [0] 0/50 [0] 0/50 [0] 1/49 [2] [NS] | 0/35 (0.0) 1/50 (3.6) 3/50 (7.3) 8/49 (18.9)** p ≤ 0.001 | 0/35 (0.0)^d^ 1/50 (3.6) 3/15 (7.3) 9/49 (21.3)** p ≤ 0.001 | See Table 4-3

[] Statistical significance calculated by NTP using the Fisher’s Exact test for pair-wise comparisons or Cochran-Armitage trend test.

* p ≤ 0.05; **p ≤ 0.01; ***p ≤ 0.001 (compared with concurrent controls by Fisher’s Exact test for pair-wise comparisons and Cochran-Armitage trend test for trends).

NS = not significant.

^a^ (Survival adjusted tumor percent incidence) or [non-adjusted tumor percent incidence].

^b^ Blood vessel tumors occurred mostly in the spleen, but also in the liver.

^c^ Historical control levels ranged from 0% to 4% in the testing laboratory and 0% to 8% in NTP studies.

^d^ Historical control levels ranged from 0% to 6% in the testing laboratory and 0% to 12% in NTP studies.

### 4.3.1 Feed Studies: Rats

Four feed studies using three different strains of rat and three grades of pentachlorophenol were found to be adequate for the cancer evaluation (Table 4-2). These studies found that pentachlorophenol and by-products of its synthesis causes malignant mesothelioma originating from the tunica vaginalis and squamous-cell carcinomas of the nasal cavity in male rats.

The most informative studies were the stop-exposure and continuous-exposure feed studies with 99% pentachlorophenol in Fischer 344/N rats (Chhabra et al. 1999; NTP 1999). These studies were informative due to appropriate dose selection, number of animals studied, duration of observation period, and comprehensive histopathologic evaluation of tissues. The stop-exposure study had a shorter exposure duration than the continuous-exposure study but they both used the same study period of two years, which approached the lifetime of the animal. The single dose level was higher (1,000 ppm) than the highest dose level of the continuous-exposure study (600 ppm), and decreased body weight with the greater dose in the stop-exposure study was evidence of some toxicity. There were no differences in survival between the concurrent control and high-dose groups in either the continuous-exposure study or the stop-exposure study. Treatment-related neoplasms occurred in the mesothelium and nasal cavity in rats exposed to pentachlorophenol in the stop-exposure study, but not the continuous-exposure study.

Malignant mesotheliomas originating from the tunica vaginalis and found throughout the abdominal cavity were significantly increased in male F344/N rats of the stop-exposure study, but not in rats continuously exposed for two years (Chhabra et al. 1999; NTP 1999). The malignant mesothelioma incidence (21%) was also higher than the incidence range of historical controls (0% to 8%). The occurrence of malignant mesotheliomas in the stop-exposure group is considered an effect of 99% pentachlorophenol administration.

Squamous-cell carcinomas of the nasal cavity were also induced in male F344/N rats in the stop-exposure study. The incidences of squamous-cell carcinomas were not statistically significantly increased but were greater than the historical control range for two-year feed studies (0% to 4%, based on 1,341 rats), and the concurrent controls (3%) were within the historical control range. The increased incidences were found in males exposed to 99% pure pentachlorophenol in the stop-exposure study (12%) and at the low dose level in the continuous-exposure study (8%). No squamous-cell carcinomas of the nasal cavity were observed in females. Respiratory epithelial hyperplasia and squamous metaplasia were also seen in the nasal cavity; however, these lesions were apparently associated with fungal infections and not with exposure to pentachlorophenol and by-products of its synthesis as the incidences of hyperplasia and metaplasia mirrored those of the infections and decreased with increasing level of pentachlorophenol dose. Although not statistically significant, the occurrence of nasal squamous-cell carcinoma in the stop-exposure group is well above concurrent and historical control levels and is considered an effect of 99% pentachlorophenol administration.

A two-year feed study in Sprague-Dawley rats exposed to Dowicide EC-7 (96.4%) reported no significant increases in total neoplasms (Schwetz et al. 1978). The tumor incidences were high (around 50% in males and 100% in females) and similar between the untreated controls and all exposed groups, but neoplasms were reported only as total neoplasms, a small number of animals were tested, and survival was not reported. Because no incidences of specific types of neoplasms were reported, the significance of specific tumor types could not be evaluated. Maximum exposure dose was 30-mg/kg bw/d as reported by the authors. Exposure concentrations used in this study are similar to that used in the NTP continuous-feed study in F344/N rats. The 600-ppm exposure in feed in that study is approximately a 30-mg/kg bw/d dose for male and female rats, similar to the high dose in the continuous-exposure study that reported no significant increase in neoplasms, and well below the stop-exposure dose of 1,000 ppm (approximately 60-mg/kg bw/d dose in feed) that resulted in tumors.

The incidence of benign liver tumors (adenomas) was significantly increased in female MRC-W rats, but not in males after 94-weeks exposure to technical grade pentachlorophenol in feed (Mirvish et al. 1991). The Mirvish study was also the only study that identified TCDD and TCDF in the test substance. These compounds are considered contaminants of pentachlorophenol rather than production by-products as they are rarely present at detectable levels in technical grade or commercial grade pentachlorophenol (WHO 1987). The authors obtained technical grade pentachlorophenol from a U.S. chemical supplier, but the production source was not identified. The Mirvish study had a low number of rats per group, but survival could not be assessed because the original number of rats was not reported. These tumors are considered a treatment-related effect possibly as a result of these contaminants, and the significance of these contaminants on rat liver carcinogenesis is discussed in Section 5.

### 4.3.2 Feed Studies: Mice

Seven feed studies using five different strains of mouse and three grades of pentachlorophenol were found to be adequate for the cancer evaluation (Table 4-3, Table 4-4, Table 4-5, Table 4-6). The most informative studies were two chronic cancer studies in mice with each using different grades of pentachlorophenol (McConnell et al. 1991; NTP 1989) conducted by NTP. These studies had minimal quality concerns and provided detailed chemical analyses of the compounds tested. Neoplasms related to treatment with pentachlorophenol and by-products of its synthesis occurred in the liver, adrenal glands, and blood vessels in mouse feed studies using technical grade pentachlorophenol or Dowicide EC-7 and these outcomes are discussed below.

Table 4-5 Summary of Dietary Pentachlorophenol and By-products of Its Synthesis Studies in Mice: Adrenal Gland (%)^a^ Tumor Incidence

Reference Strain, Sex Study Duration | Purity | Exposure Duration ppm (# Mice) | Medullary Hyperplasia | Benign | Malignant | Combined Pheo-chromocytoma | Comments
NTP (1989) B6C3F_1_, Male 2 yr | Technical grade (90.4% pure) | [underlined: 2 yr] 0 (35) 100 (50) 200 (50) Trend | 1/31 [3] 10/45 [22]^[^*^]^ 10/45 [22]^[^*^]^ [p ≤ 0.05] | 0/31 (0.0)^b^ 10/45 (37.9)** 23/45 (84.9)*** p < 0.001 | NR | | See Table 4-3
NTP (1989) B6C3F_1_, Female 2 yr | – | [underlined: 2 yr] 0 (35) 100 (50) 200 (50) Trend | 0/33 [0] 4/48 [8] 2/49 [4] [NS] | 0/33 [0] 2/48 [4] 1/49 [2] NS | 2/33 [6] 0/48 [0] 0/49 [0] [NS] | 2/33 [6]^c^ 2/48 [4] 1/49 [2] [NS] | See Table 4-3
NTP (1989) B6C3F_1_, Male 2 yr | Dowicide EC-7 (91% pure) | [underlined: 2 yr] 0 (35) 100 (50) 200 (50) 600 (50) Trend | 1/34 [3] 19/48 [40]^[^***^]^ 13/48 [27]^[^**^]^ 1/49 [2] [p ≤ 0.01] | 0/34 (0.0) 4/48 (13.8) 21/48 (67.5)*** 44/49 (97.8)*** p ≤ 0.001 | 1/34 (4.0) 0/48 (0.0) 0/48 (0.0) 3/49 (8.6) p = 0.084 | 1/34 (4.0)^b^ 4/48 (13.8) 21/48 (67.5)*** 45/49 (100.0)*** p ≤ 0.001 | See Table 4-3
NTP (1989) B6C3F_1_, Female 2 yr | Dowicide EC-7 (91% pure) | [underlined: 2 yr] 0 (35) 100 (50) 200 (50) 600 (50) Trend | 2/35 [6] 1/49 [2]^[^***^]^ 5/46 [11]^[^**^]^ 17/49 [35] [p ≤ 0.001] | 0/35 (0.0) 1/49 (3.6) 2/46 (5.3) 38/49 (86.3)*** p ≤ 0.001 | 0/35 \|0\| 1/49 \|2\| 0/46 \|0\| 1/49 \|2\| [NS] | 0/35 (0.0)^c^ 2/49 (7.1) 2/46 (5.3) 38/49 (86.3)*** p ≤ 0.001 | See Table 4-3

[] Statistical significance calculated by NTP using the Fisher’s Exact test for pair-wise comparisons or Cochran-Armitage trend test.

* p ≤ 0.05; **p ≤ 0.01; ***p ≤ 0.001 (compared with concurrent controls by Fisher’s Exact test for pair-wise comparisons and Cochran-Armitage trend test for trends).

NS = not significant; NR = not reported; NOS = not otherwise specified.

^a^ (Survival adjusted tumor percent incidence) or [non-adjusted tumor percent incidence].

^b^ Historical control levels ranged from 0% to 2% in the testing laboratory and 0% to 8% in NTP studies (includes 2/1,969 malignant pheochromocytomas).

^c^ Historical control levels ranged from 0% to 4% in the testing laboratory and 0% to 6% in NTP studies (includes 2/1,969 malignant pheochromocytomas).

Table 4-6 Summary of Dietary Pentachlorophenol and By-products of Its Synthesis Studies in Mice: Tumor Incidence

Reference Strain, Sex Study Duration | Exposure Duration ppm (# Mice) | Liver (%) Hepatocellular Carcinoma or Adenoma | Other Reported Tissues (%) | Comments
Innes et al. (1969) (C57BL/6xC3H/Anf)F_1_ and (C57BL/6xAKR)F1, Male 18 mo | [underlined: 18 mo] (ppm in food) 0 (79–90) 130 (18) | – | NS | Dowicide-7 Incidences for experimental groups that were negative were not reported. Mice were originally administered PCP by gavage, then after weaning at 3 weeks were administered PCP in the diet. The dose level was based on the results of a 19-day study.
Innes et al. (1969) (C57BL/6xC3HAnf)F_1_ and (C57BL/6xAKR)F1, Female 18 mo | [underlined: 18 mo] (ppm in food) 0 (82–87) 130 (18) | – | NS
Boberg et al. (1983) CD-1 Female, 16 mo | [underlined: 12 mo] 0 (36) 500 (36) | [underlined: Liver hepatoma] 0/32 [0] 0/31 [0] | Angioliposarcoma and hemangioma of the liver and lung adenoma – one mouse each (1/31), control (0/32). | PCP >99% pure. This study examined PCP inhibition of tumor induction by 1'-hydroxysafrole and PCP inhibition of sulfotransferase activity. Results reported for control and PCP only groups.
Delclos et al. (1986) CD-1 Female, 17 mo | [underlined: 10 mo] 0 (35) 500 (35) | [underlined: Liver hepatoma] 0/20 [0] 0/27 [0] | [underlined: Lymphoma] 1/20 [5] 3/27 [11] Mammary adenocarcinoma, malignant histiocytoma, hemangioendothelioma and angiosarcoma of the liver (one mouse each (1/27), control (0/20) | PCP >99% pure This study examined PCP inhibition of liver tumor induction by other carcinogens. Results reported for control and PCP-only groups.
Spalding et al. (2000) C57BL/6-Trp53(+/−) tm1Dol; N5 (heterozygous) Male, 26 wk | [underlined: 26 wk] 0 (10) 100 (10) 200 (10) 400 (10) | – | NS | PCP 99% pure No tumor incidences were given and results reported as “−” (negative)
Spalding et al. (2000) C57BL/6-Trp53(+/−) tm1Dol; N5 (heterozygous) Female, 26 wk | [underlined: 26 wk] 0 (10) 100 (10) 200 (10) 400 (10) | – | NS | PCP 99% pure No tumor incidences were given and results reported as “−” (negative)

NS = not significant; NR = not reported; NOS = not otherwise specified.

^a^ (Adjusted tumor percent incidence – adjusted to account for survival) or [non-adjusted tumor percent incidence].

Malignant and benign neoplasms of the liver (hepatocellular carcinoma and adenoma combined) were induced in male and female B6C3F_1_ mice exposed to Dowicide EC-7 and males exposed to technical grade pentachlorophenol. The benign neoplasm (hepatocellular adenoma) was the predominant neoplasm, being significantly increased in both males and females exposed to Dowicide EC-7 and in males exposed to technical grade pentachlorophenol. However, only the males had significant increases in the malignant neoplasm (hepatocellular carcinoma). Females exposed to either grade of pentachlorophenol did develop carcinomas, but they were not significantly increased until combined with the adenomas. There were significant dose-response trends for the combined incidences of malignant and benign, or benign liver neoplasms alone, except for females exposed to technical grade pentachlorophenol.

Combined malignant and benign or benign alone adrenal-gland neoplasms (pheochromocytoma) and pre-neoplastic lesions (medullary hyperplasia) were induced in male and female B6C3F_1_ mice exposed to Dowicide EC-7, while only benign neoplasms and pre-neoplastic lesions were induced in males exposed to technical grade pentachlorophenol. No malignant neoplasms of the adrenal gland were found in mice exposed to technical grade pentachlorophenol. The neoplasms induced by Dowicide EC-7 (benign and combined) also had significant dose-response trends. A few malignant pheochromocytomas were reported in male and female mice exposed to Dowicide EC-7 that were not statistically significant on their own but were significant when the incidences were combined with benign pheochromocytomas.

Incidences of malignant tumors of the blood vessels (hemangiosarcoma) of the spleen and/or liver were significantly increased in female B6C3F_1_ mice at the high dose levels after exposure to either technical grade pentachlorophenol or Dowicide EC-7. Significant trends were also reported in these groups. Hemangiosarcomas and hemangiomas were seen in males and a hemangioma was seen in one female exposed to Dowicide EC-7, but not at incidences that were statistically significant.

Other feed studies in mice failed to show a statistically significantly increased incidence of neoplasms and were of different experimental designs than the NTP studies (Boberg et al. 1983; Delclos et al. 1986; Innes et al. 1969; Spalding et al. 2000).

The Innes et al. (1969) study screened a large number of chemicals for tumors after neonatal gavage (postnatal days 7 to 28) and followed by feed exposures until necropsy at 18 months of age. Dowicide EC-7 was tested for slightly less than lifetime duration at a single, relatively low dose (130 ppm), comparable to the low doses used in the NTP (1989) and McConnell et al. (1991) studies in both sexes of two strains of mouse (C57BL/6xC3H/Anf)F1 and (C57BL/6xAKR)F1). Necropsy consisted of gross inspection of the pleural and peritoneal cavities for tumors and no tumors were reported for Dowicide EC-7. These results are similar to the NTP study that did not report tumors at the low dose (100 ppm) for Dowicide EC-7.

Pentachlorophenol was used in two studies of similar design, with the intent to examine the effect of pentachlorophenol inhibition of sulfotransferase activity on tumor induction (Boberg et al. 1983; Delclos et al. 1986). These studies were relatively short-term feed studies, exposing female CD-1 mice for a year or 10 months, at only one dose level of pentachlorophenol, with study durations of 16 and 17 months. Both studies used 99% pentachlorophenol in feed and the results for pentachlorophenol-only exposure (500 ppm) were compared with vehicle-only exposure for formation of hepatic nodules (“hepatomas”) by pentachlorophenol. These studies did not report liver tumors in female mice at 500 ppm. The results of the NTP study in female mice with Dowicide EC-7 did not conflict with these results, in that liver tumors were reported at a higher dose (600 ppm but not 200 ppm) and a longer exposure and observation period (2 years).

The Spalding et al. (2000) study was a short-term study in a haplo-insufficient p53(+/−) gene knock-out mouse model and exposure was to 99% pentachlorophenol in feed for 26 weeks at up to 400 ppm. A complete necropsy was performed by NTP, and results were reported as negative (no tumor incidence data were reported). The results of this study suggest that pentachlorophenol and by-products of its synthesis induced carcinogenesis through a pathway that does not involve p53 (see Section 5 “Mechanisms”). However, no positive control groups were used in the study and none of the six experimental chemicals tested in this report induced neoplasms. Additionally, this is a model system for identification of mutagenic carcinogens and cannot be interpreted as a lack of carcinogenic activity (Eastin et al. 1998; French et al. 2001).

### 4.3.3 Dermal Studies: Mice

Only one study tested dermal application of 99% pentachlorophenol in Tg•AC mice (Spalding et al. 2000) (see Table 4-7). Papillomas of the skin were induced in transgenic female mice that are hemizygous with a zeta-globin promoted v-Ha-ras oncogene after a six-month exposure period. The incidence of papillomas was significantly increased at the two highest dose levels and had a positive dose-response trend with 100% incidence at the highest dose level. In addition to increased incidences, there were increases in multiplicity, i.e., the number of papillomas per mouse. The multiplicity was not analyzed statistically but was over 100 times higher in the high-dose group (11.6/mouse) than the vehicle-treated controls (0.07/mouse) and increased with dose. The study was well designed and included not only an untreated control, but also a positive control group of 12-O-tetradecanoyl-phorbol-13-acetate-exposed mice. The finding of papillomas at high multiplicity provides support for carcinogenic activity of 99% pentachlorophenol in mice. This transgenic mouse model is more sensitive to tumor induction than conventional cancer bioassays, as it has an oncogenic mutation. However, this model has been questioned as neoplasms can be induced by non-carcinogenic treatments, such as skin irritation and wounding (Fuhrman et al. 2005).

Table 4-7 Summary of Dermal Pentachlorophenol and By-products of Its Synthesis Studies in Tg.AC Transgenic Mice

Reference Strain Sex Study Duration | Exposure Duration Dose in mg/Mouse (# Animals) 5 Doses/Week | Skin (%)^a^ Papilloma | Comments
Spalding et al. (2000) Tg•AC hemizygous (zeta-globin promoted v-Ha-ras on a FVB background) Female 26 wk | [underlined: 20 wk] 0 (15)^b^ 0.75 (13) 1.5 (13) 3.0 (14) Trend 0 (15) 0.75 (13) 1.5 (13) 3.0 (14) | [underlined: Incidence] 1/15 [7] 1/13 [8] 8/13 [62]^[^**^]^ 14/14 [100]^[^****^]^ [p ≤ 0.0001] [underlined: Multiplicity^c^] 1/15 [0.07] 1/13 [0.08] 11/13 [0.85] 162/14 [11.6] | PCP 99% Survival was similar to untreated controls. A positive control of TPA^d^ was used, which had an incidence of 15/15 [100%] and multiplicity of 405/15 (27.0 tumors/mouse).

Statistical significance calculated by NTP using one-sided Fisher Exact test for pair-wise comparisons or Cochran-Armitage trend test for trends [].

* p ≤ 0.05; **p ≤ 0.01; ***p ≤ 0.001; ****p ≤ 0.0001.

^a^ (Tumor percent incidence adjusted to account for survival) or [non-adjusted tumor percent incidence].

^b^ Negative control of acetone.

^c^ Multiplicity expressed as total tumors/# mice and [average # tumors/mouse].

^d^ 12-O-Tetradecanoyl-phorbol-13-acetate, 1.25 μg, 3 doses/wk.

## 4.4 NTP Recommendation of Level of Evidence

There is sufficient evidence for the carcinogenicity of pentachlorophenol and by-products of its synthesis in experimental animals. The listing is based on exposure-related malignant and/or a combination of malignant and benign neoplasms of the liver, adrenal gland, blood vessels, nasal cavity, and tunica vaginalis. Incidences of liver (hepatocellular carcinoma [male mice only] and hepatocellular carcinoma and adenoma combined) and adrenal gland (combined malignant and benign pheochromocytoma) neoplasms were significantly increased in male and female mice, while malignant neoplasms of the blood vessels (hemangiosarcoma) were induced in female mice. In male rats, significant increases in malignant neoplasms of the tunica vaginalis (mesothelioma) and non-statistically significant increases in rare nasal cavity (squamous-cell carcinoma) neoplasms occurred at incidences greater than historical controls.