# 3 Human Cancer Studies

## Introduction

As mentioned in Section1, the evaluation of pentachlorophenol includes by-products of its synthesis (hereinafter called pentachlorophenol). This section describes and evaluates the available epidemiological data on exposure to pentachlorophenol and cancer, reaching a level of evidence conclusion according to the approach outlined in the “Protocol: Evaluation of Human Cancer Studies on Exposure to Pentachlorophenol and By-Products of Its Synthesis for the Report on Carcinogens” (https://ntp.niehs.nih.gov/NTP/roc/thirteenth/Protocols/PCPHumanStudies20130815_508.pdf). The steps in the cancer evaluation process, listed below, are captured in the following subsections or appendices.

1. Selection of the relevant literature included in the cancer evaluation (Section 3.1 and Appendix A for the literature search strategy).
2. Description of the study design, methodologies, and characteristics of the individual studies and identification of the tumor sites of interest (Section 3.2 and Appendix C).
3. Assessment of study quality (Section 3.3 and Appendix C).
4. Cancer assessment: (a) evaluation of the cancer findings from the individual studies (Section 3.4.1) and (b) synthesis of the evidence for human carcinogenicity across studies (Section 3.4.2).
5. Preliminary recommendation for the level of evidence of carcinogenicity (sufficient, limited, or inadequate) of pentachlorophenol from human studies (Section 3.5).

## 3.1 Selection of the Relevant Literature

The procedures used to identify and select the primary studies and supporting literature for the human cancer evaluation are described in Appendix A. Primary epidemiologic studies of populations exposed to pentachlorophenol (including cohort, case-control, meta-analyses, pooled analyses, ecological or case-series studies) were considered for the cancer evaluation if (1) they provided exposure-specific analyses for pentachlorophenol and (2) risk estimates for pentachlorophenol exposure were reported or could be calculated.

Two publicly available reports, a cohort mortality study of New Zealand sawmill workers prepared for the New Zealand Department of Labour (McLean et al. 2007) and a cohort study of U.S. plywood manufacturers (Robinson et al. 1987), were identified but not included in the monograph because they were not peer reviewed. A population-based case-control study of non-Hodgkin lymphoma and occupations associated with exposure to chlorophenols and phenoxyherbicides, conducted in Washington State (Woods et al. 1987), was identified but not included in this review. Exposure to pentachlorophenol was highly probable for one of the occupations (manufacturer of chlorophenols) included in the study because the only chlorophenol producer plant located in Washington State produced pentachlorophenol. Workers at this manufacturing plant were most likely included in a cohort study (Ruder and Yiin 2011) included in this review (see Section 3.2).

Several studies were identified that provided information, according to the authors, that pentachlorophenol exposure was probable or predominant in the population or a job or occupation under study; however, they did not provide risk estimates specific for pentachlorophenol and thus are excluded from this review. These include a nested case-control study of combined childhood cancers based on the Canadian sawmill cohort (Heacock et al. 2000), a series of population-based case-control studies of NHL, soft tissue sarcoma, and multiple myeloma in New Zealand (Pearce et al. 1987; Pearce et al. 1986a; 1986b; Smith et al. 1984) and an Australian case-control study of soft tissue sarcoma and lymphomas (Smith and Christophers 1992).

## 3.2 Overview of the Methodologies and Study Characteristics of the Selected Epidemiological Studies and Identification of Cancer Endpoints

This section provides an overview of the characteristics and methodologies of the individual studies included in the review and identifies the cancer endpoints of interest. For each of the reviewed studies, detailed data on study design, methods, and findings were systematically extracted from relevant publications, as described in the study protocol, into Table C-1, Table C-2, Table C-3, and Table C-4 in Appendix C and tables in Section 3.4. In general, this assessment reports on the latest update of a cohort or case-control study unless there are additional relevant analyses or information in the previous publications.

The available epidemiological studies that satisfy the criteria for consideration in the cancer evaluation consist of four cohort studies or nested case-control studies, one ecological study and six independent population-based case-control studies (see Table 3-1). The nested case-control studies and cohort studies include (1) one nested case-control study of non-Hodgkin lymphoma (NHL) and soft tissue sarcoma (Kogevinas et al. 1995), based on an IARC registry of workers exposed to phenoxy herbicides, chlorophenols, and dioxins (Kogevinas et al. 1992), (2) two historical cohort studies of U.S. pentachlorophenol producers (Michigan and NIOSH) and (3) one cohort study of sawmill workers in Canada (Demers et al. 2006). The NIOSH study of pentachlorophenol producers cohort consisted of workers from four U.S. plants (Ruder and Yiin 2011), one of which was the Michigan plant studied by Ramlow et al. (1996) and later Collins et al. (2009b), so that part of the NIOSH cohort overlaps with the latter study. Exposure was assessed in the two producers studies based on individual work history and occupational hygiene data. The Canadian sawmill study assessed cumulative dermal exposure to pentachlorophenol and the IARC registry nested case-control study assessed exposure using individual work history and company records. A cross-sectional ecological assessment study of residents in a district of China contaminated with sodium pentachlorophenate was also identified (Zheng et al. 2013). A series of Swedish population-based case-control studies among populations in Sweden were identified for whom potential exposure to pentachlorophenol was established by self-administered questionnaire on complete occupational histories and specific exposures. These consisted of a series of studies of NHL (Hardell and Eriksson 1999; Hardell et al. 1994), or hairy cell leukemia, which is a subtype of NHL (Nordström et al. 1998), and a pooled analysis of four case-control studies of soft tissue sarcoma (Hardell et al. 1995). Hardell et al. (2002) reported on a pooled analysis of the hairy-cell leukemia and the 1999 NHL case-control studies. There was also a case-control study of residential exposure to pentachlorophenol, as assessed from carpet dust samples, and childhood acute lymphocytic leukemia (Ward et al. 2009) and a population-based case-control study of brain glioma (Ruder and Sweeney 2009).

Table 3-1 Human Cancer Studies of Exposure to Pentachlorophenol (PCP)

Primary Reference | Name of Study | Exposure Assessment | Cancer Endpoints
Cohort and nested case-control studies: PCP producers and users
Kogevinas et al. (1995); Kogevinas et al. (1992) | IARC registry-based nested case-control study | Individual exposure assessment based on company records | Mortality (OR) NHL, soft tissue sarcoma
Collins et al. (2009b) Ramlow et al. (1996) | Michigan PCP producers cohort | Individual exposure assessment (JEM for cumulative exposure) based on work history, industrial hygiene data and expert assessment Exposure to dioxin by-products based on biomonitoring data (subset of workers), work history and industrial hygiene data | Mortality (SMR, RR) All cancers and >20 specific cancers; detailed analyses for all cancers, NHL, and cancers of the lung and kidney in latest update (Collins et al. 2009b)
Ruder and Yiin (2011) | NIOSH PCP producers cohort | Individual exposure assessment (ever exposed) based on work history and industrial hygiene data | Mortality (SMR, SRR) All cancers and >20 specific cancers; more detailed analyses for NHL and lung cancer
Demers et al. (2006) | Canadian sawmill workers cohort | Individual exposure (dermal) assessment (cumulative) based on work history, expert assessment, and formulation data; calendar year and mill specific | Incidence/mortality (SIR, RR) All cancers and >20 specific cancers; more detailed analyses of NHL, multiple myeloma, soft tissue sarcoma, and cancer of the stomach, colon, rectum, liver, lung, and kidney
Ecological assessment study of PCP exposure
Zheng et al. (2015) | Chinese ecological study | Ecological assessment of residence in area sprayed with Na-PCP | Cross-sectional incidence rates and within region comparisons (SRR) All cancers and 17 specific cancers
Population-based case-control studies of PCP users
Hardell et al. (1994) | Swedish 1994 NHL study | Self- or proxy-reported structured questionnaire on lifetime occupational history and exposure to chlorophenols and phenoxy herbicides | Incidence (OR) NHL
Hardell and Eriksson (1999) | Swedish 1999 NHL study | Self- or proxy-reported structured questionnaire on lifetime occupational history and exposure to chlorophenols and phenoxy herbicides | Incidence (OR) NHL
Nordström et al. (1998) | Swedish HCL study | Self- or proxy-reported structured questionnaire on lifetime occupational history and exposure to chlorophenols and phenoxy herbicides | Incidence (OR) HCL
Hardell et al. (2002) | Swedish NHL/HCL pooled analysis | Self- or proxy-reported structured questionnaire on lifetime occupational history and exposure to chlorophenols and phenoxy herbicides | Incidence (OR) Combined NHL/HCL
Hardell et al. (1995) | Swedish soft tissue sarcoma pooled analysis | Self-reported questionnaire on lifetime occupational history, specific job categories, and leisure time information on exposure to chemicals | Incidence (OR) Soft tissue sarcoma
Ruder et al. (2009) | U.S. (4 mid-western States) glioma study | Extensive self-reported questionnaire on farming practices, jobs on farm, crops, livestock, use of pesticides, fertilizers, solvents, wood preservatives (PCP one of multiple exposures analyzed) | Incidence (OR) Glioma
Ward et al. (2009) | U.S. Northern California childhood leukemia study | Residential exposure to PCP assessed from PCP concentrations in carpet dust | Incidence Childhood acute lymphocytic leukemia

HCL = hairy-cell leukemia; LHC = lymphohematopoietic cancer; NHL = non-Hodgkin lymphoma; NIOSH = National Institute for Occupational Safety and Health; RR = relative risk; SIR = standardized incidence ratio; SMR = standardized mortality ratio; SRR = standardized rate ratio.

^a^ Pooled analysis of Hardell and Eriksson (1999) (NHL) and Nordström et al. (1998) (HCL).

^b^ The authors refer to this as a meta-analysis of four studies (Eriksson et al. 1990; Eriksson et al. 1981; Hardell and Eriksson 1988; Hardell and Sandstrom 1979); however, it appears to be more of a pooled analysis.

Not all the cohort studies reported all endpoints or reported comparable groups of cancer sites. Cancer endpoints were chosen for evaluation if there were detailed analyses (such as evaluation of exposure response relationships) on the endpoint from two or more studies: both case-control and cohort studies reported on NHL, soft tissue sarcoma and multiple myeloma and more than one cohort study provided detailed analyses for all cancers combined, and cancer of the kidney and lung. Liver cancer was also chosen for the evaluation because it is a site found in excess in animal studies.

Two case-control studies, the case-control study of brain glioma (Ruder et al. 2009) and the Northern California case-control study of childhood acute lymphocytic leukemia (Ward et al. 2009) were not included in the quality and cancer assessment because the overall database was considered to be inadequate to evaluate the evidence for the cancer sites reported by these studies (see Table C-2 and Table C-3 for details on the study characteristics and methodology). In the study of glioma (Ruder et al. 2009), a statistically significant increase in risk (OR = 4.55, 95% CI = 1.14 to 18.1, 6 cases) was observed among cases where proxy respondents were excluded, but not for all cases; however, no analysis for potential confounding by other pesticides or farm exposures was conducted. No other studies reported risk estimates specific for glioma. No statistically significant positive association was observed for exposure to residential pentachlorophenol exposure (as assessed by its concentrations in carpet dust) and childhood leukemia in the Northern California Study (Ward et al. 2009). Statistically non-significant risk estimates were elevated for some categories of exposure, but no positive exposure-response relationship was observed.

## 3.3 Assessment of the Quality of Individual Studies

This section discusses the assessment of study quality across individual studies and the utility of these studies to inform the evaluation of the potential effects of exposure to pentachlorophenol and cancer endpoints. Each study was assessed for the potential for biases and the adequacy of the ability to detect an effect and the adequacy of analytical methods, according to the guidelines for evaluating study quality described in the protocol for reviewing studies. Section 3.3.1 reports on the assessment of biases and other factors affecting study quality, Section 3.3.2 focuses on the assessment of potential confounding, and Section 3.3.3 integrates these assessments, reaching decisions on the utility of the individual studies to inform cancer identification.

### 3.3.1 Assessment of Potential Bias, Analytical Methods, and Other Study Quality Characteristics

#### Selection and Attrition Bias

Overall, selection bias is not a major concern (i.e., potential for bias is not probable) in the cohort or nested case-control studies. The potential for selection bias is generally considered to be unlikely in occupational cohort studies, with the exception of the healthy worker (hire or survival) effect in studies using external comparison populations. Both a healthy worker hire effect and a healthy worker survival effect would tend to bias towards the null, so that positive associations are unlikely to be biased upward. The potential for a healthy worker hire effect can be indirectly assessed based on observed differences between all-cause and all-cancer mortality or incidence rates; no strong evidence of a healthy worker hire effect was identified in any of the cohort studies. No analyses were done in these studies to determine whether there was a healthy worker survival effect. However, the high proportion of short-term workers in the two pentachlorophenol producers cohorts (Collins et al. 2009b; Ruder and Yiin 2011) could suggest a possible healthy worker survival effect, if workers left or were re-assigned due to ill-health. In the IARC registry-based nested case-control study (Kogevinas et al. 1995) there is no a priori reason to assume selection bias in the original cohort, or in the cancer-registry-based identification of cases. Loss to follow-up is minimal in the U.S. pentachlorophenol producers cohorts (Collins et al. 2009b; Ruder and Yiin 2011) and the Canadian sawmill cohort (Demers et al. 2006). The potential for attrition bias was assessed via loss of follow-up in the cohort studies. None of the cohort studies report >4% loss to follow-up across the cohort, and thus, the potential for attrition bias was considered to be unlikely or minimal.

In general, the cases and controls in the population-based case-control studies of pentachlorophenol were selected from the same population and matched on age, geographical location, and other appropriate factors. There was no evidence that the cases and controls were selected on criteria related to exposure and thus the potential for selection bias was not a serious concern (i.e., was not considered to be probable) in these studies.

Non-participation rates were lowest (<10%) in the Swedish 1994 NHL (Hardell et al. 1994) and soft tissue sarcoma pooled case-control studies (Hardell et al. 1995) and somewhat higher (≤20%) in the other Swedish studies (Hardell and Eriksson 1999; Nordström et al. 1998). Although participation rates are lower among controls than cases in some studies (Hardell and Eriksson 1999; Nordström et al. 1998), there is no other information to suggest that any such differences would be specifically related to potential exposure to pentachlorophenol.

In the cross-sectional ecological assessment study in China (Zheng et al. 2015), selection bias would not be a risk if cancer registry data are mostly complete for each district in the study, but there is insufficient information in this study to evaluate the quality and completeness of the cancer registry data.

#### Information Bias: Exposure Assessment

The adequacy of the characterization of intensity or duration of exposure to pentachlorophenol was assessed based on whether quantitative or semi-quantitative levels of pentachlorophenol exposure were estimated or reported, using either ambient air monitoring, knowledge of fungicide formulation, estimation of dermal exposure, or biomonitoring data. In general, the potential for misclassification in these studies was considered to be non-differential, as discussed below.

Studies considered to have good or adequate exposure assessments include the Canadian sawmill worker study (Demers et al. 2006), the Michigan pentachlorophenol producer study (Collins et al. 2009b), and to a lesser extent the NIOSH study of pentachlorophenol producers (Ruder and Yiin 2011), and the IARC registry-based nested case-control study (Kogevinas et al. 1995). The most detailed exposure characterization was conducted in the Canadian sawmill study by Demers et al. (2006), who used individual exposure assessments of cumulative full-time equivalent dermal exposure for exposure-constant calendar periods, using worker assessments of dermal exposure by job type validated by urine sampling and industrial hygienists, together with detailed information on the different formulations of pentachlorophenol and tetrachlorophenol-containing wood preservatives over time (Fenske et al. 1987; Hertzman et al. 1988; Teschke et al. 1989; Teschke et al. 1996). Pentachlorophenol was the main wood preservative used in the sawmills from 1941 to 1965, whereas tetrachlorophenol was mainly used from 1965 on.

Exposure in the Michigan pentachlorophenol producers study was assessed differently in the two updates. In the earlier update of this cohort, Ramlow et al. (1996) used individual work histories by job title and department, expert knowledge (veteran employees), and industrial data to calculate cumulative exposure to pentachlorophenol. In the latter update, Collins et al. (2009b) assessed past exposure to higher chlorinated dioxins (1,2,3,4,7,8-hexachlorodibenzo-p-dioxin [1,4-HxCDD], 1,2,3,6,7,8-hexachlorodibenzo-p-dioxin [1,6-HxCDD], 1,2,3,7,8,9-hexachlorodibenzo-p-dioxin [1,9-HxCDD], 1,2,3,4,6,7,8-heptachlorodibenzo-p-dioxin [HpCDD], and octachlorodibenzo-p-dioxin [OCDD]) that are by-products of pentachlorophenol synthesis (see Section 1) and to 2,3,7,8-TCDD. Briefly, the exposure assessment characterization of the earlier study was used to group pentachlorophenol-exposed jobs into different exposure categories. The authors then measured serum chlorinated dioxin levels from a subset of workers, selected to be representative of time spent in the different exposure categories (see Collins et al. (2007)), and used pharmacokinetic modeling and work history information to estimate past dioxin levels for jobs in each exposure category including background exposure to dioxins (including 2,3,7,8-TCDD). The dose rates were integrated with work histories to estimate individual dioxin congener levels for each individual member of the entire pentachlorophenol cohort, including the 196 members with co-exposure to trichlorophenol. Some errors in the models used to estimate past exposure levels may arise because of the limited number of samples used to create the serum by-product profiles and in the pharmacokinetic models used to predict past exposure. Half-life of dioxins is dependent upon body fat composition and peak exposure. The greater the percent body fat, the longer the half-life, particularly at low to moderate exposures. Dioxins also induce their own metabolism, such that at higher exposures they have a faster elimination (Emond et al. 2006). If the pharmacokinetic model used to extrapolate back to blood levels does not account for changes in body fat composition or dose dependency over time, it is possible for misclassification of exposure at the low and medium exposure categories. Misclassification is not a concern for individuals in the highest chlorinated dioxin category; it is very likely that these workers were exposed to pentachlorophenol.

The NIOSH study (Ruder and Yiin 2011) conducted extensive independent ambient air monitoring in each of the four participating plants, indicating that workers included in the pentachlorophenol departments were exposed to measurable levels of pentachlorophenol; however, data were inadequate to evaluate exposure levels for individual workers, and thus the assessment was not considered to be as good as the Michigan study. With respect to the nested case-control study based on the IARC registry cohort, detailed exposure assessments based on questionnaires, work histories, and employment and industrial hygiene records were used to assign categories of cumulative exposure.

Exposure assessment for each of the population-based case-control studies is generally more limited than for the cohort studies. The Swedish case-control studies rely either on self- or proxy report of lifetime use of pentachlorophenol-containing wood preservatives or related pesticide uses (Hardell and Eriksson 1999; Hardell et al. 1994; 1995; Nordström et al. 1998). The study authors reported that a validation study of the questionnaire used in two of the Swedish studies (Hardell et al. 1994; 1995) found a 97% agreement between information from self-reported exposure and employers (sawmill and pulp industry); however, sufficient information was not provided on the methods and findings for this study. The potential for recall bias about exposures might also have been reduced given that subjects were asked about multiple specific exposures and appear to have been unaware of the specific hypotheses being tested in the studies. There is some concern that individuals with little exposure to pentachlorophenol may have been considered to be exposed; the authors (Hardell et al. 1994; 1995) defined high-grade exposure as ≥1 week (continuous) or ≥1 month (total); however, ranges, average exposure duration, or exposure levels were not reported.

In the Chinese ecological study (Zheng et al. 2013), exposure was assessed based on estimated cumulative application of pentachlorophenol to soil and water for snail eradication, but it is not clear how accurately this measure reflects actual community exposure, or how data on duration of individual residents’ exposure (used in comparative analyses of cancer incidence by duration of exposure across districts with different amounts of pentachlorophenol application) were obtained or analyzed, and thus whether cumulative exposure by district was valid. The use of an ecological study design, involving large-scale aggregate data also means that limited inferences can be made about cancer risk at the individual level.

#### Information Bias: Disease Endpoints

The potential for differential and non-differential misclassification of cancer endpoints depends on the accuracy and completeness of ascertainment of vital status or diagnosis and varies depending on the cancer endpoint under consideration.

With respect to NHL, multiple myeloma, and soft tissue sarcoma, mortality data are less informative than incidence data, in part because these cancers, particularly soft tissue sarcoma, require histological confirmation for accurate and complete diagnosis, and in part because these cancer endpoints have been associated with a fairly wide range of survival times, including some long-term survivors, and thus incidence data more accurately reflect the risk of disease than mortality data. In addition, the classification systems for lymphohematopoietic cancers, including NHL and multiple myeloma, have changed since the 1980s and some non-differential misclassification of these cancers may be possible, depending on the year of the study. The Canadian sawmill cohort (Demers et al. 2006) is the most informative cohort study for evaluating NHL, multiple myeloma, and soft tissue sarcoma because it reported cancer registry-based incidence, and soft tissue sarcoma cases were histologically confirmed. The study also reported on mortality similar to the two U.S. pentachlorophenol producer studies (Ruder and Yiin 2011) and (Collins et al. 2009b). In the IARC registry-based nested case-control study, cases of NHL and soft tissue sarcoma were identified from death certificates and cancer registries.

A strength of the case-control studies is the use of cancer incidence data, and histological confirmation of cases of NHL (Hardell and Eriksson 1999; Hardell et al. 1994), and soft tissue sarcoma (Hardell et al. 1995). Cancer misclassification is therefore considered to be minimal in these studies. It is not clear whether hairy-cell leukemia cases identified by Nordström et al. (1998) were histologically confirmed or re-reviewed. The quality of the cancer incidence data in the Chinese ecological assessment study (Zheng et al. 2015) cannot be evaluated.

With respect to the solid tumors of a priori concern, i.e., cancers of the kidney and liver, diagnosis tends to be more accurate and average survival times may be shorter than for some lymphohematopoietic cancers, so the mortality cohort studies as well as incidence studies are informative. Only the NIOSH pentachlorophenol producers study reported multiple causes of death data, however, which could identify more cases of both solid and lymphohematopoietic cancers than underlying cause of death data alone (Ruder and Yiin 2011).

#### Ability to Detect an Effect and Adequacy of Analytical Methods

Factors that affect the ability of a given study to detect an association, if present, include statistical power, the length of follow-up, which should be sufficient to detect long latency cancers, and the levels, range, and duration of exposure to pentachlorophenol. In addition, analytical methods should ideally include internal analyses (for cohort studies), exposure-response analyses, and appropriate assessment of, and if necessary, adjustment for, potential confounding. Among the cohort studies, the Canadian sawmill workers study (Demers et al. 2006) is considered to have good ability to detect an effect, based on the statistical power to detect relatively rare cancers such as soft tissue sarcoma, and adequate follow-up (approximately 45 years for mortality, 25 years for incidence). The NIOSH pentachlorophenol producers cohort (Ruder and Yiin 2011) has adequate ability to detect an effect for most of the cancer endpoints of interest, but limited ability to detect an effect for soft tissue sarcoma, which is a rare outcome. The Michigan pentachlorophenol producers cohort (Collins et al. 2009b) has limited ability to detect an effect based on smaller numbers of exposed workers, although the length of follow-up is adequate in both cohorts.

With respect to the quality of analyses, the Canadian sawmill study (Demers et al. 2006) included the most informative analyses. Both external and internal incidence and mortality analyses (by estimated cumulative dermal exposure) were analyzed for workers exposed to pentachlorophenol and separately for the principal co-exposure (in this study, tetrachlorophenol). The NIOSH (Ruder and Yiin 2011) and Michigan (Collins et al. 2009b) pentachlorophenol producers studies each conducted external analyses separately for workers exposed only to pentachlorophenol as well as pentachlorophenol and the principal co-exposure, 2,4,5-trichlorophenol, but internal analyses by cumulative exposure or duration of exposure were conducted for only selected outcomes for the combined cohort. None of the available cohort studies conducted multivariate analyses in which co-exposures or other potential confounders were examined.

Case-control studies are usually more informative for studying rare cancers and there were relatively larger number of exposed cases in the Swedish combined analyses of NHL and HCl (Hardell et al. 2002) and pooled analysis of soft tissues sarcoma. However, the overall ability to detect an effect (if there is a true effect) in all the Swedish case-control studies (Hardell et al. 1994; 1995; Hardell et al. 2002) was considered limited because (1) the portion of pentachlorophenol-exposed subjects in the case-control studies was relatively low (ranging from 3% to 12% in controls) across studies, (2) exposure misclassification was considered to be probable because of a lower quality exposure assessment, and (3) lack of information on exposure levels or range of exposure. The ability to detect an effect in the cross-sectional Chinese ecological study (Zheng et al. 2015) is unclear in the absence of reported population size in different exposure areas, and the 2-year window for cancer incidence.

### 3.3.2 Assessment of Methods (or Available Information) to Evaluate Potential Confounding by Occupational Co-exposures or Other Risk Factors

As mentioned in Section 1, the candidate substance is defined as pentachlorophenol and by-products of its synthesis and thus the higher chlorinated dibenzodioxins (hereinafter called dioxins) formed during the synthesis of pentachlorophenol are not considered to be potential confounders. The evaluation of the potential for confounding from occupational exposures and other risk factors will be discussed in the cancer assessment for each endpoint of interest because whether a co-exposure is a potential confounder depends on whether it is a risk factor for a specific cancer in addition to being associated with exposure to pentachlorophenol. This section will provide a brief discussion on the methods or other data relevant to evaluating potential confounding from occupational co-exposures.

Table 3-2 lists the potential occupational co-exposures for each study and study methods or information relevant for evaluating the potential for confounding. The available studies include sawmill workers and pentachlorophenol production workers, and the types of co-exposures differ between the two groups. Most of the pentachlorophenol exposure in the Swedish population-based case-control studies (Hardell and Eriksson 1999; Hardell et al. 1994; 1995; Nordström et al. 1998) appears to be among workers in sawmills or the pulp industries. Almost none of the studies examined potentially confounding co-exposures or other risk factors, although some studies evaluated tobacco smoking as an independent risk factor. However, there are few known risk factors for several of the cancers of interest (soft tissue sarcoma, NHL, and multiple myeloma, see Section 3.4), and tobacco smoking is not a risk factor for these types of cancer, although an association between smoking and a type of NHL was found in the Interlymph Study (Morton et al. 2005). The Michigan (Collins et al. 2009b) and NIOSH (Ruder and Yiin 2011) pentachlorophenol production workers cohort studies also included workers exposed to 2,4,5-trichlorophenol and thus to 2,3,7,8-TCDD, its by-product. The exposure assessment for trichlorophenol differed between the two studies. The Michigan study classified workers as exposed to trichlorophenol if they directly worked with trichlorophenol, whereas the NIOSH study classified workers as exposed to trichlorophenol if they were directly exposed to trichlorophenol or worked in a building where trichlorophenol processes were co-located (Ruder, personal communication). The NIOSH study thus considered more workers at the Michigan plant (675) to be exposed to both trichlorophenol and pentachlorophenol than the Michigan study (196).

Table 3-2 Occupational Co-exposures and Methods Relevant for Evaluating Confounding

Study or Studies | Co-exposures | Methods Relevant to Evaluating Confounding
Pentachlorophenol producers: nested case-control or cohort studies
Kogevinas et al. (1995) | Definite exposure^a^ None No occupational exposure to other chlorophenols, phenoxy herbicides, and dioxins documented in British PCP producers cohort No relevant information on other chemicals | Internal analysis (nested case-control analysis; controls also potentially exposed to the same chemicals) No analysis of potential confounding
Collins et al. (2009b); Ramlow et al. (1996) | Definite exposure^a^ TCP: 25% of workers 2,3,7,8-TCDD: mainly as a result of TCP contaminant, slightly higher levels in PCP-only workers compared with reference Possible exposure: List of other chemicals with potential exposure (from Ruder and Yiin^b^) | Separate analysis for PCP versus PCP and TCP combined Exposure-response analysis for some cancer sites (internal and external analyses) Biomonitoring data available for 2,3,7,8-TCDD
Ruder and Yiin (2011) | Definite exposure^a^ 2,4,5-TCP: 33% of PCP production workers 2,3,7,8-TCDD: mainly as a result of TCP contaminant Possible exposure: Other chemicals: 90% of all workers exposed; list of chemicals with potential exposure specific for each plant^b^ | Separate analysis for PCP versus PCP and TCP combined Exposure duration analysis for some cancer sites (internal and external analyses) Analysis by plant for some tumor sites
Pentachlorophenol users: Sawmill workers
Demers et al. (2006) | Definite exposure^a^ Correlation coefficient for PCP and TeCP = 0.45; dermal exposure assessment for PCP and TeCP Copper chrome arsenate and creosote not used Possible exposure: inferred Wood dust | Separate analyses for pentachlorophenol, TeCP, and combined TeCP and PCP; cumulative exposure-response analyses (internal and external)
Pentachlorophenol users: Case-control studies
Swedish case-control studies Hardell and Eriksson (1999); Hardell et al. (1994; 1995); Nordström et al. (1998) | Definite exposure^a^ none Possible exposure: inferred Phenoxyacetic acids Sawmills: wood dust, copper chrome arsenate or creosote Pulp and paper: formaldehyde | Hardell et al. (1994) conducted multivariate analysis adjusting for exposure to other pesticides; Earlier report Hardell (1981) of lymphoma (which includes NHL cases reported by Hardell et al. (1994) and one of the four STS case-control studies Hardell and Sandstrom (1979) included analyses that excluded cases and controls exposed to phenoxyacetic acids. Some analyses for latency or level/duration of exposure

NHL = non-Hodgkin lymphoma; PCP = pentachlorophenol; STS = soft tissue sarcoma; 2,4,5-TCP = 2,4,5-trichlorophenol; 2,3,7,8-TCDD = 2,3,7,8-tetrachlorodibenzo-p-dioxin; TeCP = tetrachlorophenol.

^a^ Definite exposure is defined as a co-exposure that is specifically identified by the authors of the publication.

^b^ Specific co-exposures are discussed in the cancer evaluation of specific cancer sites, if they are risk factors for that cancer.

In addition, the production workers were exposed to other chemicals that were produced at the same plants. The NIOSH pentachlorophenol producers study (Ruder and Yiin 2011) provided a detailed list of occupational co-exposures at the four plants, but not at the individual worker level, and there are no data on the extent or levels of potential exposure to these agents. It is also possible that cases identified in the nested case-control study (Kogevinas et al. 1995) in association with the pentachlorophenol production plant may have had other co-exposures. Whether or not these co-exposures have a potential for confounding also depends on the specific cancer site. Sawmill workers (Demers et al. 2006) are potentially exposed to other chlorophenols, primarily tetrachlorophenol and wood dust; creosote and copper chrome arsenate were not used regularly in the sawmills in Canada, however (Demers, personal communication). While the technical grade formulation of tetrachlorophenol also contains hexa- and octachlorinated dibenzodioxin by-products, it has not been found to contain 2,3,7,8-TCDD.

Most of the population-based case-control studies were undertaken in rural and agricultural populations, and exposure to other wood impregnating agents (such as copper chrome arsenate or creosote) is possible. There is potential for exposure to formaldehyde (in the pulp industries) and to other pesticides, including phenoxyacetic acids and other chlorophenols; however, no information on co-exposures was provided. Potential confounding by other exposures or risk factors that differ across the districts under investigation may be a major concern in the ecological study of environmental exposure to pentachlorophenol reported by Zheng et al. (2013), but they were not identified or evaluated in this study.

Most of the studies did not consider or adjust for potential confounding from occupational co-exposures in formal statistical analyses. However, some studies provide other information or analyses that can help evaluate the potential for confounding. The two cohort studies of pentachlorophenol producers (Collins et al. 2009b; Ruder and Yiin 2011) conducted separate analyses on workers exposed to pentachlorophenol alone versus pentachlorophenol and trichlorophenol combined, and the Canadian sawmill cohort study (Demers et al. 2006) provided separate estimates (including exposure-response relationships) on pentachlorophenol, tetrachlorophenol and both chlorophenols combined. In addition, internal analyses and exposure-response analyses help mitigate concerns from confounding unless the confounder is highly correlated with exposure to pentachlorophenol. Multivariate analyses, which included total chlorinated phenols (of which pentachlorophenol was predominant), DDT, phenoxyacetic acids, and organic solvents were conducted in the Swedish 1994 study; however, residual confounding may be possible if the co-exposures are highly correlated. In addition, an early report (Hardell 1981) of malignant lymphomas that included the NHL cases reported in the 1994 Swedish study (Hardell et al. 1994) and one of the individual case-control studies (Hardell and Sandstrom 1979)that contributed to the pooled case-control study on soft tissue sarcoma (Hardell et al. 1995) conducted analyses that excluded cases and controls exposed to phenoxyacetic acids.

Table 3-3 lists the major tumor site(s) associated with co-exposures across studies. (An evaluation of potential confounding from co-exposures in the individual studies is discussed in the cancer assessment, in relation to each cancer endpoint of interest.) None of the co-exposures that are classified as known human carcinogens cause cancer (sufficient evidence) at the tumor sites of interest; however, there is limited evidence in humans at these sites for some of these exposures.

Table 3-3 Carcinogenicity Information (in Humans) for Occupational Co-exposures^a^

| Sufficient Evidence | Limited Evidence | Classification
Polychlorinated phenols (all)^b^ 2,4,5-TCP TeCP | – | NHL, STS Not evaluated No studies | IARC: Group 2B RoC: RAHC; IARC: Group 3
2,3,7,8-TCDD | All cancers combined | NHL, STS, lung | RoC: Known human carcinogen IARC: Group 1
Formaldehyde | Myeloid leukemia, nasal cavity and paranasal sinus^c^ and nasopharynx | – | RoC: Known human carcinogen IARC: Group 1
Wood dust | Nasal cavity and paranasal sinus ^b^and nasopharynx | – | RoC: Known human carcinogen IARC: Group 1
Creosotes (coal-based) | – | Skin | IARC: Group 2A
Phenoxy herbicides | – | Several sites (possibly NHL and STS) | IARC: Group 2B

IARC Group 1: The agent is carcinogenic to humans.

IARC Group 2A: The agent is probably carcinogenic to humans.

IARC Group 2B: The agent is possibly carcinogenic to humans.

IARC Group 3: The agent is not classifiable as to its carcinogenicity to humans.

NHL = non-Hodgkin lymphoma; STS = soft tissue sarcoma; IARC = International Agency on Research on Cancer; RoC = Report on Carcinogens; RAHC = reasonably anticipated to be a human carcinogen; 2,3,7,8-TCDD = 2,3,7,8-tetrachlorodibenzo-p-dioxin; 2,4,5-TCP = 2,4,5-trichlorophenol; TeCP = tetrachlorophenol.

^a^ Occupational co-exposures (other than TCP, TeCP and 2,3,7,8-TCDD) in the United States are discussed in the cancer evaluation of specific cancer sites, if they are risk factors for that cancer.

^b^ Includes exposure to pentachlorophenol.

^c^ IARC classifies nasal cavity and paranasal sinus as limited, whereas the RoC classifies the evidence as sufficient.

### 3.3.3 Summary of the Utility of the Studies to Inform the Cancer Evaluation

Based on the methodological evaluation of the adequacy of study design, adequacy of exposure and disease assessment of cancer incidence or mortality, and the ability to detect an effect of pentachlorophenol on multiple cancer endpoints (NHL, soft tissue sarcoma, and liver or kidney cancer) the following studies were considered to have good or adequate utility to inform the cancer evaluation: the large Canadian sawmill cancer incidence and mortality study (Demers et al. 2006), the NIOSH (Ruder and Yiin 2011) and Michigan (Collins et al. 2009b) mortality cohort studies of pentachlorophenol producers, the IARC registry-based nested case-control study (Kogevinas et al. 1995). The series of Swedish case-control studies of NHL and soft tissue sarcoma (Hardell and Eriksson 1999; Hardell et al. 1994; 1995; Hardell et al. 2002; Nordström et al. 1998) were considered to be of lower quality because of their more limited exposure assessment and the low prevalence of exposure specific to pentachlorophenol.

Of these studies, the Canadian sawmill cohort (Demers et al. 2006) is the most informative based on the following: a large population of exposed workers, very low loss to follow-up, adequate duration of follow-up, analysis of both cancer incidence and mortality data, characterization of dermal exposure and evaluation of exposure-response relationships. The main strengths of the NIOSH and Michigan pentachlorophenol producer studies are the utilization of individual exposure characterization and complete and adequate duration of follow-up (Collins et al. 2009b; Ruder and Yiin 2011). The principal limitations are the use of mortality-only data, lower statistical power, and limited examination of potential confounding by co-exposure to trichlorophenol or other agents. The Michigan study was considered to be the more informative of the two producers studies because of its assessment of exposure-response relationships in both the earlier (Ramlow et al. 1996) and later follow-ups (Collins et al. 2009b). The IARC registry-based nested case-control study of NHL and soft tissue sarcoma (Kogevinas et al. 1995) had an adequate study design based on the collection of detailed exposure data but the small numbers of exposed workers limited its ability to detect an effect (if present). The Swedish population-based case-control studies have the advantage of greater statistical power to detect less common cancer endpoints, and good disease ascertainment, but the exposure assessment is more limited and there are concerns in some of them about potential confounding from occupational co-exposures.

The Chinese ecological study (Zheng et al. 2013) was considered to be inadequate for the full evaluation based on lack of documentation and its ecological design.

## 3.4 Cancer Assessment

This section summarizes and interprets the findings from the individual studies and then synthesizes the evidence for each cancer endpoint across the body of studies. Cancer sites of interest in the evaluation include non-Hodgkin lymphoma, multiple myeloma, soft tissue sarcoma, and cancers of the liver, lung, and kidney. The key question for evaluating the level of evidence across the body of studies is whether any observed associations between pentachlorophenol exposure and each cancer endpoint with sufficient data for evaluation could be explained by chance, bias, or confounding by co-exposures or other risk factors. Several of the guidelines developed by Austin Bradford Hill (Hill 1965) are relevant to the evaluation of the level of evidence for human carcinogenicity, including the magnitude (strength) and consistency of any observed associations across studies; evidence for exposure-response relationships and associations with appropriate latency; and the degree to which chance, bias, and confounding could plausibly explain observed associations. Observed associations from methodologically limited studies or negative findings from such studies are given less weight in the overall evaluation than findings from methodologically strong studies.

### 3.4.1 Individual Studies

As noted, the focus of the majority of case-control studies is on non-Hodgkin lymphoma, multiple myeloma or all lymphomas, or soft tissue sarcoma. Available data on these endpoints are presented for both cohort and case-control studies in Table 3-4 and Table 3-5 for NHL and multiple myeloma and Table 3-6 for soft tissue sarcoma. Findings for kidney and liver cancer and all cancers combined are presented in Table 3-7.

Table 3-4 NHL Mortality and Exposure to Dioxin Congeners: Michigan Pentachlorophenol Producers Cohort Study Collins et al. (2009b)^a^

Dioxin Congener | Level of Congener^a^ SMR (95% CI); # Exposed Deaths
Dioxin Congener | Low | Medium | High
2,3,7,8-TCDD^b^ | 1.6 (0.2–5.7); 2 | 2.8 (0.6–8.1); 3 | 3.1 (0.6–9.1); 3
HxCDDs | 2.5 (0.5–7.4); 3 | 0.0 (0.0–3.1); 0 | 5.3 (1.7–12.4); 5
HpCDD | 1.8 (0.2–6.4); 2 | 1.5 (0.2–5.5); 2 | 4.6 (1.3–11.8); 4
OCDD | 1.7 (0.2–6.2); 2 | 1.6 (0.2–5.6); 2 | 4.7 (1.3–12.0); 4
TEQ | 2.4 (0.5–7.2); 3 | 0.8 (0.0–4.7); 1 | 4.5 (1.2–11.6); 4

HpCDD = 1,2,3,4,6,7,8-hepta-chlorodibenzo-p-dioxin; HxCDD = 1,2,3,4,7,8-hexachlorodibenzo-p-dioxin (1,4-HxCDD) or 1,2,3,6,7,8-hexachlorodibenzo-p-dioxin (1,6-HxCDD) or 1,2,3,7,8,9-hexachlorodibenzo-p-dioxin (1,9-HxCDD); OCDD = octachlorodibenzo-p-dioxin; 2,3,7,8-TCDD = 2,3,7,8-tetrachlorodibenzo-p-dioxin; TEQ = toxic equivalent calculated using WHO recommended weights for 2,3,7,8-TCDD, HxCDDs, HpCDD, and OCDD combined.

^a^ Estimated cumulative levels of congeners (ppb-years) were divided into low, medium, and high levels so that approximately equal numbers of deaths were assigned to each of the three categories.

^b^ According to the paper, 196 of 773 workers were exposed to 2,3,7,8-TCDD, and only 1 NHL was observed in this group. The exposure assessment also included background levels of dioxin, and thus, analysis of 8 NHL deaths most likely reflects background levels of 2,3,7,8-TCDD.

Table 3-5 NHL and Multiple Myeloma among Pentachlorophenol-exposed Populations

Reference | Study Name Population Exposure Assessment | Exposure Group (N) | External Analysis: SMR or SIR (95%CI); # Exposed Deaths or Cases | Internal Analysis: OR, SRR or RR; (95% CI); # Exposed Cases or Cases/Controls | Interpretation
Cohort and nested case-control studies with specific exposure information for pentachlorophenol
Ruder and Yiin (2011) | NIOSH PCP producer cohort 2,122 male and female PCP production workers at 4 plants Qualitative evidence of exposure assessment based on individual work/job/dept histories and investigators’ industrial hygiene studies | PCP no TCP (1,402) PCP + TCP (720) Total cohort (2,122) Employment duration (days) in PCP department Total cohort ≤57 58–<182 182–<650 ≥650 Analyses by plant Sauget, IL (788) Midland, MI (939) Other 2 plants (total 395) PCP no TCP (1,402) PCP + TCP (720) Total cohort (2,122) | [underlined: NHL: SMR]: 1.41 (0.64–2.67); 9 2.50 (1.08–4.93); 8 1.77 (1.03–2.84); 17 2.45 (0.90–5.34); 6 1.56 (0.42–3.99); 4 1.63 (0.45–4.18); 4 1.42 (0.29–4.14); 3 1.81 (0.83–3.43); 9 2.18 (0.94–4.30); 8 0 deaths [underlined: Multiple myeloma: SMR] 1.84 (0.68–4.00); 6 0.72 (0.02–3.99); 1 1.50 (0.60–3.10); 7 | [underlined: NHL: SMR] 1.0 0.55 (0.15–1.97); 4 0.63 (0.18–2.28); 4 0.62 (0.15–2.55); 3 | Adjusted for age, sex, and calendar year Some evidence of increase in risk of NHL among workers exposed to PCP and PCP+TCP; however, potential confounding from occupational co-exposures is possible Overall quality of evidence: limited
Collins et al. (2009b); Ramlow et al. (1996) | Michigan PCP producer cohort study 773 male PCP production workers, Midland, MI plant from NIOSH cohort Ramlow: Exposure assessment based on work history, industrial hygiene data, and expert assessment Collins: Exposure assessment based on individual work/job histories and model exposure to chlorophenol dioxin by-products, and 2,3,7,8-TCDD TEQ | [underlined: Ramlow et al. (1996)] PCP 15-yr lag Cumulative exposure ≥1 unit (PCP) 15-yr lag cumulative exp Low High [underlined: Collins et al. (2009b)] PCP no TCP (577) Total cohort (773) OCDD^b^ (ppb-years) [underlined: Cumulative (discrete)] 0.01–0.69 0.70–3.99 4.00–113.37 p_trend_ [underlined: TEQ^c^ continuous exposure] p_trend_ | [underlined: NHL & MM^a^: SMR:] 2.0 (0.54–5.12); 4 [underlined: All LHC^b^: SMR] NR; 1 death 1.8 (0.48–4.61); 4 [underlined: NHL: SMR] 2.8 (1.1–5.7); 7 2.4 (1.0–4.7); 8 1.7 (0.2–6.2); 2 1.6 (0.2-5.6); 2 4.7 (1.3–12.0); 4 NR | [underlined: NHL & MM^a^ RR] 2.58 (0.98–6.80); 4 [underlined: All LHC^b^: RR] NR: no deaths 2.01 (0.90–4.45); 4 [underlined: NHL: RR] 1.006 (0.960–1.054) 0.80 | All analyses adjusted for age and calendar year, in addition, internal analyses of cumulative exposure adjusted for employment stats and TEQ adjusted for hire year and birth year Evidence of an association between exposure to PCP and lymphoma or NHL based on analysis of cumulative exposure and hexa-, hepta-, and octachlorinated dibenzodioxins, which are by-products of PCP Overall quality of evidence: adequate – high
Demers et al. (2006); Friesen et al. (2007) | Canadian sawmill workers cohort Male sawmill workers (N = 27,464) Cumulative exposure assessment based on individual work/job histories, expert assessment; validated on a subset of workings using urine samples | Total cohort Mortality Incidence Cumulative exp (exp year) [underlined: Mortality] <1 1–2 2–5 5+ p_trend_ [underlined: Incidence, 20-year lag] <1 1–2 2–5 5+ p_trend_ Total cohort Mortality Incidence | [underlined: NHL] SMR 1.02 (0.75–1.34); 49 SIR 0.99 (0.81–1.21); 92 [underlined: Multiple myeloma: SMR] SMR 0.94 (0.60–1.41); 23 SIR 0.80 (0.52–1.18); 25 | [underlined: NHL: RR] 1.0; 15 1.21 (0.46–3.15); 6 2.44 (1.17–5.11); 18 1.77 (0.75–4.21); 10 0.06 1.0; 46 1.83 (0.95–3.50); 13 2.05 (1.14–3.68); 24 1.98 (0.97–4.21); 13 0.02 | RR adjusted for age, calendar period, and race Positive exposure-response relationship observed in internal analysis of NHL and multiple myeloma incidence (lagged and unlagged) and mortality. Potential confounding by TeCP unlikely to explain increase in risk for NHL and MM Overall quality of evidence: high
| | Cumulative exp (exp year) [underlined: Mortality] <1 1–2 2–5 5+ p_trend_ [underlined: Incidence, 20-year lag] <1 1–2 2–5 5+ p_trend_ | | [underlined: Multiple myeloma: RR] 1.0; 4 3.30 (0.87–12.51); 5 1.58 (0.38–6.63); 4 4.80 (1.39–16.54); 10 0.03 1.0; 8 1.72 (0.43–6.95); 3 2.05 (0.62–6.78); 6 3.84 (1.20–12.3); 8 0.03
Kogevinas et al. (1995) | IARC registry-based nested case-control study of NHL 32 cases/158 controls IARC registry cohort of 21,183 phenoxy herbicide- chlorophenol-, and dioxin-exposed workers in 11 countries Exposure assessment based on individual work/job histories and plant records | Lagged 5 years Ever exposed Cumulative exposure No exposure Low exposure Medium exposure High exposure | | [underlined: OR] 2.75 (0.45–17.00); 3/9 1.0; 29/149 0/2 0/2 4.19 (0.59–29.59); 3/5 | PCP exposure limited to one cohort without exposure to other phenoxy herbicides or chlorophenols Adjusted (via matching) by age, sex, and country of residence Small numbers of exposed cases and controls Overall quality of evidence: adequate
Population-based case-control studies
Hardell et al. (1994); Hardell et al. (1981) | Swedish 1994 case-control study of NHL Males 25–85 yr old Diagnosed 1974–1978 105 cases/335 controls Structured questionnaire (self or proxy) for information on lifetime working history and exposures | High grade exposure (>1 wk continuous or >1 month total) | | OR 8.8 (3.4–24.0); 15/9 | Potential exposure misclassification based on the use of self-reported or proxy questionnaire data. Questionnaire reported to be validated but no details provided. Adjusted for age, and vital status; analysis of chlorophenols adjusted for exposure to solvents, phenoxyacetic acids, DDT, and asbestos Overall quality of evidence: limited
Hardell and Eriksson (1999) | Swedish 1999 case-control study of NHL Males ≥25 yr old Diagnosed 1987–1990 404 cases/741 controls Structured questionnaire (self or proxy) for lifetime work history and exposures | PCP exposure Latency period (yr) 1–10 10–20 20–30 >30 | | 1.2 (0.7–1.8); 55/87 0 cases/4 controls 1.0 (0.3–2.9) 2.0 (0.7–5.3) 1.1 (0.7–1.8) | Potential exposure misclassification from the use of self and proxies for exposure information Adjusted for age, sex, year of death, or county of residence. No excess risk of NHL from cigarette smoking or use of oral snuff. Cannot rule out potential for confounding; no analysis or consideration of co-exposures or other risk factors Overall quality of evidence: limited
Nordström et al. (1998); HCL Hardell et al. (2002) (combined HCL and NHL from Hardell and Eriksson (1999)and Nordström et al. (1998)) | Swedish HCL case-control study and pooled analysis of HCL+NHL Males, diagnosed from 1987–1992 111 HCL cases, 400 controls Structured questionnaire (self-reported) lifetime work history and exposures. Minimum exposure 1 day, and induction period 1 year | Ever exposed to PCP (impregnating agent) Ever exposed to PCP Time (yr) from 1^st^ exp. 1–10 >10–20 >20–30 >30 | | [underlined: HCL] 2.6 (1.1–6.2); 9/14 [underlined: Combined NHL & HCL] 1.40 (0.99–1.98); 64/101 0 exposed cases/controls 1.91 (0.82–4.44); NR 2.13 (1.07–4.25); NR 1.13 (0.73–1.72); NR | Pooled analysis (HCL and NHL) adjusted for age, study, study area, and vital status. Cigarette smoking was not a risk factor for HCL in this study. Cannot rule out potential for confounding from other impregnating agent (creosote), which was also associated with an elevated risk in the pooled analysis, but multivariate analysis controlled for exposure to other agents Overall quality of evidence: limited

Exp. = exposed; LH = lymphohematopoietic; MM = multiple myeloma; Na-PCP = sodium pentachlorophenate; NHL = non-Hodgkin lymphoma; OCDD = octachlorodibenzo-p-dioxin; OR = odds ratio; PCP = pentachlorophenol; RR = relative risk; SIR = standardized incidence ratio; SMR = standardized mortality ratio; SRR = standardized rate ratio; 2,3,7,8-TCDD = 2,3,7,8-tetrachlorodibenzo-p-dioxin; TCP = trichlorophenol; TeCP = tetrachlorophenol.

^a^ Authors label as “other and unspecified” lymphohematopoietic cancer, as ICD 200, 202, 203, 209 (Ramlow et al. 1996).

^b^ OCDD is a pentachlorophenol by-product; other by-products are reported in Table 3-4.

^c^ TEQ = toxic equivalent based on relative potency of 1,4-HxCDD, 1,6-HxCDD, 1,9-HxCDD, HpCDD, and OCDD relative to 2,3,7,8-TCDD.

Table 3-6 Soft Tissue Sarcoma among Pentachlorophenol-exposed Populations

Reference | Study Design/Population Exposure Assessment | Exposure Group (n) | External Analysis: SMR or SIR (95%CI) # Exposed Deaths or Cases | Internal Analysis: OR, SRR or RR (95% CI) # Exposed Cases or Cases/Controls | Interpretation
Ruder and Yiin (2011) | NIOSH PCP producers cohort (see Table 3-4) | PCP no TCP (1,402) PCP + TCP (720) Total cohort (2,122) | 1.14 (0.03–6.36); 1 2.26 (0.06–12.6); 1 1.52 (0.18–5.48); 2 | – | Limited statistical power for rare tumors Connective tissue and soft tissue sarcoma (ICD code 171) Overall quality of evidence: limited (only 2 cases)
Collins et al. (2009b) ^a^ | Michigan PCP producers cohort (see Table 3-4) | PCP no TCP (577) PCP + TCP (773) | [underlined: SMR] 0.0 (0.0–10.7); 0 2.2 (0.0–12.1); 1 | – | Limited statistical power for rare tumors Overall quality of evidence: limited (only 1 case)
Demers et al. (2006) | Canadian sawmill workers cohort (see Table 3-5) | Cumulative exposure [underlined: Exp-yr: incidence] <1 1–2 2–5 5+ p_trend_ | – | [underlined: RR] 1 (ref.); 18 0.64 (0.18–2.20); 3 0.18 (0.04–0.85); 2 0 cases 0.11 | STS (internal analysis) histologically confirmed Limited statistical power for exposure-response analysis No evidence of increase in risk Smoking rates of workers similar to general population and not correlated with exposure Overall quality of evidence: high
Kogevinas et al. (1995) | IARC registry-based nested case-control study (See Table 3-5) | Ever exposed to PCP | – | No PCP exposure observed among cases or controls | Statistical power to detect an effect limited Overall quality of evidence: limited
Hardell et al. (1995) ^b^ | Swedish soft tissue sarcoma pooled analysis of four case-control studies Structured questionnaire (self- or proxy-reported) on individual lifetime work history, exposures, and lifestyle risk factors 434 cases, 948 controls Cases histologically confirmed and reexamined in some studies | High grade PCP exposure (>1 wk continuous or >1 month total) Chlorophenols exposure (most considered exposed to PCP) -days 1–77 days >77 days | – | [underlined: OR] 2.8 (1.5–5.4); 27/30 3.0 (1.1–7.3); 12/15 3.4 (1.7–7.8); 22/19 | Potential exposure misclassification based on the use of self-reported or proxy questionnaire data. Questionnaire reported to be validated but no details provided. Exposure primarily from sawmills or pulp (no clear potential confounders) and smoking not a risk factor in this study Overall quality of evidence: limited

Na-PCP = sodium pentachlorophenate; OR = odds ratio; RR = relative risk; SIR = standardized incidence ratio; SMR = standardized mortality ratio; SRR = standardized rate ratio; STS = soft tissue sarcoma; 2,3,7,8-TCDD = 2,3,7,8-tetrachlorodibenzo-p-dioxin; TCP = trichlorophenol; TeCP = tetrachlorophenol; TEQ = toxic equivalent based on relative potency of 1,4-HxCDD, 1,6-HxCDD, 1,9-HxCDD, HpCDD, and OCDD relative to 2,3,7,8-TCDD.

^a^ SMR and SIR calculated for total cohort and for connective tissue site diagnosis only: SMR = 1.10 (0.44–2.27), 7; SIR = 0.84 (0.49–1.44), 13; STS analyzed in internal analysis was diagnosed by both site (connective tissue) and histology.

^b^ Combined analysis of 4 studies using similar populations and exposure assessment, (Eriksson et al. 1990; Eriksson et al. 1981; Hardell and Eriksson 1988; Hardell and Sandstrom 1979).

Table 3-7 Cohort Studies of Pentachlorophenol Exposure: Liver and Kidney Cancer and All Cancers Combined

Reference | Study Design/ Population Exposure Assessment | Exposure group (N) | External Analysis: SMR or SIR (95%CI); # Observed Deaths or Cases | Internal Analysis: OR, SRR, or RR (95% CI); # Observed Cases or Exposed Cases/Controls | Interpretation
Cohort studies with specific exposure information for pentachlorophenol
Ruder and Yiin (2011) | NIOSH PCP producers cohort study See Table 3-5 | PCP no TCP (1,402) PCP and TCP (720) PCP no TCP (1,402) PCP and TCP (720) Analysis by plant Sauget, IL Midland, MI PCP no TCP (1,402) PCP and TCP (720) Employment duration (days) in PCP depart. [underlined: Total cohort] ≤57 58–<182 182–<650 ≥650 | [underlined: Kidney: SMR] 0.90 (0.25–2.31); 4 1.80 (0.49–4.61); 4 [underlined: Liver and biliary: SMR] 1.76 (0.81–3.35); 9 No deaths observed 2.07 (0.89–4.08); 8 0.38 (0.01–2.09); 1 [underlined: All cancers: SMR] 1.25 (1.09–1.42); 238 1.01 (0.81–1.24); 88 1.33 (1.07–1.63); 93 0.96 (0.72–1.22); 71 1.12 (0.89–1.40); 78 1.29 (1.03–1.60); 83 | 1.00 0.73 (0.48–1.09) 0.79 (0.57–1.10) 0.99 (0.72–1.38) | Quantitative evidence of PCP exposure Some evidence of increase in risk of liver cancer and all cancers combined among PCP-exposed workers not related to TCP co-exposure; however, exposure to other liver and human carcinogens possible Overall quality of evidence is limited for kidney, liver, and all cancers combined
Collins et al. (2009b); Ramlow et al. (1996) | Michigan pentachlorophenol producers cohort study See Table 3-5 | [underlined: Ramlow et al. (1996)] PCP 15-yr lag 15-yr lag cumulative exp Low High [underlined: Collins et al. (2009b)] PCP no TCP (577) Total cohort (773) TEQ^b^ (ppb-years) [underlined: Cumulative (discrete)] 0.01–0.69 0.70–3.99 4.00–113.37 p_trend_ (linear) [underlined: Continuous exposure] p_trend_ [underlined: Collins et al. (2009b)] PCP no TCP (577) PCP +/− TCP (773) [underlined: Ramlow et al. (1996)] 15-yr lag cumulative exp Low High [underlined: Collins et al. (2009b)] PCP no TCP (577) Total cohort (773) | [underlined: Kidney: SMR] 3.0 (0.62–0.88); 3 No deaths 5.02 (1.01–14.68); 3 2.3 (0.6–5.8); 4 1.7 (0.5–4.4); 4 0 3.6 (0.7–10.5); 3 1.6 (0.0–8.8); 1 [underlined: Liver and biliary: SMR] No deaths observed No deaths observed [underlined: All cancers: SMR] 0.74 (0.40–1.24); 14 1.23 (0.83–1.74); 31 1.0 (0.8–1.3); 71 1.0 (0.8–1.2); 94 | [underlined: Kidney: RR] No deaths 4.27 (1.47–12.39); 3 RR unstable 0.47 1.008 (0.924–1.100); 4 0.86 [underlined: All cancers: RR] 0.78 (0.47–1.27); 14 1.11 (0.79–1.56); 31 | –
| | TEQ (ppb-years) [underlined: Cumulative (discrete)] 0.01–0.69 0.70–3.99 4.00–113.37 p_trend_ (linear) [underlined: Continuous exposure] p_trend_ | 1.1 (0.7–1.5); 34 0.8 (0.6–1.2); 28 1.2 (0.8–1.7); 32 | 1.00 0.9 (0.2–4.4); 28 0.9 (0.2–3.7); 32 0.98 1.004 (0.991–1.018) 0.52
Demers et al. (2006) | Canadian sawmill workers See Table 3-5 | [underlined: Total cohort] Mortality Incidence Cumulative Exp (Exp-yr) [underlined: Mortality] <1 1–2 2–5 5+ p_trend_ Incidence, 20-yr lag <1 1–2 2–5 5+ p_trend_ | [underlined: Kidney] SMR 1.31 (0.98–1.73); 30 SIR 1.10 (0.88–1.38); 79 | [underlined: Kidney: RR] 1.00; 15 1.33 (0.51–3.47); 6 2.59 (1.22–5.49); 17 2.30 (1.00–5.32); 12 0.02 1.00; 39 0.96 (0.42–2.21); 7 1.94 (1.06–3.53); 21 1.80 (0.87–3.73); 12 0.03 | Quantitative estimate of cumulative exposure Evidence of exposure-response relationship for kidney mortality and incidence Information on arsenic, a risk factor for kidney cancer, is unknown Confounding by TeCP appears unlikely for kidney, but follow-up for TeCP exposure may not be optimal for cancer with longer latency, such as kidney. Overall quality of evidence: adequate for liver and kidney, limited for all cancers combined
| | [underlined: Total cohort] Mortality Incidence Cumulative exp [underlined: (exp-yr)] [underlined: Mortality] <1 1–2 2–5 5+ p_trend_ Incidence, 20-yr lag <1 1–2 2–5 5+ p_trend_ [underlined: Total cohort] Mortality (SMR) Incidence (SIR) | [underlined: Liver] 0.98 (0.62–1.49); 22 0.79 (0.49–1.21); 21 [underlined: All cancers combined] 1.0 (0.95–1.05); 1,495 0.99 (0.95–1.04); 2,571 | [underlined: Liver: RR] 1.00; 4 0.46 (0.91–13.23); 5 3.72 (1.04–13.28); 8 2.53 (0.61–10.43); 5 0.10 1.0;19 0.61 (0.08–4.74); 1 0.44 (0.05–3.47); 1 no deaths 0.38

Exp = exposure; NIOSH = National Institute for Occupational Safety and Health; RR = relative risk; SIR = standardized incidence ratio; SMR = standardized mortality ratio; TCP = trichlorophenol; TeCP = tetrachlorophenol; TEQ = toxic equivalent based on relative potency of 1,4-HxCDD, 1,6-HxCDD, 1,9-HxCDD, HpCDD, and OCDD relative to 2,3,7,8-TCDD.

#### NHL

The available database for evaluating NHL consists of three cohort studies, two reporting only on mortality (Collins et al. 2009b; Ruder and Yiin 2011) and one reporting on incidence and mortality (Demers et al. 2006); one-nested case-control study (Kogevinas et al. 1995); three population-based case-control studies from Sweden that reported risk estimates specific for exposure to pentachlorophenol (Hardell and Eriksson 1999; Hardell et al. 1994; Nordström et al. 1998) (of hairy cell leukemia, a rare subtype of NHL); and the pooled analysis of the latter two case-control studies by Hardell et al. (2002) (Table 3-4 and Table 3-5). In general, the occupational cohort studies have better exposure characterization with lower risk of exposure misclassification and are subject to fewer types of biases (such as recall bias) than the available population-based case-control studies. The case-control studies were able to evaluate NHL incidence and verify diagnoses using cancer registry or medical records.

Occupational chemicals that have limited evidence for carcinogenicity of NHL in humans (according to IARC or the RoC; none were identified with known evidence) include benzene, ethylene oxide, 2,3,7,8-TCDD, mixed polychlorinated phenols (which includes pentachlorophenol), phenoxy herbicides (possibly, but cancer tumors sites are unclear), styrene (associated with lymphohematopoietic cancers including NHL), tetrachloroethylene, trichloroethylene, and ionizing radiation (Cogliano et al. 2011; NTP 2011). Of these, 2,3,7,8-TCDD, other polychlorinated phenols, and styrene were potential co-exposures in the pentachlorophenol studies, and may be potential confounders. Non-occupational risk factors for non-Hodgkin lymphoma include viral infections (Epstein-Barr virus, hepatitis B virus [HBV], hepatitis C virus [HCV], human immunodeficiency virus [HIV]), immunosuppressive disorders, and exposure to immunosuppressive or chemotherapy drugs (Hardell and Axelson 1998). There is no a priori reason to suspect that these non-occupational factors would have a different distribution among pentachlorophenol-exposed and non-exposed people, and thus they are not considered to be potential confounders.

The most informative study, the Canadian sawmill worker study (Demers et al. 2006) provides considerable evidence of an association of NHL with exposure to pentachlorophenol, which is unlikely to be explained by confounding or biases. A major advantage of this study is the large number of deaths (N = 42) and incident cases of NHL (N = 92), of which 34 deaths and 54 incident cases occurred among workers with one or more full-time equivalent years of dermal exposure. Statistically significant exposure-response relationships (using exposure-year equivalents of dermal exposure) between pentachlorophenol exposure and NHL were observed for both mortality (p_trend_ = 0.06) and incidence (p_trend_ = 0.03). An approximately 1.7-fold increase in mortality and incidence risk was observed among workers in the highest exposure category (5+ exposure-years) compared with workers in the lowest exposure category (<1 exposure year). Somewhat stronger exposure-response trends were observed in incidence analyses allowing for 10-year (p_trend_ = 0.02) or 20-year (p_trend_ = 0.02) latency periods (lagged mortality analyses were not reported). Risk estimates in the highest categories of exposure were approximately two-fold for all analyses (e.g., mortality, lagged and unlagged incidence). No excess risk for mortality (SMR) and incidence (SIR) of NHL were found among workers in the entire cohort. However, these estimates are not specific for pentachlorophenol exposure (includes workers exposed to tetrachlorophenol and pentachlorophenol), are less sensitive (groups workers with low or no exposure with those with high exposure) and have a less appropriate comparison group (general population) than the internal analyses (non-exposed workers). Thus, the external analyses do not argue against the positive findings found in internal analyses.

Most of the cohort was also exposed to tetrachlorophenol in varying amounts; however, the correlation between pentachlorophenol and tetrachlorophenol exposure was not strong (r = 0.45 based on cumulative exposure at the end of follow-up). To date, data from other (animal or human) studies have been inadequate to evaluate the carcinogenicity of tetrachlorophenol. Although no adjustment for tetrachlorophenol was made in the analysis by pentachlorophenol exposure, a separate analysis by tetrachlorophenol exposure reported lower relative risks of NHL than for pentachlorophenol compared with non-exposed workers and no overall trend in NHL risk with increasing exposure was observed. Additional support that exposure to pentachlorophenol and not tetrachlorophenol is linked to the increased risk of NHL in this cohort comes from follow-up exposure-response analyses (log-linear and log-log) that modeled cumulative exposure to chlorophenols as a continuous variable by assigning the mean cumulative exposure to all subjects in each category (Friesen et al. 2007). These analyses found a “roughly” monotonic exposure-response relationship between exposure to pentachlorophenol or combined tetrachlorophenol and pentachlorophenol but not for tetrachlorophenol and NHL. The exposure-response relationship was stronger for exposure to pentachlorophenol than for exposure to tetrachlorophenol or combined tetrachlorophenol and pentachlorophenol.

Although the Canadian sawmill workers were also exposed to wood dust, wood dust is not a risk factor for NHL. Little information was available on non-occupational exposures, except for smoking. Cigarette smoking has not been associated with NHL risk in epidemiological studies (with the possible exception of follicular cell lymphoma), and survey of a subset of workers (~7%) found that age-adjusted cigarette smoking prevalence among workers was similar to that of the general population and was not associated with exposure to pentachlorophenol, so it is unlikely that smoking could explain the observed association between NHL and pentachlorophenol. Overall, the finding of positive exposure-response relationships for pentachlorophenol exposure using internal analyses and the lack of evidence of exposure to carcinogenic co-exposures argues against confounding by non-occupational or occupational co-exposures.

There is some evidence for an association between exposure to pentachlorophenol among producers and NHL, primarily based on the findings from the Michigan pentachlorophenol producers cohort study (Collins et al. 2009b; Ramlow et al. 1996). The evidence from the NIOSH pentachlorophenol producers study (Ruder and Yiin 2011), which includes workers in the Michigan study, is weaker; however, this study had a more limited exposure assessment (by production department only). The most predominant co-exposure in these studies is trichlorophenol. Trichlorophenol causes leukemia in experimental animals (listed in the RoC as reasonably anticipated to be a human carcinogen), and 2,3,7,8-TCDD, a trichlorophenol contaminant, is a risk factor for NHL (limited evidence).

Statistically significant increased risks for NHL in the pentachlorophenol-only subcohort (SMR = 2.8, 95% CI = 1.1 to 5.7, 7 deaths) and the combined pentachlorophenol/trichlorophenol cohort (SMR = 2.4, 95% CI = 1.0 to 4.7, 8 deaths) were found in the Michigan cohort (Collins et al. 2009b). Additional analyses using two different exposure assessments (reported in the two different updates) of specific, or surrogates for, cumulative pentachlorophenol exposure provide support for the hypothesis that the excess risk of NHL observed in the pentachlorophenol workers is caused by exposure to pentachlorophenol. In the earlier update (Ramlow et al. 1996), risks for NHL and multiple myeloma for workers with >1 pentachlorophenol-year of cumulative (duration x intensity) exposure were reported for “other or unspecified” lymphohematopoietic cancers (4 deaths; ICD-8 200, 202, 203, or 209); however, it seems reasonable to assume that most if not all the deaths were NHL. In an internal analysis of these cancers, an increased relative risk (RR = 2.58, 95% CI = 0.98 to 6.80, 4 deaths) was observed among workers with at least one pentachlorophenol-year of cumulative exposure compared with non-exposed workers.

In the later update by Collins et al. (2009b) statistically significant increased SMRs (four to five fold) for NHL were found among workers in the highest cumulative exposure category for modeled exposure for all three chlorinated dioxins (HxCDD, HpCDD, and OCDD) that are pentachlorophenol by-products. This is considered to be a congener pattern for pentachlorophenol exposure (see Section 1) and for the total toxic equivalent (TEQ) (which includes 2,3,7,8-TCDD, HxCDD, HpCDD, and OCDD) (Table 3-4). SMRs did not increase consistently in the lower and medium exposure categories (trend not reported) of the three chlorinated dioxins; however, as noted in Section 3.3.1, there is a potential for misclassification in these categories. No significant exposure-response trends were reported for modeled cumulative TEQ analysis using either discrete or cumulative continuous measures (see Table 3-5).

There is independent evidence that the excess risk of NHL observed in pentachlorophenol-exposed workers is unlikely to be explained by co-exposure to trichlorophenol. Only a small statistically non-significant increase in NHL mortality was reported in a separate analysis of the trichlorophenol production workers from this plant who did not have exposure to pentachlorophenol (SMR = 1.3, 95% CI = 0.6 to 2.6, 8 exposed deaths) (Collins et al. 2009a). The risk of NHL also increased with increasing levels of 2,3,7,8-TCDD in this study, although not significantly. It is not known whether 2,3,7,8-TCDD exposure levels correlated with levels of the higher chlorinated dioxins that are pentachlorophenol by-products, and thus it is not known whether exposure to 2,3,7,8-TCDD contributes to the excess NHL risk observed in pentachlorophenol-exposed workers.

According to data reported in the NIOSH cohort, workers in the Michigan cohort were also exposed to several animal carcinogens and to styrene (which is a risk factor for lymphohematopoietic cancers including NHL), but there are no data on whether exposures to these chemicals were correlated with exposure to pentachlorophenol. Overall, the findings of excess risk of NHL with exposure-specific assessment mitigate concerns for confounding.

Although a statistically non-significant increased risk for NHL mortality was observed in the NIOSH cohort (SMR = 1.41, 95% CI = 0.64 to 2.67, 9 deaths) among pentachlorophenol only (no trichlorophenol) workers, it is not clear that this can be attributed to pentachlorophenol exposure in this study because of the lack of an exposure-response relationship with duration of work in pentachlorophenol departments (which may not be the best surrogate for exposure) and potential confounding from occupational co-exposures. The majority of workers appear to have had short-term exposure in the pentachlorophenol production departments (mean durations ranging from 1.3 to 3.2 years), however, so that an exposure duration-response relationship may be difficult to detect.

The risk of NHL was higher in workers who were exposed to both pentachlorophenol and trichlorophenol (SMR = 2.50, 95% CI = 1.08 to 4.93, 8 deaths). This differs from the Michigan pentachlorophenol producers cohort study, which found higher risk estimates for the pentachlorophenol-only exposed subgroup compared to the workers exposed to both chlorophenols (see above). This difference could be explained, in part, by differences in the exposure assessments for trichlorophenol (see Section 3.2). Most (77%) of the workers classified as exposed to pentachlorophenol and trichlorophenol in the NIOSH study were from the Michigan plant. Thus, it seems reasonable that the biomonitoring data on pentachlorophenol-exposed and pentachlorophenol and trichlorophenol-exposed workers, for the Michigan study reported by Collins et al. (2008; 2007), are relevant to the NIOSH study. These studies found that pentachlorophenol-only-exposed workers had only a small increase in trichlorophenol by-product, 2,3,7,8-TCDD, dioxin serum levels compared with unexposed workers, whereas a much larger increase was observed for workers exposed to both pentachlorophenol and trichlorophenol. Furthermore, no association between trichlorophenol, nor its by-product, 2,3,7,8-TCDD, and NHL was found in a separate analysis of trichlorophenol workers in the Michigan plant (Collins et al. (2009a), see above), which argues against potential confounding by 2,3,7,8-TCDD.

The NIOSH study authors stated that approximately 90% of the workers in the entire cohort were also exposed to other chemicals. Potential exposures at the Michigan and Illinois plants included several chemicals that cause cancer in animals (for example, dichlorobenzene, nitrobenzene, ethylbenzene) or which are associated with limited evidence of carcinogenicity in humans (e.g., styrene). Thus, confounding from other occupational carcinogens cannot be ruled out.

Additional support for an association between exposure to pentachlorophenol among pentachlorophenol production users and NHL comes from the IARC registry-based nested case-control study (Kogevinas et al. 1995). Although the case-control study included workers from cohorts manufacturing phenoxy herbicides and chlorophenols, only one of the included cohorts produced pentachlorophenol. All of the NHL deaths occurred among production workers with the highest cumulative exposure to pentachlorophenol (OR = 4.19, 95% CI = 0.59 to 29.59, 3 deaths). The major limitation of the study is low statistical power; however, the findings are consistent with the findings for pentachlorophenol production workers in the United States.

Finally, the series of population-based case-control studies in Sweden are consistent with an association between NHL and pentachlorophenol exposure. Increased ORs for exposure to pentachlorophenol and NHL were reported in the pooled analysis of hairy-cell leukemia and NHL (OR = 1.40, 95% CI = 0.99 to 1.98, 64 exposed cases and 101 exposed controls) (Hardell et al. 2002), and a smaller case-control study of NHL (OR = 8.8, 95% CI = 3.4 to 24.0, 15 exposed cases and 9 exposed controls (Hardell et al. 1994). (Note that the evidence is weaker for NHL in the 1999 study of NHL alone than the pooled analysis.) In the 1994 study, the magnitude of the risk estimate is much higher than the other studies, and the high-risk estimate is most likely an overestimate due to chance (because of small numbers) or an unidentified bias. The OR was not decreased in a multivariate analysis adjusting for phenoxy acid herbicides, DDT, asbestos, and solvent exposure. Pentachlorophenol was banned in 1997 in Sweden. The 1994 studies enrolled cases identified the Umea region in Sweden prior to the ban (1974 to 1978) and the later studies enrolled cases after the ban (1987 to 1990, NHL or 1992, HCL). A further analysis of the pooled data, by first or last date of exposure, suggested that the maximum increase in risk occurred at approximately 20 to 30 years after first exposure and 10 to 20 years after last exposure (Hardell et al. 2002). As noted, the major limitation in these population-based case-control studies is limited exposure assessment, especially where proxies were used for some subjects, which tends to result in non-differential exposure misclassification and a loss of precision. In addition, confounding by co-exposures, primarily phenoxy acid herbicides or other pesticides, in some of the studies cannot be ruled out.

#### Multiple Myeloma

Multiple myeloma is also an uncommon cancer (rarer than NHL in the United States) with a relatively high survival rate, and, similar to NHL, cancer incidence studies with histological diagnoses are more informative than mortality studies using death certificates. Only two cohort studies, the NIOSH pentachlorophenol producers study (Ruder and Yiin 2011) and the Canadian sawmill workers study (Demers et al. 2006), reported findings for exposure specific to pentachlorophenol and only the latter study reported incidence in addition to mortality data (Table 3-5). Occupational chemicals that have limited evidence (none identified with known) for multiple myeloma include benzene, ethylene oxide, and ionizing gamma radiation (Cogliano et al. 2011), none of which are potential co-exposures identified in the studies of pentachlorophenol. Potential non-occupational risk factors for multiple myeloma include certain autoimmune disorders, and race (NCI 2013) and possibly obesity (Birmann et al. 2007); however, none of these would be expected to be associated with pentachlorophenol exposure.

In the most informative study, the Canadian sawmill worker study (Demers et al. 2006), a statistically significant exposure-response relationship between dermal exposure to pentachlorophenol and multiple myeloma was observed for both incidence (p_trend_ = 0.02) and mortality (p_trend_ = 0.03) using the lowest exposure group (<1 exposure-year) as a referent. Similar exposure-response relationships for incidence were found when exposure was lagged for 10 years (p_trend_ = 0.04) or 20 years (p_trend_ = 0.03). Risk estimates were approximately four-fold higher in the highest exposure category (5+ exposure-years) compared with the lowest category (<1 exposure-year) in lagged and unlagged incidence analyses. Although statistically non-significant elevated RRs for mortality and incidence were found in the highest exposure category of tetrachlorophenol, no exposure-response relationships were observed, suggesting that tetrachlorophenol was not a confounder.

In the NIOSH pentachlorophenol producers study, the SMR for multiple myeloma mortality among the pentachlorophenol-only workers was 1.84 (95% CI = 0.68 to 4.00, 6 exposed deaths) (Ruder and Yiin 2011). No other studies reported on this endpoint.

#### Soft Tissue Sarcoma

Soft tissue sarcoma is a rare cancer with a higher survival rate, and most likely a long latency. A key challenge is disease diagnosis, which should be verified on the basis of both site and histology. The available studies reporting on soft tissue sarcoma mortality or incidence include the Canadian sawmill workers study (Demers et al. 2006), the Michigan pentachlorophenol producers study, and a pooled analysis of four case-control studies in Sweden (Hardell et al. 1995). Only the Canadian sawmill cohort study (Demers et al. 2006) and the pooled case-control study (Hardell et al. 1995) were considered to be informative to evaluate this endpoint. The two U.S. producer studies and the IARC-based registry nested case-control study had insufficient statistical power (less than 20%) to evaluate this endpoint; no deaths were observed in the nested case-control study and only one death was observed among pentachlorophenol producer workers in each of the two producer cohort studies (Collins et al. 2009b; Ruder and Yiin 2011). As mentioned previously, the New Zealand and Australian case-control studies had limited exposure information specific for pentachlorophenol. Potential occupational risk factors (with limited evidence of carcinogenicity in humans) include 2,3,7,8-TCDD and mixed chlorophenols (including pentachlorophenol).

In the Canadian sawmill workers cohort, cases of soft tissue sarcoma were identified via histological classification, and follow-up was relatively complete (Demers et al. 2006). Dermal exposure to pentachlorophenol was not associated with soft tissue sarcoma risk. Most of the cases of soft tissue sarcoma occurred among individuals in the lower exposure group (less than 1 exposure-year) and the relative risk decreased in both lagged and unlagged analyses although the trends were not statistically significant.

In contrast, a statistically significant increased risk was found for soft tissue sarcoma and “high” (>1 week continuous or >1 month total) exposure to pentachlorophenol in the pooled analysis of four Swedish population-based case-control studies (OR = 2.8, 95% CI = 1.5 to 5.4, 27 exposed cases and 30 exposed controls) (Hardell et al. 1995). No difference between workers with longer (greater than 77 days) and shorter-term (1 up to 77 days) exposure to total chlorophenols was observed, of which pentachlorophenol was reported to be the predominant component (e.g., 27 of 33 exposed cases). A strength of the pooled analysis (Hardell and Eriksson 1999) was the larger number of cases and histological re-review of the cases (in some of the individual case-control studies). The major limitation of the study was potential misclassification of exposure; exposure was assessed using self-reported or proxy data for exposure information. The authors stated that there was a 97% agreement between self-reported questionnaire data and employer records (in the sawmill and pulp industry); however, no details on the validation study were reported. No increased risk was found for smoking or oral snuff use, which is consistent with the observation that tobacco smoking has not been identified as a risk factor for soft tissue sarcoma. An increase in risk was also observed for exposure to phenoxyacetic acids in these studies. However, in one of the four case-control studies included in the pooled analysis that excluded cases and controls exposed to phenoxyacetic acids (Hardell 1979), an increased risk of soft tissue sarcoma and exposure to chlorophenols was observed.

#### Other Cancer Sites: Liver, Kidney, Lung and All Cancers Combined

The available data to evaluate the solid tumors, kidney and liver, consist of the three cohort studies: the Canadian sawmill workers cohort (Demers et al. 2006) and the two pentachlorophenol production workers cohorts (Ruder and Yiin 2011); (Collins et al. 2009b; Ramlow et al. 1996). Exposure-response analyses for kidney tumor were conducted in two studies (Demers et al. 2006; Ramlow et al. 1996), for liver in one study (Table 3-7) (Demers et al. 2006), lung in all three cohort studies, and all cancers combined in the two pentachlorophenol producers studies. Both liver and kidney cancers are relatively rare cancers with lower survival rates and are not as subject to misclassification as lymphohematopoietic cancers and soft tissue sarcoma. Mortality data are therefore more closely comparable to incidence data for these endpoints. Potential risk factors for these cancers that may be relevant in the pentachlorophenol studies include smoking, arsenic (both endpoints), and alcoholic beverage consumption (liver only).

In the Canadian sawmill study (Demers et al. 2006), elevated risks for liver cancer mortality and incidence were observed for some exposure groups in the unlagged and 10-year lagged analyses; however, no exposure-response relationships were observed and increased risks were no longer present in the 20-year lagged analyses, which may be more relevant for solid tumors. In general, the magnitudes of the relative risks were weaker for exposure to tetrachlorophenol. A statistically non-significant increase in liver cancer mortality was observed in the pentachlorophenol-only workers in the NIOSH cohort, which was concentrated in the Illinois plant; only one liver cancer death was observed in the Michigan plant (Ruder and Yiin 2011). Potential confounding from other occupational co-exposures (several animal liver carcinogens and a possible human liver carcinogen, polychlorinated biphenyls, were produced or used at this plant) or smoking cannot be ruled out. Workers at this plant accumulated more pack-years than former unexposed workers at this plant; however, they were also older.

There is evidence for an association between kidney cancer and exposure to pentachlorophenol in the Canadian case-control study of sawmill workers (Demers et al. 2006) (Table 3-7). A statistically significant trend in risk for both mortality (p_trend_ = 0.02) and to a lesser extent in incidence (p_trend_ = 0.07) was observed when a separate analysis by exposure-years to pentachlorophenol was conducted; the response with incidence was strongest in models lagging exposure by 20 years (p_trend_ = 0.03). A more modest but statistically significant trend was also observed in the mortality analysis by tetrachlorophenol exposure, but not for incidence, in lagged and unlagged models.

The evidence for an association between pentachlorophenol and kidney cancer is less clear among the pentachlorophenol producers cohorts, and there is limited power to examine exposure-response relationships due to the small number of deaths. A non-statistically significant excess of risk of kidney cancer mortality was found in the pentachlorophenol-exposed group in the Michigan cohort (Collins et al. 2009b) but not in the NIOSH study (Ruder and Yiin 2011). In the Michigan study, all three of the exposed deaths occurred in the highest cumulative exposure groups (RR = 4.27, 95% CI = 1.47 to 12.39, high exposure compared with low exposure) in the 1996 analysis by Ramlow et al. (1996), however, in the subsequent analysis by Collins et al. (2009b) no exposure response was observed for total TEQ (which may not be a perfect surrogate for pentachlorophenol exposure since it includes 2,3,7,8-TCDD) in either internal or external analyses (no analyses for specific chlorinated dioxins were reported). In addition, workers in the Michigan plant were also exposed to a number of other chemicals, some of which cause renal tumors in experimental animals, and no information was available on tobacco smoking in this study.

In the three cohort studies, there was no evidence of an association of exposure to pentachlorophenol and lung cancer across studies. A statistically significant risk of lung cancer mortality (SMR = 1.56, 95% CI = 1.27 to 1.90; 99 exposed deaths) was observed among pentachlorophenol producers in the NIOSH study but no exposure-response relationship with employment in pentachlorophenol departments was observed in either internal or external analyses (total cohort, including workers also exposed to trichlorophenol) and there is a potential for confounding from other occupational co-exposures in this study. No increased risk of lung cancer was found among pentachlorophenol producers in the Michigan study (Collins et al. 2009b; Ramlow et al. 1996). Finally, no exposure-response relationships between dermal exposure to pentachlorophenol and lung cancer mortality (p_trend_ = 0.68) or incidence (p_trend_ = 0.45) were observed in the Canadian sawmill cohort study (Demers et al. 2006).

Analyses are limited to evaluate all cancers combined. In the NIOSH study (Ruder and Yiin 2011), a statistically significant increased SMR was observed among pentachlorophenol-only workers. No exposure-response was observed with employment in pentachlorophenol departments in the total cohort, but it is unclear whether employment duration is the best surrogate for exposure, and there is a potential for a healthy worker survival effect. In the earlier lagged analysis of the Michigan pentachlorophenol producers cohort by Ramlow et al. (1996), a marginal statistically non-significant increase in mortality in the higher exposure category with 15-year lag was observed in external and internal analyses, but no trend was observed. In the subsequent analysis (Collins et al. 2009b), relative risks were close to one for all levels of TEQ in internal analyses. In the Canadian sawmill cohort study (Demers et al. 2006), no increase in risk was observed in all cancer mortality and incidence for the total cohort; however, no exposure-response analyses were conducted.

### 3.4.2 Synthesis

Overall, there is evidence suggesting that an association between exposure to pentachlorophenol and NHL is credible, based on consistent findings across studies in different occupational populations with varying co-exposures, different geographical areas and study designs, and evidence of statistically significant positive exposure-response relationships in the most informative study (Demers et al. 2006). An increased risk of NHL was found among workers exposed to pentachlorophenol in all three cohort studies (Collins et al. 2009b; Demers et al. 2006; Ramlow et al. 1996; Ruder and Yiin 2011), the nested case-control study of IARC herbicide workers (Kogevinas et al. 1995) and two Swedish population-based case-control studies (Hardell et al. 1994; Hardell et al. 2002) (see Figure 3-1). However, the quality of the evidence for an association varied across studies, the magnitude of the association was moderate, and there were a limited number of high-quality studies.

Figure 3-1

Risk Estimates (SMR, RR) for Exposure to Pentachlorophenol and NHL

Risk estimates and 95% confidence intervals for NHL for the six studies that were considered in the assessment. SMRs reported for MI and NIOSH producer studies; RR for the sawmill cohort incidence study for highest PCP cumulative exposure category vs. lowest exposure (no PCP-specific SIR or RR reported for ever vs. never exposed); OR for the two Swedish studies.

Solid circles = cohort studies; clear circles = case-control studies; IARC = International Agency for Research on Cancer; MI = Michigan; PCP = pentachlorophenol.

The strongest evidence comes from the large cohort of Canadian sawmill workers (Demers et al. 2006), which observed exposure-response relationships between cumulative dermal exposure to pentachlorophenol and both NHL mortality and incidence in lagged (10 and 20 years) and unlagged analyses. This finding is supported by findings from the Michigan pentachlorophenol cohort, in which a statistically significant increase in NHL was observed among workers who were only exposed to pentachlorophenol (Collins et al. 2009b). Analyses by exposure level found increases in NHL or NHL and multiple myeloma combined mortality among workers with at least one year of cumulative exposure (Ramlow et al. 1996) (in the earlier follow-up), and in the highest category of surrogates (chlorinated dioxins) for pentachlorophenol exposure in the subsequent follow-up (Collins et al. 2009b). The evidence for an association from the other individual studies with specific exposure information for pentachlorophenol (Hardell et al. 1994; Hardell et al. 2002; Kogevinas et al. 1995; Ruder and Yiin 2011) is considered to be more limited, but as a group they provide evidence to support the associations found in the two most informative studies.

The next key question in the evaluation is whether the observed increases in risks in these studies can be explained by chance, bias, or confounding. There was little evidence for potential systematic biases in the studies. A potential bias in the Swedish case-control studies was the use of proxies for exposure information for some cases and controls; however, in most studies the dead cases were also matched with dead controls, and proxies were used for both, and thus exposure misclassification would be expected to be non-differential and most likely bias findings toward the null.

The major co-exposures in the cohort studies are tetrachlorophenol for sawmill workers, and 2,4,5-trichlorophenol for some pentachlorophenol production workers. In addition, there is potential exposure to 2,3,7,8-TCDD, a by-product of trichlorophenol production. (However, as noted in Section 1.3.1, 2,3,7,8-TCDD is not considered to be a by-product of pentachlorophenol production.) There is limited evidence from studies in humans linking NHL to exposure to 2,3,7,8-TCDD (IARC 1997; 2012), or mixed polychlorophenols as a group (IARC 1999); however, there are few independent studies that have adequately and specifically evaluated 2,4,5-trichlorophenol and tetrachlorophenol. Potential confounding from tetrachlorophenol can reasonably be ruled out in the Canadian sawmill cohort (Demers et al. 2006) based on the lack of evidence of an exposure-response relationship with NHL both in the original analysis (Demers et al. 2006) and in analyses of cumulative exposure to tetrachlorophenol as a continuous variable in this cohort (Friesen et al. 2007), in contrast to a positive exposure-response relationship for pentachlorophenol. In addition, no exposure to 2,3,7,8-TCDD or other known or potential carcinogens would be expected in this cohort. Similarly, potential confounding by co-exposure to trichlorophenol can also reasonably be ruled out among the Michigan pentachlorophenol production workers. A separate analysis of the trichlorophenol-exposed cohort at the Michigan plant found only a small, statistically non-signficant excess of NHL among trichlorophenol production workers without co-exposure to pentachlorophenol (Collins et al. 2009a).

The potential for confounding from co-exposures in the NIOSH cohort study cannot be reasonably ruled out. The population-based case-control studies also found an increased risk for NHL and exposure to phenoxy herbicides, suggesting the potential for confounding; however, ORs for NHL and exposure to chlorophenols (of which pentachlorophenol was the predominant agent) remained elevated in multivariate analyses controlling for exposure to other pesticides (Hardell et al. 1994).

Although most of the studies did not measure other occupational co-exposures or assess lifestyle information, the findings of an exposure-response relationship in internal analyses in the most informative study helps to mitigate these concerns. In addition, lifestyle factors such as smoking and alcohol use have not been shown to have a clear association with NHL. Finally, the pattern of co-exposures varies in the two occupational settings (production plant and sawmill) in the most informative studies and among the case-control studies, which adds strength to the hypothesis that pentachlorophenol is a common etiologic agent.

The associations between exposure to pentachlorophenol and other cancers were weaker. There was strong evidence for an association between multiple myeloma and moderate evidence for kidney cancer in the most informative (Canadian sawmill) cohort study (Demers et al. 2006), based on statistically significant exposure-response relationships; however, there was little evidence from other studies to support this finding. The pooled Swedish population-based case-control study of soft tissue sarcoma (Hardell et al. 1995) found an increased risk of this cancer with exposure to pentachlorophenol. However, no association was observed between pentachlorophenol exposure and soft tissue sarcoma incidence in the Canadian sawmill cohort study, which had an adequate number of cases to evaluate risks from this rare cancer; most of the cases of soft tissue sarcoma occurred in the lowest exposure group in this study (less than 1 to 2 dermal exposure-years). The Swedish pooled case-control study classified individuals as exposed based on very short duration periods (1 week of continuous exposure or 1 month of total exposure), and thus differences in exposure measures may help explain the inconsistency. There was little evidence for an association with cancer of the liver and lung, and the available studies were not adequate to evaluate all cancers combined.

## 3.5 NTP Level of Evidence Recommendation

There is limited evidence for the carcinogenicity of pentachlorophenol and by-products of its synthesis from studies in humans based on epidemiological studies finding a consistent association between occupational exposure to pentachlorophenol and non-Hodgkin lymphoma. The available evidence suggests that a causal association between exposure to pentachlorophenol and cancer is credible. However, due to the limited number of high-quality studies, chance and confounding across the body of studies cannot be adequately excluded. Since occupational exposure consists of pentachlorophenol and by-products of its synthesis, epidemiological studies cannot distinguish the effects of pentachlorophenol itself from the effects of its by-products (e.g., chlorinated dioxins), and dioxin activity may be associated with NHL risk. Some studies found an association between exposure to pentachlorophenol and multiple myeloma, soft tissue sarcoma, and kidney cancer; however, the evidence is either limited to one study or it is not consistent across studies.