# 2 Disposition and Toxicokinetics

Disposition and toxicokinetics discuss how a xenobiotic chemical can enter and leave the body, what happens to it once it is in the body, and the rates of these processes. Section 2.1 discusses the absorption, distribution, and excretion of pentachlorophenol. Metabolism is discussed in Section 2.2. Toxicokinetic models were described in humans and laboratory animals in several studies and are reviewed in Section 2.3. These data are important because they help identify the various factors that affect the toxicity of a chemical. These factors include routes and rates of absorption, tissue concentrations and their temporal changes, reactive metabolites, metabolic activation and detoxification reactions, routes of elimination, and gender and/or species differences in these factors. The mechanistic implications of these data are discussed in Section 5.

## 2.1 Absorption, Distribution, and Excretion

Several studies were available that described the absorption, distribution, and excretion of pentachlorophenol in humans and experimental animals, and they are reviewed below. The data are generally consistent across studies and show that pentachlorophenol is well absorbed, widely distributed, and excreted primarily in the urine.

### 2.1.1 Human Studies

Humans are exposed to pentachlorophenol from a variety of sources (see Section 1) and by different routes. Pentachlorophenol and other chlorophenols are well absorbed from all routes of exposure (ingestion, inhalation, and dermal). The dermal route is the most important for sawmill or other timber-processing workers who handle treated wood (Demers et al. 2006; Fenske et al. 1987; Kauppinen and Lindroos 1985). The inhalation route may be more important for pentachlorophenol producers or residents living in treated homes (IARC 1991; Ruder and Yiin 2011; Wilson et al. 2007). Ingestion may be important for the general population through consumption of food contaminated with pentachlorophenol (see Appendix B, Table B-9).

Pentachlorophenol has been detected in blood and/or urine samples collected from the general population or from people living in log homes (Cline et al. 1989; Gerhard et al. 1999; Gómez-Catalán et al. 1987; Hosenfeld 1986; Peper et al. 1999; Reigner et al. 1992a; Thompson and Treble 1994; 1996; To-Figueras et al. 1997; Treble and Thompson 1996; Wilson et al. 2007), as well as from accidental (Gray et al. 1985; Smith et al. 1996), or occupational exposures (Demers et al. 2006; Fenske et al. 1987; Hertzman et al. 1988; Hertzman et al. 1997; Jones et al. 1986; Kalman and Horstman 1983; Kauppinen and Lindroos 1985; Pekari et al. 1991; Reigner et al. 1992a; Teschke et al. 1989; Teschke et al. 1996). Absorption from the respiratory tract was 76% to 88% in two human volunteers exposed in an enclosed area for 45 minutes (Casarett et al. 1969). About 90% of pentachlorophenol ingested by four human volunteers was detected in feces (~4%) and urine (~86%); the large percentage recovered in the urine indicates that absorption from the gastrointestinal tract is highly efficient (Braun et al. 1979). Evidence of toxicologically significant dermal absorption of pentachlorophenol comes from case reports of fatal poisonings due to extensive skin contact with pentachlorophenol (Gray et al. 1985; Jones et al. 1986; Smith et al. 1996; Wood et al. 1983). Horstman et al. (1989) reported that 62% of pentachlorophenol in diesel oil and 16% of sodium pentachlorophenate in an aqueous solution penetrated human skin in vitro over a 24-hour period. Wester et al. (1993) reported that 0.6% or 1.5% of pentachlorophenol in acetone accumulated in the plasma receptor fluid while 2.6% or 3.7% accumulated in two human skin samples in vitro, but the authors noted that receptor fluid accumulation greatly underestimated in vivo absorption for pentachlorophenol because of low solubility in the receptor fluid. Horstman et al. (1989) reported that in vitro penetration of pentachlorophenol and tetrachlorophenol through human cadaver skin were similar in diesel oil, but in a water-based commercial preparation, penetration of tetrachlorophenol was about twice that of pentachlorophenol.

Data for distribution of pentachlorophenol in human tissues are available from autopsies of individuals who died from pentachlorophenol intoxication or from other causes. These data show that pentachlorophenol was widely distributed, was bound extensively to plasma proteins, and could cross the blood-brain and placental barriers, but it did not accumulate appreciably in any tissues. WHO (1987) reported that pentachlorophenol was detected in the liver, kidneys, lungs, and brain of individuals who died from pentachlorophenol poisoning. The data did not present clear evidence of accumulation in these tissues because the concentrations were similar to those observed in the blood. One study in Germany measured background levels of pentachlorophenol in urine and tissues collected during the autopsy of 21 people (Grimm et al. (1981) as cited in ATSDR (2001)). The highest concentrations were detected in liver (0.067 μg/g), kidneys (0.043 μg/g), brain (0.047 μg/g), spleen (0.019 μg/g), and body fat (0.013 μg/g). The median level in the blood was 0.033 μg/mL. Geyer et al. (1987) used data from Grimm et al. (1981) and Uhl et al. (1986) and calculated bioconcentration factors for pentachlorophenol. The highest bioconcentration factors were for liver (5.7 to 7.0), kidneys (4.0), and brain (3.3 to 4.0) and indicate limited accumulation in body tissues. Other studies have shown that pentachlorophenol can cross the placental barrier with concentration ratios of 0.91 to 1.44 reported for maternal blood to cord blood (Guvenius et al. 2003; Park et al. 2008). Uhl et al. (1986) reported high plasma protein binding (>96%) in three volunteers that were administered single oral doses of 3.9 to 18.8 mg of pentachlorophenol. High plasma protein binding limits the amount available to the liver and kidneys for metabolism and excretion and, thus, may prolong retention in the body (ATSDR 2001).

Studies of various human populations exposed to pentachlorophenol show that urine is the primary route of excretion (Bevenue et al. 1967; Cline et al. 1989; Gómez-Catalán et al. 1987; Jones et al. 1986; Kalman and Horstman 1983; Pekari et al. 1991; Reigner et al. 1992a; Thompson and Treble 1994; 1996; Treble and Thompson 1996; Uhl et al. 1986; Wilson et al. 2007). Studies using human volunteers (oral or inhalation exposure) reported that 76% to 86% of the administered dose was excreted in the urine within 5 to 7 days while about 4% was excreted in the feces (Braun et al. 1979; Casarett et al. 1969). Uhl et al. (1986) showed that alkalinization of the urine resulted in a distinct increase in urinary excretion of pentachlorophenol. Half-lives reported for urinary excretion of pentachlorophenol in humans show considerable variation ranging from 33 hours (Braun et al. 1979) to 20 days (Uhl et al. 1986), which may be partially explained by differences in study inclusion criteria, urine pH, diet, chemical form of pentachlorophenol, and vehicle (see Section 2.3).

### 2.1.2 Laboratory Animal Studies

Pentachlorophenol is well absorbed in laboratory animals following oral, inhalation, or dermal exposure with no clear species differences (Table 2-1). The oral absorption efficiency showed some variability but was greater than 90% in most studies in rats, mice, and monkeys. Lower absorption was reported when the chemical was administered in feed or mixed with soil compared with exposure by gavage or in drinking water. One inhalation study in rats indicated that at least 70% to 75% of the administered dose was absorbed (Hoben et al. 1976b). Lower absorption was observed for dermal exposure: about 29% of the dose applied to the skin of monkeys (Wester et al. 1993) and 29% to 50% applied to the skin of pigs (Qiao et al. 1997; Qiao and Riviere 2002) was absorbed when nonocclusive conditions were used. However, under occlusive conditions, dermal absorption from a soil-based mixture was 100% in pigs (Qiao et al. 1997).

Table 2-1 Absorption of Pentachlorophenol Administered to Laboratory Animals

Species (Sex) | Exposure | | % Dose Absorbed | Reference
Species (Sex) | Route | Dose/Conc. | % Dose Absorbed | Reference
Sprague-Dawley rats (M/F) | Gavage | 10–100 mg/kg | 98–99 | Braun et al. (1977)
Wistar rats (M) | Drinking water | 1.4 mM [370 μg/mL] | 90 | Meerman et al. (1983)
Sprague-Dawley rats (M) | Gavage | 2.5 mg/kg | 91–97 | Reigner et al. (1991)
Sprague-Dawley rats (M) | Drinking water | 30 μg/mL | 75–107 | Reigner et al. (1992b)
F344 rats (M) | Gavage | 9.5–38 mg/kg | 86–100 | Yuan et al. (1994)
F344 rats (M) | Feed | 302–1,010 ppm | 30–52 | Yuan et al. (1994)
Sprague-Dawley rats (M) | Gavage (in soil) | 0.1–0.2 mg/kg | 36–77 | Pu et al. (2003)
B6C3F_1_ mice (M) | Gavage | 15 mg/kg | 106 | Reigner et al. (1992c)
Rhesus monkeys (M/F) | Gavage | 10 mg/kg | 96–103 | Braun and Sauerhoff (1976)
Sprague-Dawley rats (M) | Inhalation | 1–5.7 mg/kg | 70–75 | Hoben et al. (1976b)
Rhesus monkeys (F) | Dermal | 0.7–0.8 μg/cm^2^ | 24–29^a^ | Wester et al. (1993)
Pigs (F) | Dermal | 300 μg | 29–101^b^ | Qiao et al. (1997)
Pigs (F) | Dermal | 300 μg | 50^c^ | Qiao and Riviere (2002)

^a^ Applied in soil (24%) or dissolved in acetone (29%) for 24 hours and monitored for 14 days.

^b^ Applied in soil under nonocclusive (29%) and occlusive (101%) conditions and monitored for 17 days.

^c^ Applied in ethanol vehicle and monitored for 17 days.

Tissue distribution data were available for rats (Braun et al. 1977; Hoben et al. 1976b; Larsen et al. 1972), mice (Jakobson and Yllner 1971), chickens (Stedman et al. 1980), bats (Shore et al. 1991), sheep (Wilson et al. 1982), pigs (Qiao et al. 1997; Qiao and Riviere 2002), and monkeys (Braun and Sauerhoff 1976). In general, these data indicate that pentachlorophenol is widely distributed but does not accumulate in body tissues. Low tissue accumulation has been attributed to extensive binding of pentachlorophenol to plasma proteins (97% to 99% in rats) (Braun et al. 1977; Gómez-Catalán et al. 1991). The highest relative concentrations were usually found in organs associated with metabolism and excretion and included the liver, gall bladder, kidneys, and gastrointestinal tract. Distribution data for laboratory animals are summarized in Table 2-2.

Table 2-2 Distribution of Pentachlorophenol in Laboratory Animals

Species (Route) | Dose/Conc. | Sample Time | Tissues | Conc. (μg/g Tissue) | Reference
Chicken (feed) | 1,000 ppm | 8 wk | Kidneys Liver | 33.7 17 | Stedman et al. (1980)
Sheep (intraruminal) | 10 mg/kg | 36 hr | Pericardial fat Lungs Adrenal glands Kidneys Subcutaneous fat Omental fat Intestinal lymph nodes Liver | 96^a^ 59 48 44 41 29 21–25 23 | Wilson et al. (1982)
Mouse (intraperitoneal) | 15–37 mg/kg | 4–30 d | Gall bladder Liver Stomach Intestines Kidneys | 60–90 3–26 10–21 8 0.3–8 | Jakobson and Yllner (1971)
Rat (gavage) | 31–40 mg/kg | 40 hr | Liver Kidneys Stomach + intestines | ~0.24^b,c^ ~0.18 ~0.1 | Larsen et al. (1972)
Rat (inhalation) | 5.7 mg/kg | 72 hr | Liver Lungs | ~20^c,d^ ~1.8 | Hoben et al. (1976b)
Rat (gavage) | 10 mg/kg | 9 d | Liver Kidneys | 0.315^d^ 0.045 | Braun et al. (1977)
Bat (dermal) | 65 mg/g^e^ | 24 hr | Subcutaneous fat Liver Kidneys Body | 15.1–98.9 nd–64.7 nd–24.8 3.19–29.8 | Shore et al. (1991)
Pig (dermal) | 40 μg/cm^2^ | 17 d | Liver Lungs Large intestine Small intestine Kidneys | 5.15^d^ 1.79 0.53 0.42 0.22 | Qiao et al. (1997)
Pig (dermal) | 40 μg/cm^2^ | 11 d | Liver Ovaries Kidneys Lungs Gall bladder Uterus Small intestines Large intestines | 0.0128^b^ 0.0038 0.0034 0.0032 0.0026 0.0025 0.0024 0.0018 | Qiao and Riviere (2002)
Monkey (gavage) | 10 mg/kg | 15 d | Small intestines Large intestines Liver | 5.0^d^ 2.6 1.1 | Braun and Sauerhoff (1976)

^a^ 47% of the dose remained in the digestive tract including 37% in the rumen.

^b^ Values represent the mean percent of administered activity per gram of tissue.

^c^ Values were estimated from a figure.

^d^ Values are the percentage of administered dose.

^e^ Surface concentration measured in scrapings from treated wooden roost boxes (all bats died within 24 hr).

Studies in laboratory animals consistently show that pentachlorophenol is primarily excreted in the urine either unchanged or as metabolites (see Section 2.2). Moderate amounts of pentachlorophenol are excreted in the feces while trace amounts may be excreted in exhaled breath. Distribution data indicate that enterohepatic circulation and biliary excretion are involved. Most of the recovered dose was excreted within 24 hours in rodents. Studies in monkeys showed slower excretion compared with rodents. Treatment of monkeys with cholestyramine (an ion-exchange resin that binds phenols) resulted in a 2- to 7-fold decrease in urinary excretion, 9- to 18-fold increase in fecal excretion, and a 40% overall increase in pentachlorophenol excretion (Ballhorn et al. 1981; Rozman et al. 1982). Although the study authors attributed these effects to interruption of enterohepatic circulation and enhancement of intestinal elimination, it is more likely explained by decreased absorption of pentachlorophenol bound to cholestyramine and subsequent elimination in the feces. Data are summarized in Table 2-3.

Table 2-3 Excretion of PCP in Laboratory Animals

Species (Sex) | Route | Duration (Days)^a^ | Excretion (% Dose) | | | Reference
Species (Sex) | Route | Duration (Days)^a^ | Urine | Feces | Exhaled | Reference
Mice (F) | i.p. | 3–7 | 72–83 | 3.8–11.5 | <0.05 | Jakobson and Yllner (1971)
Mice (NR) | i.p. | 4 | 79^b^ | NR | nd | Ahlborg et al. (1974)
Mice (NR) | oral | 4 | 26^b^ | NR | nd | Ahlborg et al. (1974)
Mice (M) | oral | 2 | 54.6–57.4^c^ | 6.4–8.8 | NR | Reigner et al. (1992c)
Rat (F) | oral | 10 | 68.3 | 9.2–13.2 | <0.04 | Larsen et al. (1972)
Rat (NR) | i.p. | 4 | 84^b^ | NR | nd | Ahlborg et al. (1974)
Rat (NR) | oral | 4 | 46^b^ | NR | nd | Ahlborg et al. (1974)
Rat (M/F) | oral | 9 | 64–79.8 | 18.6–33.6 | 0.2 | Braun et al. (1977)
Rat (M) | i.v. | 3 | 57.9 | 10.1 | NR | Reigner et al. (1991)
Rat (M) | oral | 3 | 51.5 | 9.3 | NR | Reigner et al. (1991)
Rat (M) | inh. | 1 | 55^b^ | NR | NR | Hoben et al. (1976a)
Rabbit (NR) | oral | 7–12 | 47.7–66.1 | 0.8–4.0 | NR | Deichmann et al. (1942)
Monkey (M/F) | oral | 7–15 | 68.6–78 | 11.9–23.8 | NR | Braun and Sauerhoff (1976)
Monkey (M) | oral | 7 | 31.6–35.6 | 2–3.5 | NR | Ballhorn et al. (1981)
Monkey (M) | oral | 6 | 35.4^d^ | 2.8^d^ | NR | Rozman et al. (1982)

F = female; inh. = inhalation; i.p. = intraperitoneal injection; i.v. = intravenous injection; M = male; nd = not detected; NR = not reported.

^a^ Following a single dose.

^b^ Estimated from a graph.

^c^ Sum of β-glucuronidase and sulfatase data for pentachlorophenol and tetrachlorohydroquinone.

^d^ Animals were equipped with a bile duct bypass and ~70% of dose was detected in the bile.

## 2.2 Metabolism

Pentachlorophenol is excreted unchanged in the urine or is metabolized in the liver via oxidative and reductive dechlorination and/or conjugation. Enzymes involved in metabolism include cytochromes P450, peroxidases, UDP-glucuronosyl transferase and sulfotransferases (Ahlborg and Thunberg 1978; Mehmood et al. 1996; Reigner et al. 1991; Samokyszyn et al. 1995; Tsai et al. 2001). A role for non-enzymatic bioactivation of pentachlorophenol to quinones or semiquinones by endogenous lipid hydroperoxides has also been proposed (Tsai et al. 2001). Metabolism was enhanced to different extents by pretreating with various inducers of P450 (Ahlborg et al. 1978; Ahlborg and Thunberg 1978; Tsai et al. 2001; van Ommen et al. 1986b). Metabolites included tetrachlorohydroquinone, sulfate or glucuronide conjugates of pentachlorophenol and tetrachlorocatechol (ATSDR 2001; Reigner et al. 1992c; Renner and Hopfer 1990); however, qualitative and quantitative species differences may partially explain differences in toxicity. Tetrachlorohydroquinone and tetrachlorocatechol may be further oxidized to form semiquinones and benzoquinones. The only metabolites confirmed in humans in vivo are the glucuronide or sulfate conjugates of pentachlorophenol; however, in vitro studies demonstrated that human microsomes can metabolize pentachlorophenol to tetrachlorohydroquinone. In addition, pentachlorophenol is a metabolite of lindane (γ-hexachlorocyclohexane), γ-2,3,4,5,6-pentachlorocyclohexene, hexachlorobenzene, pentachlorobenzene, and pentachloronitrobenzene (Betts et al. 1955; Engst et al. 1976; Stewart and Smith 1986; van Ommen et al. 1989). This section identifies the known and possible metabolic pathways of pentachlorophenol. Mechanistic implications are discussed in Section 5.

### 2.2.1 Humans

Pentachlorophenol metabolism in humans has not been extensively studied and is limited to two studies in human volunteers following a single dose of pure pentachlorophenol (Braun et al. 1979; Uhl et al. 1986) and a few chronic studies of non-occupational or occupational exposure to mixed chlorophenols (Gómez-Catalán et al. 1987; Norén and Sjövall 1987; Pekari et al. 1991). Only one study included more than four subjects, thus, the small sample sizes likely account for some of the variability.

Overall, the data indicate that conjugation with glucuronic acid is the major metabolic pathway in humans while excretion of unconjugated compound is a relatively minor pathway (Reigner et al. 1992a). Sulfate conjugates were only measured in one study but also were important, especially in workers exposed to lower pentachlorophenol concentrations in that study (Pekari et al. 1991). Tetrachlorohydroquinone was not detected in most of the studies and is a minor metabolite at best. The relative amounts of pentachlorophenol and its conjugated metabolites reported in human urine samples are shown in Table 2-4. Only one study indicated that most of the administered dose was excreted unchanged (Braun et al. 1979). Braun et al. used the same urine sample extraction and storage techniques that were used in a study in monkeys (Braun and Sauerhoff 1976) that reported no glucuronide metabolites in the urine (see Section 2.2.2). Reigner et al. (1992a) suggested that the different results reported by Braun et al. (1979) and Uhl et al. (1986) could be explained by the instability of the glucuronide conjugates and differences in urine sample treatment methods (see further discussion below).

Table 2-4 Relative Amounts of Pentachlorophenol and Conjugated Metabolites Recovered in Human Urine

Reference | Route/Subjects | Number of Subjects | Urinary Metabolites (%)
Reference | Route/Subjects | Number of Subjects | PCP | PCP Conjugate^a^
Braun et al. (1979) | oral/volunteers | 4 | 86 | 14
Uhl et al. (1986) | oral/volunteers | 1 | ~35 | ~65
Gómez-Catalán et al. (1987) | ns/general population | 30 | 13.2 | 86.8
Gómez-Catalán et al. (1987) | ns/occupational | 3 | 9.3 | 90.7
Norén and Sjövall (1987) | ns/non-occupational | 3 | 1.5 | 98.5
Pekari et al. (1991) | dermal/sawmill workers | 7 | 23.8–30.9 | 69.1–76.2^b^

ns = not specified; PCP = pentachlorophenol.

^a^ Glucuronide conjugate unless otherwise noted.

^b^ Includes both sulfate and glucuronide conjugates (sulfate was dominant but proportion of glucuronide conjugates increased at higher exposure levels).

Studies that examined metabolism of pentachlorophenol (>99% purity) in human volunteers following a single exposure reported that only the unmetabolized compound and its glucuronide conjugate were detected in urine (Braun et al. 1979; Uhl et al. 1986). No traces of tetrachlorohydroquinone, tetrachlorophenols, or other metabolites were observed in these studies. Braun et al. (1979) reported that 74% of the administered dose (86% of the urinary excretion) was excreted unchanged after 7 days. Uhl et al. (1986) reported that the percentage of pentachlorophenol eliminated as the conjugate increased from about 25% to 40% over the first 10 days and reached a steady state of about 65% from day 12 to 37. Thus, the difference between the Braun et al. (1979) and the Uhl et al. (1986) study after 7 days is not as great as it appears in Table 2-4. Uhl et al. (1986) also reported that 61% to 70% of pentachlorophenol was excreted as the glucuronide in 13 non-occupationally exposed individuals but the source of these data was not clearly described.

Studies of chronic non-occupational or occupational exposure to chlorophenols also reported that the majority of pentachlorophenol was excreted as conjugates and that tetrachlorohydroquinone was not detected (Gómez-Catalán et al. 1987; Norén and Sjövall 1987; Pekari et al. 1991). Two of the three studies showed an increase in the percentage excreted in conjugated form compared with the single dose study of Uhl et al. (1986) and may indicate toxicokinetic differences between acute and chronic exposures. Pekari et al. (1991) reported that sulfate conjugates were dominant in workers exposed to lower pentachlorophenol concentrations while the proportion of glucuronide conjugates increased with increasing chlorophenol concentrations. Because sulfation is a high affinity-low capacity process and glucuronidation is a low affinity-high capacity process, low concentrations would favor sulfation.

The variability among studies in the relative amounts excreted as the unconjugated versus the conjugated form may be partially explained by the different treatment methods used for urine samples, urine pH of the subjects, kinetic differences following single versus chronic exposures, and other study protocol differences (Gómez-Catalán et al. 1987; Reigner et al. 1992a). Subjects used in the Braun et al. (1979) study fasted prior to exposure and were known to have minimal exposure to pentachlorophenol prior to the study (confirmed by urine analysis). Urine samples also were acidified and frozen prior to analysis. The glucuronide conjugates are unstable due to pH-dependent hydrolysis; therefore, analysis of urine samples generally leads to an underestimation of the conjugate originally excreted (Lilienblum 1985). Norén and Sjövall (1987) also reported that pentachlorophenol was released from the conjugate during storage at room temperatures and after repeated freezing and thawing of urine samples. Therefore, the free versus conjugated amounts in these studies should be regarded as estimates that likely overestimate the free pentachlorophenol.

Although most studies have not detected tetrachlorohydroquinone as a metabolite of pentachlorophenol in humans, Edgerton et al. (1979) reported that tetrachlorohydroquinone was detected at low concentrations in 4 of 11 urine samples collected from the general population. Ahlborg et al. (1974) also detected low levels of tetrachlorohydroquinone in urine samples from two workers (described as spraymen) exposed to pentachlorophenol on the job. However, interpretation of these studies is hampered by possible exposures to other chlorobenzenes or chlorophenols and the small sample size. Levels of pentachlorophenol were 2 to 150 times higher than the levels of tetrachlorohydroquinone detected in these samples. Edgerton et al. (1979) also detected tetrachlorophenols in 10 of the 11 samples.

In vitro studies indicate that human microsomes can metabolize pentachlorophenol to tetrachlorohydroquinone and provide some support for the findings reported by Ahlborg et al. (1974) and Edgerton et al. (1979). Juhl et al. (1985) demonstrated that human liver homogenates metabolized pentachlorophenol to tetrachlorohydroquinone and that the pharmacokinetics were comparable to results obtained with rat liver homogenates. Mehmood et al. (1996) also demonstrated that microsomal fractions and whole cells of Saccharomyces cerevisiae expressing human cytochrome P450 3A4 (CYP3A4) metabolized pentachlorophenol to tetrachlorohydroquinone. The rate of metabolism was low, but no metabolism was detected in transformants lacking CYP3A4; however, the purity of the pentachlorophenol used in this study was not specified. Dubois et al. (1997; 1996) also demonstrated that pentachlorophenol was a strong inducer of CYP3A7 in human HepG2 cells but metabolites were not measured in that study.

### 2.2.2 Laboratory Animals

Numerous metabolism studies of pentachlorophenol have been conducted in experimental animals. Pentachlorophenol is more extensively metabolized in rodents than in other species but the relative amounts of unmetabolized pentachlorophenol and its metabolites detected in the urine showed considerable differences among the various studies (Table 2-5). For example, Braun et al. (1977) reported that 48% of a single oral dose of 100 mg/kg administered to rats was excreted as unchanged pentachlorophenol, 6% as the glucuronide conjugate, and 10% as tetrachlorohydroquinone. In contrast, Reigner et al. (1991) reported that only about 5% of a single oral dose of 2.5 mg/kg was excreted as unchanged pentachlorophenol and about 90% of the conjugated metabolites were sulfates. The one inhalation study reviewed indicated that 70% to 75% of the administered dose was excreted as pentachlorophenol with only trace amounts of tetrachlorohydroquinone (Hoben et al. 1976b). Lin et al. (1997; 1999; 1996) demonstrated that tetrachlorohydroquinone and tetrachlorocatechol could be further oxidized to their corresponding benzosemiquinones and benzoquinones in rats and mice. In rabbits, one study reported considerable amounts of pentachlorophenol glucuronide in urine (Tashiro et al. 1970) while two other studies reported little or no evidence of glucuronidation (Betts et al. 1955; Deichmann et al. 1942). Pentachlorophenol was excreted unchanged in the urine of monkeys (Braun and Sauerhoff 1976). Cravedi et al. (1999) reported that trout exposed to pentachlorophenol orally excreted the unchanged compound along with its glucuronide and sulfate conjugates. Urinary metabolites reported in experimental animals are summarized in Table 2-6 and metabolic pathways are shown in Figure 2-1.

Table 2-5 Relative Amounts of Urinary Metabolites of Pentachlorophenol in Rats and Mice

Reference | Dose | | | Metabolites (% Total Urinary Metabolites or % Dose)
Reference | Route | mg/kg/day | # Doses | PCP | PCP Glucuronide | PCP Sulfate | TCHQ | TCHQ Glucuronide | TCHQ Sulfate
Rats
Hoben et al. (1976b) | Inhalation | 1–6 | 1–5 (20 min) | 70–75^a^ | – | – | trace | – | –
Braun et al. (1977) | Gavage | 100 | 1 | 48^a^ | 6^a^ | – | 10^a^ | – | –
Renner (1989) | Gavage | 53 | 28 | 36–58^b^ | 42–64^b^ | – | 10–19^c^ | 81–90^c^ | –
Reigner et al. (1991) | Gavage/i.v. | 2.5 | 1 | 5^a^ | 0.5–6.2 | 18–20^a^ | 1^a^ | 1^a^ | 24–27^a^
Ahlborg et al. (1974) | i.p. | 25 | 1 | 43^d^ | 14^d,e^ | – | 5^d^ | 38^d,e^ | –
Ahlborg et al. (1978) | i.p. | 10 | 1 | 60^d^ | 9–16^d^ | – | 7^d^ | 16–22^d^ | –
Mice
Reigner et al. (1992c) | Gavage | 15 | 1 | 6.7–8.6^a^ | 1^a^ | 10–15^a^ | 3.6–5.5^a^ | 0.1–3^a^ | 15–18^a^
Ahlborg et al. (1974) | i.p. | 25 | 1 | 41^d^ | 13^d,e^ | – | 24^d^ | 22^d,e^ | –
Jakobson and Yllner (1971) | i.p. | 15–37 | 1 | 30^a^ | 8^a^ | – | 21^a,f^ | | –

i.p. = intraperitoneal; i.v. = intravenous; PCP = pentachlorophenol; TCHQ = tetrachlorohydroquinone.

^a^ % of administered dose.

^b^ % of PCP excreted unchanged or as glucuronide conjugate.

^c^ % of TCHQ excreted unchanged or as glucuronide conjugate.

^d^ % of recovered urinary metabolites or radioactivity.

^e^ Based on increases in PCP and TCHQ concentrations after boiling the urine with hydrochloric acid.

^f^ Reliable estimate of amount of TCHQ and glucuronide conjugate could not be determined separately due to insufficient sample.

Table 2-6 Urinary Metabolites of Pentachlorophenol in Experimental Animals

Compound | Rat^a^ | | | Mouse^b^ | | Rabbit^c^ | Monkey^d^ | Trout^e^ | In Vitro^f^
Compound | Oral | Inhal | i.p. or i.v. | Oral | i.p. | Oral | Oral | Oral | Mouse | Rat
Pentachlorophenol (PCP) | X | X | X | X | X | X | X | X
PCP glucuronide | X | | X | X | X | X | | X
PCP sulfate | X | | X | X | | | | X
Tetrachlorohydroquinone (TCHQ) | X | trace | X | X | X | | | | | X
TCHQ glucuronide | X | | X | X | X
TCHQ sulfate | X | | X | X
Tetrachlorocatechol | X | | | | | | | | | X
Tetrachlororesorcinol | X
Tetrachlorophenols and glucuronides g | X
Tetrachloro-p-benzosemiquinone | X | | | | | | | | X | X
Tetrachloro-p-benzoquinone (TCBQ) | X | | | X | X | X | | | X | X
Tetrachloro-o-benzosemiquinone | X | | | X | | | | | X | X
Tetrachloro-o-benzoquinone | | | | X | | | | | X | X
2,3,4-Trichlorophenol and glucuronide | X
Trichlorohydroquinone | X | | X
Trichlorobenzoquinone | trace

^a^ Sources: Ahlborg et al. (1978); Ahlborg et al. (1974); Ahlborg and Thunberg (1978); Braun et al. (1977); Edgerton et al. (1979); Engst et al. (1976); Hoben et al. (1976b); Lin et al. (1999); Lin et al. (1996); Reigner et al. (1991); Renner (1989); Renner and Hopfer (1990).

^b^ Sources: Ahlborg et al. (1974); Jakobson and Yllner (1971); Lin et al. (1997); Lin et al. (1999); Reigner et al. (1992c); Tashiro et al. (1970).

^c^ Sources: Betts et al. (1955); Deichmann et al. (1942); Tashiro et al. (1970).

^d^ Sources: Braun and Sauerhoff (1976).

^e^ Sources: Cravedi et al. (1999).

^f^ Sources: Ahlborg et al. (1978); Tsai et al. (2001); van Ommen et al. (1986b).

^g^ Includes 2,3,4,5-, 2,3,4,6-, and 2,3,5,6-tetrachlorophenol.

Figure 2-1

Pentachlorophenol Metabolic Pathways in Mammals

* = Primary urinary metabolite in rodents; bold arrow = predominant pathway in humans; PCP = pentachlorophenol; TCBQ = tetrachlorobenzoquinone; TCCAT = tetrachlorocatechol; TCHQ = tetrachlorohydroquinone; TCPs = tetrachlorophenols; TCR = tetrachlororesorcinol; TCSQ = tetrachlorobenzosemiquinone; TCoBQ = tetrachloro-ortho-benzoquinone; TCoSQ = tetrachloro-ortho-benzosemiquinone; TriCBQ = trichlorobenzoquinone; TriCHQ = trichlorohydroquinone.

Sources: ATSDR (2001); Lin et al. (2002); Renner and Hopfer (1990); Tsai et al. (2001).

Some of the variability may be explained by differences in sample treatment methods. Glucuronide and sulfate conjugates are unstable in acidic conditions (Reigner et al. 1991). Studies that extracted pentachlorophenol and tetrachlorohydroquinone after acidification with hydrochloric acid (Ahlborg et al. 1974; Braun et al. 1977) reported higher concentrations of unconjugated pentachlorophenol and tetrachlorohydroquinone than studies that performed urinary extraction after addition of a pH 7.4 buffer (Reigner et al. 1991). This also may explain why no conjugates of pentachlorophenol were found in the urine of monkeys since urine was extracted after acidification. Differences in the relative amounts of tetrachlorohydroquinone may be explained by the instability of this chemical in urine. Reigner et al. (1991) used ascorbic acid and EDTA to prevent tetrachlorohydroquinone degradation. Reigner et al. (1991) also was the only study to report sulfate conjugates in rodents; however, these authors noted that their results provided only indirect evidence for the occurrence of these metabolites even though the sulfatase enzyme used was considered specific (i.e., no β-glucuronidase activity).

Pentachlorophenol induced CYP1A1 in fetal rat hepatocytes and CYP2B in quail hepatocytes in vitro (Dubois et al. 1997; Dubois et al. 1996). van Ommen et al. (1989; 1986b; 1988) conducted in vitro metabolism studies with microsomes derived from rats treated with different inducers and demonstrated that P450b (CYP2B2), P450d (CYP1A2), and P450p (CYP3A1) were effective at metabolizing pentachlorophenol. There is some evidence that tetrachloro-1,4-benzoquinone can be formed by direct oxidation of pentachlorophenol via peroxidases (Chung and Aust 1995; Samokyszyn et al. 1995); however, this observation was challenged by Kazunga et al. (1999) as an artifact of the extraction and analytical methods. Nevertheless, peroxidase-catalyzed oxidation of pentachlorophenol may be important, especially in extrahepatic tissues (Dai et al. 2005; Dai et al. 2003). Tsai et al. (2001) reported that under normal conditions the primary metabolic pathway involved oxidation to quinones and semiquinones via microsomal P450s; however, under conditions of oxidative stress, endogenous lipid hydroperoxides might increase the rate of pentachlorophenol metabolism and enhance its toxicity and carcinogenicity. Other metabolites identified from in vitro studies with mouse and rat liver microsomes are shown in Table 2-6.

## 2.3 Toxicokinetic Studies

Toxicokinetic studies of pentachlorophenol have been conducted in rodents, monkeys, and humans and show significant species differences (Table 2-7). Plasma protein binding, enterohepatic circulation, renal tubule reabsorption, and urine pH influence elimination kinetics of pentachlorophenol (ATSDR 2001; Pekari et al. 1991; Uhl et al. 1986). An open-system, two-compartment model described most studies in rodents while an open, one-compartment model with first-order absorption and elimination kinetics adequately described data from monkey and human studies. In rats, two distinct elimination phases were evident and included an initial rapid phase followed by a slower terminal phase. About 90% of the total was eliminated in the initial phase (Braun et al. 1977). The slower elimination phase in rodents likely was due to high plasma protein binding and retention in the liver. Reported clearance values in rats ranged from about 0.015 to 0.027 L/hr/kg while elimination half-lives showed some possible dose and sex differences (see Table 2-7). Braun et al. (1977) reported that the overall elimination in rats was biphasic in low- and high-dose males and in low-dose females but was monophasic in high-dose females. No explanation was provided for the difference in kinetics observed in high-dose females. Fecal excretion was much higher and urinary excretion was much lower in female rats in the high-dose group compared with the other groups and could indicate decreased absorption.

Table 2-7 Toxicokinetic Parameters of Pentachlorophenol Reported in Humans and Experimental Animals

Reference | Species (Sex) | Route | Dose (mg/kg) | Plasma t_max_ (Hours) | Clearance (L/hr/kg) | Plasma Half-life | | Elimination Half-life
Reference | Species (Sex) | Route | Dose (mg/kg) | Plasma t_max_ (Hours) | Clearance (L/hr/kg) | t_½_ α (hr) | t_½_ β (hr) | t_½_ α (hr) | t_½_ β (hr)
Reigner et al. (1992c) | B6C3F_1_ mice (M) | i.v. gavage | 15 15 | na 1.5 ± 0.05 | 0.057 ± 0.007 – | 5.2 ± 0.6 5.8 ± 0.6 | NA | – – | NA
Braun et al. (1977) | SD rats (M) | gavage | 10 100 | 4–6 | – | 6.9^a^ – | 24^a^ – | 17.4 ± 1.7 12.8 ± 1.1 | 40.2 ± 6.3 121 ± 63.7
Braun et al. (1977) | SD rats (F) | gavage | 10 100 | 4–6 | – | 11^a^ – | 30^a^ – | 13.4 ± 2.3 | 32.5 ± 9.1
Braun et al. (1977) | SD rats (F) | gavage | 10 100 | 4–6 | – | 11^a^ – | 30^a^ – | 27.2 ± 1.1
Meerman et al. (1983) | Wistar rats (M) | i.v. | 10.6 | na | – | 2.17 | 7.24 | – | –
Reigner et al. (1991) | SD rats (M) | i.v. i.v. gavage | 2.5 20 2.5 | na na 1.8 ± 0.3 | 0.026 ± 0.003 0.033 0.027 ± 0.005 | 0.67 ± 0.46 4.1–4.5 7.54 ± 0.44 | 7.1 ± 0.87 35.5–45 NA | – | –
Reigner et al. (1992b) | SD rats (M) | i.v. dw | 2.5 30 μg/mL | na – | 0.023 ± 0.008 0.025 ± 0.003 | 7.99 ± 2.71 8.02 ± 2.08 | NA | – | –
Yuan et al. (1994) | F344 rats (M) | i.v. gavage gavage | 5 9.5 38 | na 2 4 | 0.016 ± 0.0007 0.015 ± 0.0004 0.016 ± 0.0005 | – [8.6] ^b^ [6.3] ^b^ | 5.6 ± 0.37 NA NA | – | –
Yuan et al. (1994) | F344 rats (F) | i.v. | 5 | na | 0.017 ± 0.002 | – | 9.5 ± 4.2 | – | –
Braun and Sauerhoff (1976) | Rhesus monkey (M) | gavage | 10 | 12–24 | [0.19]^c,d^ | 72.0 | NA | 40.8 | NA
Braun and Sauerhoff (1976) | Rhesus monkey (F) | gavage | 10 | 12–24 | [0.19]^c,d^ | 83.5 | NA | 92.4 | NA
Braun et al. (1979) | Human (M) | oral | 0.1 | 4 | [0.0073]^b,d^ [0.51] L/hr | 30.2 | NA | 33.1 ± 5.4 | NA
Uhl et al. (1986) | Human (M) | oral | 0.016 0.31 | – | [0.000069]^c^ [0.0042] L/hr^c^ | 384 ± 60 – | NA | 432 ± 57.6 480 ± 81.6 | NA
Pekari et al. (1991) | Human (M/F) | inhalation and skin | – | – | [0.012–0.084] L/hr^c^ | – | NA | 384 | NA
Reigner et al. (1992a) | Human (M/F) | inhalation and skin | 0.005–24 mg/day | – | 0.018 L/hr | – | – | – | NA
Barbieri et al. (1995) | Human (–) | inhalation and skin | – | – | – | – | – | 240 | NA

– = not reported; dw = drinking water; F = females; i.v. = intravenous; M = males; na = not applicable; t_max_ = time to maximum concentration in plasma; [ ] = calculated value.

^a^ Values estimated by Goodman (2001).

^b^ Calculated from elimination rate constant (k_e_).

^c^ Renal clearance.

^d^ Based on 4.5 kg body weight for Rhesus monkeys and 70 kg body weight for humans.

Elimination in monkeys was much slower than that observed in rodents and followed first-order kinetics (Braun and Sauerhoff 1976). Biliary excretion and enterohepatic circulation might explain the long half-life in monkeys; however, the authors presented no data to verify this assumption. The renal clearance rate of 14.5 mL/min corresponded to the glomerular filtration rate and indicated that pentachlorophenol was not actively transported into tubular filtrate or reabsorbed.

In humans, renal clearance values increased in relation to urine flow, which indicated increased tubular reabsorption at lower urinary flow rates (Pekari et al. 1991). However, elimination half-lives and clearance values in humans following a single oral dose varied by more than an order of magnitude (Braun et al. 1979; Uhl et al. 1986). The reasons for these differences are not completely understood, but a review of pentachlorophenol in urine and plasma reported from 11 studies that included workers, the general population, and residents of log homes indicated that the elimination half-life and clearance values reported by Braun et al. (1979) appear to be outliers (Reigner et al. 1992a). Reigner et al. (1992a) calculated 20 clearance values from these 11 studies that included more than 600 subjects. An overall weighted average clearance of 0.018 L/hr (range: 0.0064 to 0.0346 L/hr) was derived compared with 0.51 L/hr reported by Braun et al. (1979) and 0.0042 L/hr reported by Uhl et al. (1986). Reigner et al. (1992a) also noted that the clearance value reported by Uhl et al. (1986) only represented renal clearance; therefore, they estimated that total clearance in that study was about 0.01 L/hr and compared favorably with other studies they reviewed.

Braun et al. (1979) selected volunteers with residual plasma levels of pentachlorophenol that were four to five times lower than average levels in the general population; therefore, their inclusion criterion might have selected subjects having a higher rate of clearance than the general population. Other factors that might have contributed to the different results reported by Braun et al. (1979) and Uhl et al. (1986) include differences in dosing solutions and study protocol. Subjects used in the Braun et al. (1979) study fasted for 8 hours before and 1 hour after receiving an oral dose of sodium pentachlorophenate (0.1 mg/kg) dissolved in water while subjects in the Uhl et al. (1986) study had no dietary restrictions before or after ingesting a solution of pentachlorophenol dissolved in ethanol (0.016 mg/kg).

## 2.4 Synthesis and Summary

Studies in humans and experimental animals show that pentachlorophenol is efficiently absorbed following oral, inhalation, or dermal exposure. Although pentachlorophenol is widely distributed, accumulation in tissues appears to be limited by extensive binding to plasma proteins in rats and humans. Tissue distribution studies in experimental animals show that the highest concentrations are found in organs associated with metabolism and excretion and include the liver, gall bladder, kidneys, and gastrointestinal tract. Pentachlorophenol is mostly excreted in the urine, either unchanged or as metabolites.

Metabolism and toxicokinetics show considerable interspecies variation. The primary urinary metabolites in rodents include, tetrachlorohydroquinone, unmetabolized pentachlorophenol, and their glucuronide or sulfate conjugates. Tetrachlorohydroquinone may be further metabolized to form reactive benzosemiquinones and benzoquinones. Only one metabolism study has been conducted in monkeys and no metabolites were identified. Pentachlorophenol was excreted unchanged in the urine of monkeys. Metabolism in humans is controversial because two studies using pure compound reported that only the parent compound and its glucuronide conjugate were excreted in the urine. Although there was no evidence of tetrachlorohydroquinone or tetrachlorophenols in subjects administered single oral doses of pure pentachlorophenol; a few studies that included occupationally exposed individuals or subjects from the general population detected low levels of tetrachlorohydroquinone and tetrachlorophenols in urine. Exposures were not adequately characterized in the latter studies; therefore, the source of these metabolites could not be confirmed. However, an in vitro study demonstrated that human liver microsomes could metabolize pentachlorophenol to tetrachlorohydroquinone. Whether or not humans metabolize pentachlorophenol to tetrachlorohydroquinone is a particularly important consideration because this metabolite is thought to be important to the carcinogenic effects observed in rodents. Toxicokinetic studies indicate that clearance is much slower and the excretion half-life is much longer in humans compared with rats. Thus, the species differences in metabolism and toxicokinetics are important for mechanistic considerations discussed in Section 5.