# 1 Properties and Human Exposure

The candidate substance being reviewed in this monograph is ‘Pentachlorophenol and By-products of Its Synthesis.’ During synthesis of pentachlorophenol, several additional chlorinated molecules are formed as by-products because of the elevated temperatures and pressures used in the production processes (see Section 1.3, below). The concentrations of these by-products can be altered somewhat by changing the conditions of the manufacturing process, but all commercial forms of pentachlorophenol contain by-products of its synthesis in detectable amounts.

Evidence that exposure to pentachlorophenol includes exposure to by-products of its synthesis comes from biomonitoring studies. The pentachlorophenol by-products most commonly found in serum samples are 1,2,3,6,7,8-hexachlorodibenzo-p-dioxin, 1,2,3,4,6,7,8-heptachlorodibenzo-p-dioxin, and octachlorodibenzo-p-dioxin, but not 2,3,7,8-TCDD, which is not a by-product of the pentachlorophenol synthetic process used in the United States. These specific by-products consistently have been found in serum samples from people exposed to pentachlorophenol in multiple occupational settings and in the environment near active and former wood treatment facilities, e.g., in dust collected from houses. The by-products have been observed to persist in serum of workers for decades after exposure ceased in sawmill workers and pentachlorophenol manufacturers. Further, these same by-products also have been found in environmental samples from different geographical areas where pentachlorophenol had been used including the United States, China, and New Zealand and in adipose tissue, beef, and milk from cows exposed to pentachlorophenol-treated wood. Thus, people who are exposed to pentachlorophenol or pentachlorophenol-containing products are always exposed to the combination of pentachlorophenol and its by-products. [Note that throughout the rest of this monograph, when the term “pentachlorophenol” is used, it denotes exposure to ‘pentachlorophenol and by-products of its synthesis.’]

This section describes the chemical identification and properties of pentachlorophenol (Section 1.1), use and production data (Section 1.2), synthesis of pentachlorophenol and its by-products (Section 1.3), characterization of exposure in the workplace (Section 1.4), and exposure of people to pentachlorophenol (Section 1.5). The material in Sections 1.1 through 1.5 is summarized in Section 1.6.

## 1.1 Chemical Identification and Properties

Pentachlorophenol (Figure 1-1) (CASRN 87-86-5) is a chlorinated aromatic compound. Pure pentachlorophenol exists as light tan to white needle-like crystals at room temperature. Also known as PCP, chlorophen, penchlorol, and penta, the compound is relatively volatile, practically insoluble in water at the pH generated by its dissociation (pKa = 4.7), and soluble in most organic solvents (NTP 1989; WHO 1987). Salts of pentachlorophenol, such as sodium pentachlorophenate, are readily soluble in water. Technical grade pentachlorophenol consists of brown flakes; technical grade sodium pentachlorophenate consists of cream-colored beads. Regarding production and use, pentachlorophenol and its salt, sodium pentachlorophenate, are considered the most important forms of pentachlorophenol. Table 1-1 contains some chemical identification information for pentachlorophenol. Table 1-2 lists some physical and chemical properties of pentachlorophenol.

Figure 1-1

Chemical Structure of Pentachlorophenol (C_6_HCl_5_O)

Table 1-1 Chemical Identification of Pentachlorophenol

Characteristic | Information
Chemical Abstracts index name | Pentachlorophenol^a^
CAS Registry number | 87-86-5^b^
Molecular formula | C_6_HCl_5_O^b^
Synonyms | Chlorophen; PCP; penchlorol; penta; pentachlorphenol; 2,3,4,5,6-pentachlorophenol^c^

^a^ IARC (1999).

^b^ Akron (2010).

^c^ NTP (1989).

Table 1-2 Physical and Chemical Properties of Pentachlorophenol

Property | Information
Molecular weight | 266.3^a^
Melting point | 188°C^a^
Boiling point | 310°C^a^
Vapor pressure (mm Hg) | 0.0003 at 25°C^a^
Vapor density (air = 1) | 1.98^a^
Density | 1.978 g/cm^3^ at 22°C^a^
Solubility in water | 14 mg/L at 25°C^b^
Octanol/water partition coefficient (pK_ow_) | 5.12^a^
Henry’s law constant | 2.45 × 10^-8^ atm-m^3^/mole at 22°C^b^
Conversion factors (pentachlorophenol in air)
parts per million (ppm) to µg/m^3^ | μg/m^3^ = 10,900 × (ppm)^c^
µg/m^3^ to parts per million (ppm) | ppm = 9 × 10^-5^ × (μg/m^3^)^c^

^a^ Akron (2010).

^b^ ChemIDplus (2013).

^c^ Smarte.org (2008).

## 1.2 Pentachlorophenol Use and Production Data

Current pentachlorophenol use is limited to the treatment of utility poles, cross arms, wooden pilings (e.g., wharf pilings), fence posts, and lumber or timbers for construction. In the United States, pentachlorophenol-containing products remain registered for wood preservation, and utility poles and cross arms represent about 92% of all uses of pentachlorophenol-treated lumber (ATSDR 2001; USEPA 2010). Pentachlorophenol was first used in the United States in 1936 as a wood preservative to prevent decay from fungal organisms and damage from insects. Pentachlorophenol also was used as a biocide and was found in ropes, paints, adhesives, leather, canvas, insulation, and brick walls. In 1984 indoor uses were cancelled. In 1987 non-wood preservative uses were cancelled and restricted. Prior to 1987, pentachlorophenol was one of the most widely used biocides in the United States (USEPA 2008b). Pentachlorophenol has also been used in the laboratory as a competitive inhibitor of sulfotransferase (Mulder and Scholtens 1977), but this use would involve very small quantities of the substance.

Pentachlorophenol is a high-production-volume chemical in the United States based on data submitted to EPA under the Chemical Data Reporting rule for 2011 of >1 million to 10 million pounds annually. Although no companies currently report production activities in the United States, one U.S.-owned company in North America reports producing pentachlorophenol at a plant in Mexico and formulating the pentachlorophenol at a facility in the United States (Dunn 2013). Earlier, manufacture of pentachlorophenol was reported for at least 6 companies worldwide, including at least 1 company in the United States (SRI Consulting 2012). Table 1-3 presents production data for pentachlorophenol.

Table 1-3 Production Data for Pentachlorophenol

Category | Years Covered | Quantity in Pounds^a^
U.S. EPA CDR rule | 2011 | >1 million to 10 million
U.S. imports (recent)^b^ | 2012 | 14.6 million
U.S. imports (historical)^b^ | 2007 | 0
U.S. exports (recent)^b^ | 2012 | 99,000
U.S. exports (historical)^b^ | 2007 | 697,000

Sources: USEPA (2013a), USITC (2013).

CDR = Chemical Data Reporting Rule, formerly called Inventory Update Rule.

^a^ From 3/2013 Internet searches; data subject to change.

^b^ Reported as “pure pentachlorophenol (not pentachlorophenol preparation) other than put up for retail sale.”

## 1.3 Synthesis of Pentachlorophenol and Its By-products

Synthesis of pentachlorophenol requires a combination of high temperatures and pressure that results in formation of other chlorinated aromatic molecules, particularly chlorinated dibenzo-p-dioxins and dibenzofurans (see below). Pentachlorophenol has only been produced by direct chlorination of phenol in the United States (ATSDR 2001; Ruder and Yiin 2011; Williams 1982), but alkaline hydrolysis of hexachlorobenzene (HCB) might have been used in some instances in other countries (e.g., in Europe or China) (Collins 2013; Dunn 2013).

Direct chlorination of phenol to pentachlorophenol uses heat (>75°C), pressure, and a catalyst to replace the hydrogen atoms on the benzene ring of phenol with chloride atoms (Dunn 2013; Ruder and Yiin 2011; Williams 1982), and the alkaline hydrolysis of hexachlorobenzene to pentachlorophenol also uses high temperatures (approximately 125°C to 275°C) in the presence of caustic soda and solvents (Williams 1982; WHO 1987).

Once pentachlorophenol is manufactured, the solid product is prepared for shipping to end users. It may be converted to flakes by pumping molten pentachlorophenol into a pan, crystallizing it by rolling a water-cooled drum through it, then shaving off the product with a knife and bagging it, to prills by spraying it as a liquid into a tower, forming sleet-like pellets, which collect at the bottom of the tower as beads or pellets or to blocks by pouring molten pentachlorophenol into one or two-ton molds and allowing them to harden before wrapping for shipping.

### 1.3.1 Synthesis of Pentachlorophenol By-products

An inherent result of the elevated temperatures and pressure required for the direct chlorination of phenol to pentachlorophenol and for the alkaline hydrolysis of HCB to pentachlorophenol is the generation of side reactions that produce other chemicals (i.e., by-products of its synthesis) in addition to the final pentachlorophenol product (ATSDR 2001; USEPA 1999; Williams 1982; WHO 1987). As these chemicals are always produced when pentachlorophenol is synthesized, these intrinsic impurities of manufacture are herein referred to as ‘by-products of synthesis.’ Commonly found by-products of both synthetic processes are polychlorinated phenols (tri- and tetra-); HCB; hexa-, hepta-, and octachlorodibenzo-p-dioxins (HxCDD, HpCDD, and OCDD); and hexa-, hepta-, and octachlorodibenzofurans (Collins 2013; Dunn 2013). Table 1-4 presents chemical composition of pentachlorophenol products manufactured by direct chlorination of phenol. The alkaline hydrolysis of HCB to pentachlorophenol also results in formation of 2,3,7,8-tetrachlorodibenzo-p-dioxin (TCDD). However, 2,3,7,8-TCDD has rarely been detected in commercial preparations of pentachlorophenol (WHO 1987) and is not a by-product of pentachlorophenol synthesis by the direct chlorination of phenol, which is the production method used in the United States. Thus, the presence of 2,3,7,8-TCDD in a pentachlorophenol preparation produced in the United States would be considered to be a contaminant rather than a production by-product. As discussed below, synthesis of both pentachlorophenol and trichlorophenol, whose manufacture produces 2,3,7,8-TCDD as a by-product, in the same plant could result in exposure of workers to 2,3,7,8-TCDD.

Table 1-4 Chemical Composition of Pentachlorophenol Products Produced in the United States, ppm

Component | Product
Component | Technical Monsanto^a^ | Technical Dow^b^ | Purified Dow^b^ | Dowicide EC-7^c^ | Dowicide 7^d^
Pentachlorophenol^je^ | 84.6% | 88.4% | 98% | 90.4% | NS
Dichlorophenol | NS | NS | NS | NS | NS
Trichlorophenol | NS | <1,000 | 500 | <1,000 | NS
Tetrachlorophenol | 30,000 | 44,000 | 2,700 | 104,000 | NS
Higher chlorinated phenoxyphenols | NS | 62,000 | 5,000 | NS | NS
Hexachlorobenzene | NS | NS | NS | 400 | NS
2,3,7,8-TCDD | <0.1 | <0.05 | <0.05 | <0.05 | <0.2^f^
Pentachloro-DD | <0.1 | NS | NS | NS | <0.2^f^
Hexachloro-DD | 8 | 4 | <0.5 | 1 | 9
Heptachloro-DD | 520 | 125 | <0.5 | 6.5 | 235
Octachloro-DD | 1,380 | 2,500 | <1.0 | 15 | 250
Tetrachlorodibenzofuran | <4 | NS | NS | NS | <0.2^f^
Pentachloro-DF | 40 | NS | NS | NS | <0.2^f^
Hexachloro-DF | 90 | 30 | <0.5 | 3.4 | 39
Heptachloro-DF | 400 | 80 | <0.5 | 1.8 | 280
Octachloro-DF | 260 | 80 | <0.5 | <1.0 | 230
Hexachlorohydroxy-DF | NS | NS | NS | NS | NS
Heptachlorohydroxy-DF | NS | NS | NS | NS | NS

Source: WHO (1987).

DD = dibenzo-p-dioxins; DF = dibenzofurans; NS = not specified.

^a^ Goldstein et al. (1977), as cited in WHO (1987).

^b^ Schwetz et al. (1974), as cited in WHO (1987).

^c^ Schwetz et al. (1978), as cited in WHO (1987)

^d^ Buser (1975), as cited in WHO (1987).

^e^ Pentachlorophenol content expressed as percent.

^f^ Below detection limit.

### 1.3.2 Pentachlorophenol By-products: Biomonitoring Data

The pentachlorophenol by-products most commonly found in serum samples are the dioxin congeners 1,2,3,6,7,8-HxCDD, 1,2,3,4,6,7,8-HpCDD, and OCDD (Collins et al. 2006; McLean et al. 2009b), which reflect the spectrum of by-products found in the PCP from its manufacture and indicate exposure to pentachlorophenol, including past exposure. The relative levels of these by-products has been proposed by some authors as distinct congener patterns for exposure to pentachlorophenol when individuals have little or no increase in 2,3,7,8-TCDD above the non-exposed reference population level (Collins et al. 2008) (see Figure 1-2). Collins et al. (2008) were able to distinguish between workers exposed to pentachlorophenol and those exposed to 2,4,5-trichlorophenol (TCP), which was manufactured in the same plant; an increase in TCDD levels was seen only in the workers exposed to trichlorophenol.

Figure 1-2

Dioxin Congener Patterns for PCP and TCP Workers: Relative Increase (or Decrease) in Serum Levels of Dioxin Congeners Compared with Reference Population for Pentachlorophenol (PCP) and Trichlorophenol (TCP) Workers^a^

^a^Values shown are for PCP-only workers and TCP-only workers as defined by Collins et al. (2008). Samples were collected 26 to 62 years after occupational exposure.

Source: Collins et al. (2008)

The rectangle drawn around the HxCDD, HpCDD, and OCDD congeners identifies the congener pattern used to distinguish workers exposed to PCP and TCP. Serum levels for dioxin congeners of workers exposed to PCP and TCP were divided by the values from the reference group of unexposed individuals (workers in the same plant who had no known exposure to chlorophenols). The horizontal line at “1” indicates equivalence with the reference group. Bars that extend below the line indicate a lower value for the exposed compared with the reference group.

By-products of pentachlorophenol synthesis have consistently been found in serum samples from people occupationally exposed to pentachlorophenol in multiple settings including pentachlorophenol manufacturers in the United States (Michigan) (Collins et al. 2007; Collins et al. 2006) and in Germany (Päpke et al. 1992), sawmill workers in New Zealand (McLean et al. 2009b; Smith and Lopipero 2001), wood treatment workers and people living near active and former wood treatment facilities in the United States (Florida Karouna-Renier et al. (2007), Texas Dahlgren et al. (2007), and Mississippi Dahlgren et al. (2007)), and pesticide handlers and people living in areas sprayed for control of snail-borne schistosomiasis in China (Schecter et al. 1994). Further, these same by-products have been observed to persist in serum of workers for decades after exposure ceased in sawmill workers (McLean et al. 2009b) and in pentachlorophenol manufacturing workers (Collins et al. 2007). Levels from studies reporting mean values for exposed populations compared with non-exposed individuals are illustrated in Table 1-5.

Table 1-5 PCP By-products in Different Geographic (United States and New Zealand) and Environmental (Near a U.S. Wood Plant) Settings

Study | 4-HxCDD | 6-HxCDD | 9-HxCdd | HpCDD | OCDD | TCDD | PeCDD | TCDF | PeCDF | HxCDF | HpCDF | OCDF
U.S. PCP producers^a^ | ++ | ++ | +++ | ++++ | +++++ | <1.5 | + | inv. | <1.5 | <1.5 | <1.5 | inv.
NZ sawmill workers^b^ | <1.5 | ++ | + | ++ | ++ | <1.5 | <1.5 | NR | NR | NR | NR | NR
U.S. wood plant^c^ | <1.5 | <1.5 | + | +++ | +++ | inv. | inv. | <1.5 | inv. | <1.5 | <1.5 | <1.5
PCP cattle (pg/g fat)^d^ | 10 | 102 | 11 | 328 | 331 | 0 | 6.1 | 0 | 2.4 | 25 | 50 | 73

Fold increase of lipid-adjusted dioxins compared with reference population: <1.5, + = 1.5–1.9, ++ = 2.0–2.5, +++ = 2.5–2.9, ++++ = 5 or greater.

^a^ Collins et al. (2008).

^b^ McLean et al. (2009a).

^c^ Dahlgren et al. (2007).

^d^ Huwe et al. (2004). (No reference group available for PCP-exposed cattle; measure levels are reported.)

Exposure to pentachlorophenol results in markedly higher levels of HxCDD, HpCDD, and OCDD compared with those in reference groups while 2,3,7,8-TCDD levels increase only slightly, if at all (Collins et al. 2008). In contrast, workers exposed to dioxins during manufacture (Päpke et al. 1992) or disposal of phenoxy herbicides (Littorin et al. 1994) or manufacture of trichlorophenol (Collins et al. 2008) show elevations of tetrachlorodioxin that are similar to or greater than those for the hexa-, hepta-, and octachlorodioxins (Littorin et al. 1994; Päpke et al. 1992). Data from one study of pentachlorophenol sprayers in China indicate that levels of 2,3,7,8-TCDD were higher than those seen for U.S. and New Zealand workers exposed to pentachlorophenol (see below); however, these workers may also have been exposed to other pesticides containing 2,3,7,8-TCDD. No information was identified on U.S. restrictions on the presence of TCDD in imported pentachlorophenol.

Other evidence supporting the usefulness of these dioxin congener patterns to demonstrate current or past pentachlorophenol exposures include measurement of attic dust from houses near treatment facilities. Significantly elevated levels of pentachlorophenol by-products, primarily OCDD and HpCDD, also have been detected in samples of household dust collected from homes in the vicinity (i.e., within a 1- to 2-mile radius) of pentachlorophenol wood treatment plants that also showed significantly elevated HpCDD and OCDD levels relative to local general population control groups (e.g., Dallas, TX unexposed controls) (Dahlgren et al. 2007). Elevated levels of dioxins in attic dust, expressed as TCDD toxic equivalents (TEQs), were also reported for sampling locations 1 to 2 miles from active wood treatment facilities in Mississippi, Alabama, and Louisiana (2 facilities) (Feng et al. 2011) and a former wood treatment facility in Alabama (Hensley et al. 2007).

Increased dioxin congeners have also been detected in tissues and milk from cows and pigs exposed to pentachlorophenol-treated wood (see Table 1-5). A pattern of polychlorinated dibenzo-p-dioxins and dibenzofurans (i.e., high amounts of 1,2,3,6,7,8-HxCDD, 1,2,3,4,6,7,8-HpCDD, and OCDD but little or no tetra- or penta-congeners) was found in adipose tissue collected from cattle at agricultural research facilities in the United States where pentachlorophenol-treated wood was present (Huwe et al. 2004). According to the authors, the residue pattern “somewhat resembled” the by-products present in pentachlorophenol that would have been used to treat the wood. Residues of dioxins and furans were also detected in beef and milk from cows exposed to pentachlorophenol-treated wood (Fries et al. 2002; Fries et al. 1999). Ryan (1983) reported levels of HxCDD, HpCDD, and OCDD for tissues and milk from piglets that showed high mortality after being raised on a pentachlorophenol-treated wooden floor.

## 1.4 Characterization of Exposure in the Workplace

Occupational exposure to pentachlorophenol still occurs in the United States for workers who treat lumber or come in contact with treated lumber in their work activities even though no production of pentachlorophenol currently takes place in the United States. This exposure has been documented by measurements of pentachlorophenol in workplace air, work surface wipes, and the blood and urine of exposed workers, including exposure information gathered from a group of NIOSH Hazard Evaluation and Technical Assistance (HETA) surveys. Human exposure to pentachlorophenol occurs in occupational settings through dermal contact with the substance or with treated wood products and via inhalation of affected workplace air. The OSHA PEL and the ACGIH TLV-TWA for pentachlorophenol are both 0.5 mg/m^3^, and both occupational exposure limits include a skin notation, which indicates potential significant contribution to overall exposure via the cutaneous route, including mucous membranes and eyes, by contact with vapors, liquids, and solids (see Appendix B). Sources of exposure to workers in the past have included (1) production plants, (2) wood treatment facilities, including sawmills, and (3) contact during the use or disposal of the treated wood. Other uses are possible in other industries (e.g., as an algaecide, fungicide, or bactericide), such as leather tanning and paint or glue manufacturing, but no exposure data for these uses were identified. Comparisons of exposures across different processes are not possible in all instances; for example, exposure data for manufacturing are limited to air levels while data for other uses include blood and urine levels in some instances.

Pentachlorophenol absorbed in the human body is excreted primarily in the urine as a glucuronide conjugate or unchanged (see Section 2.2.1) (ATSDR 2001), and elimination half-lives of pentachlorophenol between 4 and 72 days have been observed (McLean et al. 2009b). By-products of pentachlorophenol synthesis, however, are believed to have elimination half-lives of up to 10 years (Collins 2013; McLean et al. 2009b). As such, pentachlorophenol measurements in urine or blood can provide estimates of current exposure, and blood measurements of by-products of pentachlorophenol synthesis (e.g., serum dioxin measurements) may provide estimates of past exposure (see Section 1.3).

### 1.4.1 Pentachlorophenol Manufacturing

The most important route of exposure for workers in pentachlorophenol manufacturing is through inhalation. Air sample measurements taken at U.S. manufacturing plants between 1971 and 1983 as part of the NIOSH Dioxin Registry indicate that workers involved in the various stages of production of pentachlorophenol are exposed to the chemical in workplace air (see Appendix B, Table B-1). Based on the air samples, both area and personal, taken at the factories over several years, exposure varied by work area. Although there was some indication that specific areas had higher airborne levels, results varied for each site and for different years. As described by Marlow et al. (1991), the “chlorination area,” i.e., the factory site where phenol is directly chlorinated, had airborne pentachlorophenol levels as high as 4.5 mg/m^3^ in 1976, but maximum levels for other years did not exceed 0.14 mg/m^3^ (area sample in 1980). A related area tagged “chlorination area, torch burning” reported a single unusually high level of 68.69 mg/m^3^ (area sample in 1971). Workers handling the chemical “blocks” near the end of production or in the packaging area could also be exposed to appreciable levels, up to 14 mg/m^3^ (area sample in 1979) or 17 mg/m^3^ (area sample in 1976), respectively, while levels in the warehouse were consistently low.

### 1.4.2 Workers Processing or Using Pentachlorophenol to Treat Wood Products

Very high levels of exposure to pentachlorophenol have been reported for some workers handling the product in preparation for its use as a wood preservative or other end uses. Pentachlorophenol is most commonly used as a solution in petroleum-based products or as its salt sodium pentachlorophenate in a water-based solution. In either case, exposure can occur to workers who process the original product to formulate solutions for end users. The processing step can be carried out by the same company that produces pentachlorophenol as blocks, flakes, or prills at either the same location or at another facility (KMG Chemicals 2011), by intermediate processors, or by the end user at a sawmill or wood-treatment facility where solutions are prepared onsite from solid pentachlorophenol. In all instances of use of pentachlorophenol, dermal exposure is much more likely than during manufacture, where inhalation is the more important route.

Table B-2 (Appendix B) lists blood and urine pentachlorophenol levels for workers exposed in various processing and wood treating steps. Wood preservations workers were reported by Cline et al. (1989) to have mean serum pentachlorophenol levels of 0.49 ppm. Only urine levels were available for sawmill and wood treatment workers in other studies, but the highest mean value (2.8 ppm) was reported for mixers of concentrated pentachlorophenol at a sawmill in New Zealand (McLean et al. 2009a).

The major route of exposure for workers using pentachlorophenol to treat wood is dermal (as much as 95% of total exposure based on urinary chlorophenol levels for sawmill workers exposed dermally) to the solutions used to treat a variety of wood products (Demers 2013; Fenske et al. 1987). The wood products are treated with solutions of pentachlorophenol in oil or sodium pentachlorophenate in water. The dermal exposure of these workers occurs due to the manner in which pentachlorophenol is used and because of its low vapor pressure, which limits inhalation exposure in these settings mainly to mist from the pentachlorophenol solutions (Demers et al. (2006); Santodonato (1986), as cited in ATSDR (2001)). Dermal exposure can occur during both pressure and non-pressure treating processes (Williams 1982). Exposure to wood preservatives can occur in a variety of ways, including during mixing and handling of the chemicals, entering pressure-treatment cylinders, preservative spraying or dipping, handling freshly treated wood, cleaning or repairing equipment, or disposing of wastes (Thomasson et al. 2006). Wearing of protective equipment (e.g., gloves and aprons) in areas where pentachlorophenol is sprayed or where basic joinery occurs (i.e., construction of roof trusses, pallets, etc.) can help mitigate these exposures (Jones et al. 1986).

Inhalation can also occur in these occupational settings during pressure treating of wood; inhalation exposure can occur when the door to the pressure chamber is opened. The greatest inhalation exposure to workers during the wood treatment process occurred during the manual handling of bagged pentachlorophenol in an industrial facility that reported lower, but detectable, levels in the air for other tasks. Measurements in personal workplace air ranged up to 2.00 mg/m^3^ with area levels to 3.83 mg/m^3^ (Markel and Lucas 1975).

Data from the NIOSH National Occupational Exposure Survey (NOES), conducted between 1981 and 1983, estimated that about 27,000 workers were potentially exposed to pentachlorophenol during that time period (NIOSH 1990) (Note: The NOES database has not been updated since July 1, 1990, and NIOSH has not conducted any national surveys of occupational exposure since that time). Census data from 2007 indicate that about 13,000 workers in the wood preservative industry may have been potentially exposed (Dunn 2013). Industry estimates indicate that less than 1,000 production workers in facilities using pentachlorophenol for wood treatment may be potentially exposed (Estreicher 2013).

### 1.4.3 Handlers and Users of Pentachlorophenol-treated Wood

Exposure in workers who have contact with wood that has been treated with pentachlorophenol has been assessed for several groups, including those working at plywood mills and paper mills, as well as fence installers and electrical utility linemen. Levels of urinary pentachlorophenol were elevated for wood preservation workers (handlers) who had a mean value of 0.49 ppm and for employees in a log museum with pentachlorophenol-treated logs (mean of 0.45 ppm) (see Appendix B, Table B-2, Table B-3).

## 1.5 Non-occupational Exposure of People to Pentachlorophenol

Exposure to pentachlorophenol is widespread for people living in the United States because of its presence and persistence in the environment, and this exposure has been documented by measurements during the last decade or so of levels of pentachlorophenol in blood and urine that reflect current exposure (see Section 1.5.1) and levels in tissues such as liver, brain, kidneys, spleen, and body fat (see Section 2.1.1) that likely reflect more long-term exposure. Dioxin congeners making up the distinct pattern for current and/or past exposure also have been demonstrated in samples collected in the last 10 years. In addition to this documentation for current or recent exposure of the U.S. general population to pentachlorophenol, the evidence for past exposure, i.e., the 1990s and earlier, is very extensive and indicates levels of exposure more than 10-fold higher than recent exposures. The decrease in exposure from the period 30 to 40 years or more ago to the present is consistent with actions taken by EPA to restrict pentachlorophenol use as a heavy-duty preservative, cancelling and restricting non-wood uses in the 1984 Registration Eligibility Decision and finalizing that decision in 1987.

Studies of current or recent exposure are discussed in Section 1.5.1, past exposures in Section 1.5.2, and sources of exposure to pentachlorophenol in Section 1.5.3. Exposure data tables and regulations are provided at the end of Appendix B.

### 1.5.1 Current or Recent Exposures and Biomonitoring

Data for releases to the environment through the continued use of pentachlorophenol for treatment of wood in limited settings indicate continuing exposure to nearby residents. Direct release of pentachlorophenol into the atmosphere occurs via volatilization from pentachlorophenol-treated wood (ATSDR 2001). Pentachlorophenol also can be released to the atmosphere from incineration of chlorine-containing wastes and from pyrolysis of polyvinyl chlorides. Historically, atmospheric releases of pentachlorophenol (used as a slimicide) from cooling tower waters also has occurred, but pentachlorophenol and its salt are no longer commonly used for this purpose since its use restriction in 1984.

Data for air, dust, urine, and blood measurements for individuals living in the vicinity of active wood treatment facilities in the United States reflect release of pentachlorophenol from these facilities into the environment. Individuals living near sites where pentachlorophenol is used, such as wood-treatment facilities, are more likely to be exposed than other members of the general public. Exposure of the general population to pentachlorophenol is most likely to result from inhalation of air or from dietary or non-dietary ingestion. Dermal exposure could occur, but it would not be expected to represent a large part of exposure as it does for workers using pentachlorophenol in wood-treatment facilities. Exposure to individuals is most commonly monitored by collection and analysis of urine samples, which can be analyzed for pentachlorophenol, and by collection and analysis of blood samples for both pentachlorophenol and the dioxin congeners that are by-products of its synthesis. Potential environmental sources of exposure are monitored by measurements of pentachlorophenol in indoor and outdoor air, household dust from floors and other surfaces, and soil outside houses.

Evidence for exposure to pentachlorophenol in the United States after use was restricted comes primarily from samples taken from people and homes near wood treatment facilities, from samples taken from preschool children and from their homes and daycare centers, and from the results of the most recent data from the National Health and Nutrition Examination Survey (NHANES).

Dahlgren et al. (2007) and coworkers collected blood samples from 29 residents of a neighborhood adjacent to a wood-treatment plant in a small town in Mississippi where the plant had treated railroad cross ties with creosote and pentachlorophenol since 1904. Blood levels of dioxin congeners from this study and from 200 controls from the general population of Dallas, Texas are listed in Table 1-6 showing the congener pattern of increases in the higher chlorinated dioxins for these studies. The authors also calculated mean levels for attic dust, soil, and sediment samples combined for the area near the facility and compared them with Mississippi Department of Environmental Quality (MDEQ) Soil Cleanup Target Levels. The authors were not able to explain the large TEQ values for these samples other than by the presence of the wood-treatment facility. They also noted that the current blood levels of dioxin congeners could reflect current exposure, prior exposure, or a combination of both.

Table 1-6 Dioxin Congeners in Blood of Residents Near Wood-treatment Facilities in Mississippi

Dioxin Congener, ppt (Lipid Based) | Blood Levels (ppt) | | Soil Levels (ppt)
Dioxin Congener, ppt (Lipid Based) | Near Wood Treatment, N = 29 | General Population (Dallas, TX), N = 200 | Homes Near Wood Treatment, N = 10 | MDEQ Soil Cleanup Targets
TCDD | 3.4 | 3.8 | 3.068 | 4.26
HxCDD | 71.3 | 54.5 | 1,669.238 | 248.60
HpCDD | 132.0 | 45.1 | 34,788.292 | 426.00
OCDD | 1,049 | 374 | 271,366.694 | 4,260.00

Source: Dahlgren et al. (2007).

MDEQ = Mississippi Department of Environmental Quality.

Evidence for recent exposure to pentachlorophenol was also reported in a series of studies of preschool children (Wilson et al. 2003; 2007) that detected pentachlorophenol in indoor and outdoor air, floor or house dust collected at daycare centers or the children’s homes, and urine from the children living in North Carolina and Ohio. Pentachlorophenol was detectable in these environmental media, and the children in both studies had detectable levels in their urine (Table 1-7) (Wilson et al. 2003; 2007).

Table 1-7 Environmental Samples from Daycare Centers and Homes of Preschool Children

Analyte | Wilson et al. (2003) | | Wilson et al. (2007)
Analyte | Day Care | Home | Day Care NC, OH | Home NC, OH
Indoor air, ng/m^3^ | 0.918 | 9.11^a^ | 1.16, 1.32 | 1.50, 2.14
Outdoor air, ng/m^3^ | 0.480 | 0.244 | 0.770, 0.220 | 0.910, 0.430
House or floor dust, ng/g | 0.050 | 0.135 | 81.3, 35.6 | 59.8, 59.8
Urine (48 hr) ng/mL | 0.329 ng/mL (0.175–0.666)^a^ | | 0.419–0.993 ng/mL ^b^

^a^ Mean (range) for 9 children (2–5 yr old). The authors noted that creatinine-adjusted values were not included because of the uncertainty of the applicability of this adjustment to data for young children.

^b^ Geometric means for 254 children (120 daycare, 134 home care).

Urinary pentachlorophenol measurement in the most recent NHANES dataset (2003 to 2004) (September 2013 update) showed levels at the 95th percentile of 4.58 μg/L for men and 3.20 μg/L for women and at the 75th percentile of 1.32 μg/L for men and 0.880 μg/L for women, but the proportions of results below the limit of detection (0.5 μg/L) were too high (~66%) to allow for calculation of valid geometric means. However, exposure to even 34% of the U.S. population equates to more than 100 million individuals (CDC 2011; CDC 2013a). These results show a decrease in pentachlorophenol levels in the general public compared with results of earlier NHANES studies. Results from NHANES II (1976 to 1980) showed that pentachlorophenol was detectable in urine in 71.6% of the general population, and geometric means for males were 6.7 ng/mL (μg/L) while those for females tended to be lower at 5.9 ng/mL (μg/L) (Kutz et al. 1992). However, the urinary pentachlorophenol measurement in the 2001–2002 NHANES dataset showed somewhat lower levels at the 95th percentile of 1.94 μg/L for men and 1.98 μg/L for women compared with the 2003–2004 results (CDC 2009). One possible factor contributing to the increase in urinary pentachlorophenol measurements from the 2001–2002 NHANES dataset to the 2003–2004 dataset could be metabolic transformation of other chlorinated compounds within the body (see Section 1.5.3); CDC notes that pentachlorophenol is a metabolite of several organochlorine insecticides (CDC 2013b).

Thus, the evidence of exposure from these recent studies is consistent with continuing exposure to pentachlorophenol for many individuals in the United States based on environmental levels and urinary excretion that are easily measurable. However, the levels of these exposures are generally lower than those from 3 or 4 decades ago due to the greater past uses of pentachlorophenol. Zheng et al. (2011) conducted a meta-regression analysis of 80 studies with data from 21 countries published between 1967 and 2010. The trends for blood and urine levels are illustrated in Figure 1-3a,b.

Figure 1-3

(a) Trends in Blood Levels for North America, Germany, and Other European Countries and (b) in Urinary Levels for the United States and Germany

The data shown in Figure 1-3 illustrate several important points for exposure to pentachlorophenol.

1. They indicate that levels of approximately 1 μg/L pentachlorophenol have been reported in blood and urine for samples collected in studies in North America and Europe during the last 10 to 15 years, and these are slightly higher than levels reported recently for children in the United States by Wilson et al. (2003); Wilson et al. (2007) and Wilson et al. (2010).
2. They clearly demonstrate the decrease in levels of exposure over time. Blood levels for North America, Germany, and other European countries (Figure 1-3a) and for the United States and Germany (Figure 1-3b) decreased over time.
3. The patterns of exposure show considerable similarity for the United States (and North America) compared with European countries. This is reasonable since the United States and most European countries took actions to restrict use of pentachlorophenol in the 1980s and use of pentachlorophenol declined in these areas since that time.

Although no significant gender difference was found for blood levels in the United States (Cline et al. 1989), significantly (p < 0.019) higher levels were reported for children (ages 2 to 7 years) compared with individuals over 15 years among Canadian Inuit (Sandau et al. 2000). Other data indicated that serum pentachlorophenol in children of all ages was approximately twice as high as in their parents. NHANES data for 2003–2004 indicate that urinary pentachlorophenol levels at the 95th percentile are higher for children age 6 to 11 years (5.67 µg/L) than for age 20 years and older (3.4 µg/L) (CDC 2013a). In contrast, mean pentachlorophenol levels in urine have been reported to be higher in adults than in children (Zheng et al. 2011).

Recent estimates for potential exposure were calculated by Wilson et al. (2003); Wilson et al. (2007) and Wilson et al. (2010) based on diet, inhalation, and non-dietary ingestion. Estimates of aggregate potential dose for two groups of children were 7.26 and 8.83 ng/kg/day with approximately half the total exposure resulting from inhalation. Wilson et al. (2003); Wilson et al. (2007) and Wilson et al. (2010) estimated potential doses for children in two households for dietary ingestion (37% or 51%), inhalation (54% or 43%), and non-dietary, indirect ingestion (9% or 6%).

### 1.5.2 Past Exposures (More Than 15 Years Ago)

As noted above, more extensive exposure to pentachlorophenol occurred in the past because of its more widespread use as a pesticide for many uses besides treating wood. Pentachlorophenol levels in blood and urine (see Appendix B, Table B-4) in the range of 10s to 100s of μg/L for blood and generally around 10 μg/L for urine (see also Figure 1-3 for U.S. and European data) were reported for people living in the United States in studies published from the late 1960s through the 1980s.

Potential sources of exposure to pentachlorophenol in the past are discussed below along with information on environmental occurrence (i.e., air, dust, water, and soil levels) that resulted from those exposures.

### 1.5.3 Sources of Exposure to Pentachlorophenol

Current or past exposure to pentachlorophenol is primarily attributable to its release during production and particularly during its processing and use, which result in both occupational exposure to workers and exposure to the general public. Exposures to the general population have been modeled based on exposure from ingestion of food, inhalation of air, and other potential sources. The main routes of exposure to the general public are through inhalation of air and ingestion of food. Releases of pentachlorophenol can result from the presence of treated wood in the environment as well as from the releases that occur during production, processing, and use in treating wood products. Several studies have also reported high levels of exposure to people living in log homes or other houses treated with pentachlorophenol. Exposure for the general public to pentachlorophenol from food, water, and dust has also been identified.

#### Modeling Studies of Exposure to the General Population

A number of modeling studies were carried out using exposure data from the 1980s, when environmental exposure to pentachlorophenol would likely have been higher than for more recent time periods. The estimated daily intake of pentachlorophenol for adults in the United States was 16 μg/day in a model published by Hattemer-Frey and Travis (1989), which estimated levels in food from environmental distribution of pentachlorophenol and uptake into plants and animals. The range of estimates from Canada (2.6 μg/day, adjusted for a 70-kg adult) (Coad and Newhook 1992), the United Kingdom (4.53 μg/day) (Wild et al. 1992; Wild and Jones 1992), and Germany (19.4 μg/day) (Geyer et al. 1987), as well as from the United States, might be explained by differences in modeling assumptions as well as from geography and time period of data collection since uses of pentachlorophenol were changing in the late 1980s due to restrictions on use.

#### Releases from Production, Processing, and Use to Treat Wood

Pentachlorophenol has been widely used throughout the United States historically as a pesticide and currently as a heavy-duty wood preservative. Thus, based on releases of pentachlorophenol at wood treatment facilities in the United States and the widespread distribution of Superfund sites where pentachlorophenol is listed as a site contaminant, dispersion modeling data support likely widespread exposure of the general population to pentachlorophenol. Pentachlorophenol is not currently produced within the United States, but a production plant belonging to a U.S company operates just across the border from Brownsville, Texas in Matamoros, Mexico, and pentachlorophenol released to the air during production there could travel hundreds of miles into the United States. This is supported by pentachlorophenol emission transport calculations from Hungarian and United Kingdom emission sources and multimedia modeling estimates that indicate pentachlorophenol can be transported over substantial distances (1,500 to 3,000 km [930 to 1,860 mi]) with a half-life in the environment of approximately 1.5 months (Berdowski et al. 1997; Duchak et al. 2002; Shatalov 2002), as cited in Borysiewicz (2008). The European dispersion modeling data also support possible widespread exposure of the general population to pentachlorophenol from its current use as a wood preservative or because of its past widespread use historically as a pesticide and continuing presence in the environment.

Evidence that pentachlorophenol is currently released to the environment in the United States comes from the U.S. Environmental Protection Agency’s (EPA) Toxics Release Inventory (TRI), the National Priorities List (NPL), and the National Response Center (NRC). TRI lists the total reported on- and off-site release of pentachlorophenol as slightly over 96,000 lb. from approximately 30 facilities in 2011 (USEPA 2013b). Releases to land (RCRA Subtitle C landfills) accounted for 92.9% of total releases, off-site disposal for 6.3%, releases to water for 0.5%, and releases to air for 0.3%. Sites with reported on-site releases are concentrated in the southeastern and northwestern United States, with the highest reported release (89,200 lb.) by a hazardous waste treatment and disposal facility operating a hazardous waste landfill on the border between Oregon and Washington State. In addition to these sites, 220 Superfund sites on the National Priorities List at which pentachlorophenol was listed as a site contaminant appear to be distributed throughout the United States and Alaska, but more commonly in the eastern half of the nation (TOXMAP 2013). Based on a review of spill report data from the National Response Center (National Response Center (NRC) 2013) covering the period from January 1, 1990 to the present, 100 chemical spill incidences were reported involving “pentachlorophenol” (N = 97) or “sodium pentachlorophenate” (N = 3).

Although the pentachlorophenol released during production, processing, and use could become a contaminant in any environmental medium (i.e., air, water, soil, and dust), pentachlorophenol in air is likely to result from those releases and to cause exposure to workers and the general public. Pentachlorophenol is detectable in air samples from multiple sources (see Appendix B, Table B-5 and Table B-6 and Figure 1-4) ranging from <1 ng/m^3^ in air from rural settings to approximately five orders of magnitude higher in industrial settings where pentachlorophenol is manufactured or used, in homes near sites of use of pentachlorophenol, (e.g., wood treatment facilities, or in log homes treated with pentachlorophenol, as discussed in the section below) (WHO 1987; Zheng et al. 2011).

Figure 1-4

Comparison of Pentachlorophenol Concentration Ranges in Air from Different Sources

Other evidence for the presence of pentachlorophenol in the environment comes from measurements of household dust and of soil. Sampling of household dust in homes in the vicinity (i.e., within a 1 to 2-mile radius) of pentachlorophenol wood treatment plants has shown significantly elevated levels of pentachlorophenol by-products (Dahlgren et al. 2007) (see Section 1.5.1). The two highest levels of pentachlorophenol in soil (200,000 and 45,600 μg/kg soil) were for samples collected immediately beneath production sites for pentachlorophenol. Other onsite samples exceeded 10,000 μg/kg; however, levels in soil sampled in the vicinity of pentachlorophenol production facilities were in the range of only 12 to 184 μg/kg.

#### Exposure from Log Homes and Other Treated Wood Products

The general population can be exposed to pentachlorophenol released from treated wood, especially if that wood is used for building houses such as log homes. Several publications reported much higher levels of exposure for people living in pentachlorophenol-treated log homes (Cline et al. 1989; Hernandez and Strassman 1980) with some blood levels exceeding 1,000 μg/L. Similar exposure was reported for workers in the log museum at Fort Stanwix National Monument in Rome, NY (see Appendix B, Table B-7), but washing the surfaces of the logs with ethyl alcohol to remove crystals of pentachlorophenol greatly reduced exposure for those workers. Some of the highest levels of pentachlorophenol in indoor air (as much as five orders of magnitude higher than ambient levels) (see Figure 1-4) have been associated with log homes treated with pentachlorophenol (WHO 1987; Zheng et al. 2011). Concentrations of pentachlorophenol have also been measured in dust sampled from the houses of residents in Germany using wood preservatives at a median value of 13.3 µg/g (N = 65) versus 0.008 µg/g (N = 41) for controls (Krause et al. 1989).

Because wood products treated with pentachlorophenol (e.g., utility poles) often are in contact with soil, this provides another potential route of exposure to pentachlorophenol. Exposure of the general population to pentachlorophenol from the soil is less likely than for inhalation of contaminated air, but ATSDR (2001) noted that small children have a tendency to eat soil and to put their hands or foreign objects in their mouths, which could expose them to pentachlorophenol present in the soil or on the objects. Pentachlorophenol can be released to soil via leaching from treated wood products (e.g., utility poles) that results from downward movement within the pole due to movement of the solvent as a result of gravity (ATSDR 2001). In a study of 180 in-use utility poles, surface soil samples generally showed higher levels of pentachlorophenol than subsurface soil samples, and pentachlorophenol soil concentrations decreased exponentially with distance from the pole (USEPA 1999) (see Appendix B, Table B-8). Based on estimates of the number of preservative-treated wood utility poles currently in service in the United States (120 to 200 million), the percentage of the total annual preserved utility pole production estimated to be treated with pentachlorophenol (62%), and the percentage of pentachlorophenol-treated poles replaced annually (3%), approximately 2.2 million to 3.7 million pentachlorophenol-treated utility poles per year could be treated and emplaced (Bolin and Smith 2011; USEPA 2008a).

#### Exposure from Food, Water, and Dust

While pentachlorophenol in food was found to be an important source of exposure in the models for environmental exposure, the available data indicate that pentachlorophenol was found at higher levels more frequently in foods from time periods before its restricted use, but that low levels of pentachlorophenol continued to be found in food in the time period after its restricted use (1991 to 1993 and 2003 to 2004). In the period of 1965 to 1970, pentachlorophenol had as much as a 3.3% average positive incidence in food composites in the United States (Duggan and Corneliussen (1972) as cited in WHO (2004)).In comparison, in the April 1982 to April 1984 time period, pentachlorophenol was detected in 15% of the foods from 8 United States market basket surveys (Gunderson (1988), as cited in ATSDR (2001)). Based on analytical results for U.S. Food and Drug Administration Total Diet Study market baskets 1991 to 1993 through 2003 to 2004 collected between September 1991 and October 2003, pentachlorophenol was found at levels ranging from 0.01 to 0.02 ppm in only 1 out of 44 samples in two food categories: (1) ham, cured (not canned), baked and (2) chicken breast, oven-roasted (skin removed) (FDA 2006). Although both of the earlier samples reported more frequent detection of pentachlorophenol in foods compared with the period after 1990, it is not clear why the earliest period (1965 to 1970) had a lower percentage than the period from 1982 to 1984.

Pentachlorophenol was also reported in a wide variety of foods such as meats, fish, dairy products, grains and vegetables (see Appendix B, Table B-9) in studies from Canada, the United Kingdom, and Germany from the 1980s. Levels of pentachlorophenol in food varied in the different studies, and no clear patterns were observed for specific types of food or geographical areas. In a more recent report, no pentachlorophenol was detected in 1995 to 1996 in a Danish National Pesticide Monitoring Program that sampled fruits, vegetables, dairy foods, meats, and other foods (ATSDR 2001).

Pentachlorophenol has been detected in drinking water supplies as well as in groundwater and surface water. The data reported here are for measurements made before restrictions were placed on the use of pentachlorophenol and are reported from several secondary sources; no recent reports of levels in water were identified. Pentachlorophenol concentrations in drinking water have been reported to range from <1 to 50 µg/L (ATSDR 2001; WHO 1987), which can result in part from synthesis of pentachlorophenol due to chlorination of phenolic compounds during water treatment (Detrick (1977); Smith et al. (1976) as cited in ATSDR (2001)) (see Appendix B, Table B-10). Pentachlorophenol has been detected in groundwater at levels ranging from 0.6 to 19,000 µg/L (ATSDR 2001; WHO 1987). Higher levels were reported for groundwater near industrial areas such as wood preserving facilities. Pentachlorophenol levels in surface water have been reported to range from non-detectable to 10,500 µg/L (WHO 1987; Zheng et al. 2011).

Releases of pentachlorophenol to surface water can occur through direct discharge and entry from nonpoint sources such as treated wood. Additionally, wet deposition from the atmosphere and runoff and leaching from soil also can transport pentachlorophenol to surface water (ATSDR 2001).

Pentachlorophenol has been detected on household dust, as noted above, but Liebl et al. (1996) (as cited in Schnelle-Kreis et al. (2000)) did not find a correlation between pentachlorophenol dust concentrations and pentachlorophenol in blood plasma. Ingestion of non-dietary pentachlorophenol, such as that associated with dust, has been considered a minor contributor to exposure (Wilson et al. 2007; Wilson et al. 2010), but it might be more of a factor for small children because of their contact with dust on floors.

#### Other Sources of Exposure

Pentachlorophenol has been detected in commercial samples (9 of 65 samples at concentrations ranging from 100 to 2,700 mg/kg) of paints used on children’s toys in the United States in a study from the 1970s (van Langeveld (1975) as cited in WHO (1987)), and at low levels in clothing samples (concentrations ranging from 0.015 to 0.96 mg/kg) from Switzerland (Siegwart (1983) as cited in WHO (1987)).

A potential source of pentachlorophenol exposure to people that was not taken into account in the models described above is the metabolic transformation of other chlorinated compounds within the body (WHO 1987). The chlorinated compounds that can give rise to pentachlorophenol include hexachlorobenzene, pentachlorobenzene, pentachloronitrobenzene, γ-2,3,4,5,6-pentachlorocyclohexene, lindane, and other hexachlorocyclohexanes. WHO suggested that this source of endogenous production of pentachlorophenol, particularly from hexachlorobenzene, could explain the low level of pentachlorophenol excretion from people with no apparent exposure to pentachlorophenol; however, the extent to which this occurs has not been established.

## 1.6 Synthesis and Summary

U.S. exposure to pentachlorophenol and by-products of its synthesis is significant based on available biomonitoring data, its widespread past use as a pesticide, and current use in treated-wood products. Exposures have decreased by at least an order of magnitude in recent years (e.g., the last 10 to 15 years) compared with exposures prior to restrictions on use of pentachlorophenol to treat certain wood products in the 1980s. People living near wood treatment facilities that use pentachlorophenol may be exposed through the air or through soil contamination. Modeling studies of pentachlorophenol intake by humans in the United States indicate that human exposure in the 1980s or before occurred primarily from the food chain (i.e., fruits, grains, and vegetables), but more current data indicate that this source has declined in importance.

Synthesis of pentachlorophenol involves conditions of high temperatures and pressure that result in formation of additional chlorinated aromatic molecules, particularly dibenzo-p-dioxins and dibenzofurans, as by-products of its synthesis. Human exposure to pentachlorophenol and its by-products occurs in occupational settings via inhalation of affected workplace air and dermal contact with the substance or with treated wood products. Occupational exposure has been documented by measurements of pentachlorophenol in workplace air, on work surface wipes, and in the blood and urine of exposed workers. Individuals exposed to pentachlorophenol occupationally also have a pattern of increased by-products, particularly the hexa-, hepta-, and octachlorodioxin congeners, that reflect their long-term exposure.

Pentachlorophenol was ubiquitously distributed in the environment in the past as evidenced by measured levels reported for surface water, groundwater, drinking water, ambient and indoor air, soil, sediment, and food from several countries and time periods. Current exposures are generally lower than those in the past, but exposures to workers using pentachlorophenol and to the general public still occur for a significant number of people living in the United States. Levels of pentachlorophenol in indoor air in industrial settings can be as much as five orders of magnitude higher than ambient levels. The by-products of pentachlorophenol manufacture have been detected in people exposed to pentachlorophenol occupationally in the past or from exposures of the general public to air and dust, particularly at sites near production or use of pentachlorophenol.