# Publication Details

Publisher: National Toxicology Program

Publishing Location: Research Triangle Park, NC

ISSN: 2331-267X

DOI: https://doi.org/10.22427/ROC-MGRAPH-03

Report Series: RoC Monograph Series

Report Series Number: 03

Official citation: National Toxicology Program (NTP). 2014. Report on Carcinogens monograph on pentachlorophenol and by-products of its synthesis. Research Triangle Park, NC: National Toxicology Program. RoC Monograph 03.