# Peer Review

Peer review of the Draft RoC Monograph on Pentachlorophenol and By-Products of its Synthesis was conducted by an ad hoc expert panel at a public meeting held December 12–13, 2013, in the Rodbell Auditorium at the National Institute of Environmental Health Sciences, David P. Rall Building, Research Triangle Park, NC (see https://ntp.niehs.nih.gov/go/38854) for materials, minutes, and panel recommendations from the peer review meeting). The selection of panel members and conduct of the peer review were performed in accordance with the Federal Advisory Committee Act and Federal policies and regulations. The panel members served as independent scientists, not as representatives of any institution, company, or governmental agency.

The charge to the Peer-Review Panel was as follows:

1. To comment on the draft cancer evaluation component, specifically, whether it is technically correct and clearly stated, whether NTP has objectively presented and assessed the scientific evidence, and whether the scientific evidence is adequate for applying the listing criteria.
2. To comment on the draft substance profile, specifically, whether the scientific evidence supports NTP’s preliminary RoC listing decision for the substance (available in the RoC, first listed in the 13th edition, at https://ntp.niehs.nih.gov/ntp/roc/content/profiles/toluidine.pdf).

The Panel was asked to vote on the following questions:

1. Whether the scientific evidence supports NTP’s conclusion on the level of evidence for carcinogenicity from cancer studies in humans.
2. Whether the scientific evidence supports NTP’s conclusion on the level of evidence for carcinogenicity from cancer studies in experimental animals.
3. Whether the scientific evidence supports NTP’s preliminary policy decision on the RoC listing status of the substance.

This RoC monograph on pentachlorophenol and by-products of its synthesis has been revised based on NTP’s review of the Panel’s peer-review comments. The Peer-Review Panel Report, which captures the Panel recommendations for listing status of pentachlorophenol and by-products of its synthesis in the RoC and their scientific comments, and the NTP Response to the Peer-Review Report are available on the Peer-Review Meeting webpage for pentachlorophenol (https://ntp.niehs.nih.gov/go/38854).

## Peer Reviewers*

- Kenneth McMartin, Ph.D. (Chair)
  Professor
  Department of Pharmacology, Toxicology and Neuroscience
  Louisiana State University Health Sciences Center
  Shreveport, Louisiana, USA
- Stelvio M. Bandiera, Ph.D.
  Professor
  Pharmaceutical Sciences
  University of British Columbia
  Vancouver, British Columbia, Canada
- Laura Beane-Freeman, Ph.D.
  Tenure Track Investigator
  Occupational and Environmental Epidemiology Branch
  Division of Cancer Epidemiology and Genetics
  National Cancer Institute
  Bethesda, Maryland, USA
- Stephen Nesnow, Ph.D.
  Scientist Emeritus
  National Health and Environmental Effects Research Laboratory
  U.S. Environmental Protection Agency
  Research Triangle Park, North Carolina, USA
- Martha Sandy, Ph.D.
  Chief
  Reproductive and Cancer Hazard Assessment Branch
  California Environmental Protection Agency
  Oakland, California, USA
- MaryJane Selgrade, Ph.D., ATS
  Expert Consultant
  Environmental Risk & Toxicology
  ICF International
  Durham, North Carolina, USA
- Allan Smith, M.D., Ph.D.
  Professor
  Department of Epidemiology
  School of Public Health
  University of California, Berkeley
  Berkeley, California, USA
- Glenn Talaska, Ph.D.
  Professor, Associate Director, Department of Environmental Health
  Director, Division of Industrial and Environmental Hygiene and Biological Monitoring Component
  University of Cincinnati
  Cincinnati, Ohio, USA
- Paul Villeneuve, Ph.D.
  Associate Professor
  Institute of Health: Science, Technology and Policy
  Carleton University
  Ottawa, Ontario, Canada
- Elizabeth Ward, Ph.D.
  National Vice President for Intramural Research
  American Cancer Society
  Atlanta, Georgia, USA
- Shelia Zahm, Sc.D.
  Independent Consultant

*Two reports were peer reviewed at the meeting: RoC Monograph on ortho-Toluidine and RoC Monograph on Pentachlorophenol and By-Products of Its Synthesis. Gabriele Sabbioni, Ph.D., Tulane University, did not participate in the review of the monograph on pentachlorophenol and by-products of its synthesis.