# Abbreviations

  ^1^H NMR: proton nuclear magnetic resonance
  2,3,7,8-TCDD: 2,3,7,8-tetrachlorodibenzo-p-dioxin, TCDD
  2,4,5-TCP: 2,4,5-trichlorophenol
  8-OH-dG: 8-hydroxydeoxyguanosine
  AAF: 2-acetylaminofluorene
  ACGIH: American Conference of Governmental Industrial Hygienists
  AhR: aryl hydrocarbon receptor
  ALL: acute lymphocytic leukemia
  ARNT: aryl hydrocarbon nuclear translocator
  ATSDR: Agency for Toxic Substances and Disease Registry
  BDL: below detection limit
  CHO: Chinese hamster ovary
  Cl_4_-1,2-BQ: tetrachloro-1,2-benzoquinone
  Cl_4_-1,2-SQ: tetrachloro-1,2-benzosemiquinone
  Cl_4_-1,4-BQ: tetrachloro-1,4-benzoquinone
  CL_4_-1,4-SQ: tetrachloro-1,4-benzosemiquinone
  Cx: connexin
  Cx32: gap junction beta 1-protein; connexin32
  dA: deoxyadenosine
  DEN: diethylnitrosamine
  dG: deoxyguanosine
  DMV: Division of Motor Vehicles (U.S.)
  DNA: deoxyribonucleic acid
  dw: drinking water
  Endo III: endonuclease III
  EPA: Environmental Protection Agency
  Exp.: exposed
  F: female
  FDA: Food and Drug Administration
  FTE: full-time equivalent
  G: guanine
  GI: gastrointestinal
  GIS: Geographic Information System
  HBV: Hepatitis B virus
  HCB: hexachlorobenzene
  HCFA: Health Care Financing Administration (U.S.)
  HCL: hairy-cell leukemia
  HCV: Hepatitis C virus
  HDAC: histone deacetylase
  HEG: (2-hydroxyethyl) guanine
  HETA: Health Hazard Evaluation and Technical Assistance
  HGPRT: hypoxanthine-guanine phosphoribosyl transferase
  HHE: Health Hazard Evaluation
  HIC: highest ineffective concentration
  HID: highest ineffective dose
  HIV: Human immunodeficiency virus
  HpCDD: 1,2,3,4,6,7,8-heptachlorodibenzo-p-dioxin
  HPLC: high-performance liquid chromatography
  hr: hour
  HWE: healthy worker (hire or survival) effect
  HxCDD: 1,2,3,4,7,8-hexachlorodibenzo-p-dioxin (1,4-HxCDD) or 1,2,3,6,7,8-hexachlorodibenzo-p-dioxin (1,6-HxCDD) or 1,2,3,7,8,9-hexachlorodibenzo-p-dioxin (1,9-HxCDD)
  I: inconclusive
  i.p.: intraperitoneal
  i.v.: intravenous
  IARC: International Agency for Research on Cancer
  ICD-O-2: International Classification of Diseases for Oncology (revision 2)
  ICD: (WHO) International Classification of Diseases (and revision versions)
  IDLH: immediately dangerous to life and health
  kg: kilogram
  L: liter
  LEC: lowest effective concentration
  LED: lowest effective dose
  LH: lymphohematopoietic
  LHC: lymphohematopoietic cancer
  LOD: limit of detection
  LOH: loss of heterozygosity
  M: male
  m^2^: square meter
  m^3^: cubic meter
  MCL: maximum contaminant level
  MDEQ: Mississippi Department of Environmental Quality
  mg: milligram
  mL: milliliter
  MM: multiple myeloma
  MS: mass spectrometry
  N: number
  N.D.: not detected; not determined
  NA: not applicable/not available
  Na-PCP: sodium pentachlorophenate
  NCE: normochromatic erythrocyte
  NDMA: N-nitrosodimethylamine
  ng: nanogram
  NHANES: National Health and Nutrition and Examination Survey
  NHL: non-Hodgkin lymphoma
  NIOSH: National Institute for Occupational Safety and Health (U.S.)
  NLM: National Library of Medicine
  NOES: National Occupational Exposure Survey
  NOS: not otherwise specified
  NPL: National Priorities List
  NR: not reported; none reported
  Nrf2: nuclear factor (erythroid derived-2)-like 2
  ns: not specified
  NS: not significant
  NT: not tested
  OCDD: octachlorodibenzo-p-dioxin
  OR: odds ratio
  OSHA: Occupational Safety and Health Administration
  OTM: olive tail moment
  PCDD: polychlorinated dibenzodioxins
  PCE: polychromatic erythrocyte
  PCNA: proliferating cell nuclear antigen
  PCP: pentachlorophenol and by-products of its synthesis
  PEL: permissible exposure limit
  ppm: parts per million
  ppt: parts per trillion
  R: estimated daily production of adducts
  RAHC: Reasonably anticipated to be a human carcinogen
  REL: recommended exposure limit
  RoC: Report on Carcinogens
  ROS: reactive oxygen species
  RQ: reportable quantity
  RR: relative risk
  SAFE: significance analysis of function and expression
  SCE: sister-chromatid exchange
  SD: standard deviation
  SIR: standardized incidence ratio
  SMR: standardized mortality ratio
  SOCMI: synthetic organic chemical manufacturing industry
  SPA: solid phosphoric acid
  SRR: standardized rate ratio, standardized relative risk
  STS: soft tissue sarcoma
  TCBQ: tetrachlorobenzoquinone
  TCCAT: tetrachlorocatechol
  TCDF: 2,3,7,8-tetrachlorodibenzofuran
  TCHQ: tetrachlorohydroquinone
  TCoBQ: tetrachloro-ortho-benzoquinone
  TCoSQ: tetrachloro-ortho-benzosemiquinone
  TCP: trichlorophenol; 2,4,5-trichlorophenol
  TCPs: tetrachlorophenols
  TCR: tetrachlororesorcinol
  TCSQ: tetrachlorobenzosemiquinone
  TDS: Total Diet Study
  TeCP: tetrachlorophenol
  TEF: toxic equivalency factor
  TEQ: toxic equivalents
  TL: tail length
  TLV-TWA: threshold limit value time-weighted average
  t_max_: time to maximum concentration in plasma
  TRI: Toxics Release Inventory
  TriCBQ: trichlorobenzoquinone
  TriCHQ: trichlorohydroquinone
  TSCA: Toxic Substances and Recovery Act
  TWA: time-weighted average
  UDS: unscheduled DNA synthesis
  UK: United Kingdom
  WHO: World Health Organization
  wt%: weight percent
  yr: year or years
  µg: microgram