# References

Adachi S, Yoshida S, Kawamura K, Takahashi M, Uchida H, Odagiri Y, Takemoto K. 1994. Inductions of oxidative DNA damage and mesothelioma by crocidolite, with special reference to the presence of iron inside and outside of asbestos fiber. Carcinogenesis. 15(4):753–758. 10.1093/carcin/15.4.753 8149491
Agency for Toxic Substances Disease Registry (ATSDR). 1993a. Public health assessment for Koppers Company/Charleston, Charleston County, South Carolina, Region 4. Government Reports Announcements & Index (GRA&I), No. 20. CERCLIS No. SCD980310239.
Agency for Toxic Substances Disease Registry (ATSDR). 1993b. Public health assessment for Munisport Landfill, North Miami, Dade County, Florida, Region 4. Government Reports Announcements & Index (GRA&I), Issue 09. CERCLIS No. FLD084535442.
Agency for Toxic Substances Disease Registry (ATSDR). 1995. Health assessment for American Creosote Works, Incorporated, (Winnfield Plant), Winnfield, Winn Parish, Louisiana, Region 6. Government Reports Announcements & Index (GRA&I), No. 13. CERCLIS No. LAD000239814.
Agency for Toxic Substances Disease Registry (ATSDR). 2001. Toxicological profile for pentachlorophenol. Atlanta, GA: Agency for Toxic Substances and Disease Registry.
Agency for Toxic Substances Disease Registry (ATSDR). 2007. Health consultation. Exposure investigation report, Meredith William C Co., Inc., East Point, Georgia. Atlanta, GA: Agency for Toxic Substances and Disease Registry.
Ahlborg UG, Larsson K, Thunberg T. 1978. Metabolism of pentachlorophenol in vivo and in vitro. Arch Toxicol. 40(1):45–53. 10.1007/BF00353278 580375
Ahlborg UG, Lindgren JE, Mercier M. 1974. Metabolism of pentachlorophenol. Arch Toxicol. 32(4):271–281. 10.1007/BF00330109 4480027
Ahlborg UG, Thunberg T. 1978. Effects of 2,3,7,8-tetrachlorodibenzo-p-dioxin on the in vivo and in vitro dechlorination of pentachlorophenol. Arch Toxicol. 40(1):55–61. 10.1007/BF00353279 580376
Akron. 2010. The chemical database. The Department of Chemistry at the University of Akron. http://ull.chemistry.uakron.edu/erd and search on CAS number. [Accessed: February 4, 2013]
Allen DG, Pearse G, Haseman JK, Maronpot RR. 2004. Prediction of rodent carcinogenesis: An evaluation of prechronic liver lesions as forecasters of liver tumors in NTP carcinogenicity studies. Toxicol Pathol. 32(4):393–401. 10.1080/01926230490440934 15307212
Anonymous. 1999. Public health assessment for Camilla Wood Preserving Company, Camilla, Mitchell County, Georgia, Region 4. Govt Reports Announcements & Index (GRA&I), No. 13. CERCLIS No. GAD008212409. NTIS/PB2000-103266.
Arrhenius E, Renberg L, Johansson L. 1977. Subcellular distribution, a factor in risk evaluation of pentachlorophenol. Chem Biol Interact. 18(1):23–34. 10.1016/0009-2797(77)90138-7 890838
Ateeq B, Abul Farah M, Niamat Ali M, Ahmad W. 2002. Clastogenicity of pentachlorophenol, 2,4-D and butachlor evaluated by Allium root tip test. Mutat Res. 514(1-2):105–113. 10.1016/S1383-5718(01)00327-8 11815249
Aurand K, Englert N, Krause C, Ulrich D, Walter R. 1981. [Pentachlorophenol containing wood preservatives in rooms]. Schr-Reihe Ver WaBoLu. 52:293–313.
Bader M, Zimmer H, Triebig G. 2007. Urinary pentachlorophenol in painters and bricklayers in a four-years time interval after the PCP prohibition ordinance in Germany. Ind Health. 45(2):338–342. 10.2486/indhealth.45.338 17485880
Ballhorn L, Rozman T, Rozman K, Korte F, Greim H. 1981. Cholestyramine enhances fecal elimination of pentachlorophenol in Rhesus monkeys. Chemosphere. 10(8):877–888. 10.1016/0045-6535(81)90087-4
Barbieri F, Colosio C, Schlitt H, Maroni M. 1995. Urine excretion pn pentachlorophenol (PCP) in occupational exposure. Pestic Sci. 43(4):259–262. 10.1002/ps.2780430402
Barouki R, Aggerbeck M, Aggerbeck L, Coumoul X. 2012. The aryl hydrocarbon receptor system. Drug Metabol Drug Interact. 27(1):3–8. 10.1515/dmdi-2011-0035 22718620
Bauchinger M, Dresp J, Schmid E, Hauf R. 1982. Chromosome changes in lymphocytes after occupational exposure to pentachlorophenol (PCP). Mutat Res. 102(1):83–88. 10.1016/0165-1218(82)90148-3 7121476
Berdowski JJM, Baas J, Bloos JPJ, Visschedijk AJH, Zandveld PYJ. 1997. The European emission inventory of heavy metals and persistent organic pollutants for 1990. Apeldoorn, Netherlands: TNO Institute of Environmental Science, Energy Research and Process Innovation. UBA-FB report 104 02 672/03.
Berkowitz GS, Obel J, Deych E, Lapinski R, Godbold J, Liu Z, Landrigan PJ, Wolff MS. 2003. Exposure to indoor pesticides during pregnancy in a multiethnic, urban cohort. Environ Health Perspect. 111(1):79–84. 10.1289/ehp.5619 12515682
Betts JJ, James SP, Thorpe WV. 1955. The metabolism of pentachloronitrobenzene and 2:3:4:6-tetrachloronitrobenzene and the formation of mercapturic acids in the rabbit. Biochem J. 61(4):611–617. 10.1042/bj0610611 13276346
Bevenue A, Wilson J, Casarett LJ, Klemmer HW. 1967. A survey of PCP content in human urine. Bull Environ Contam Toxicol. 2:319–332. 10.1007/BF01684407 24189956
Birmann BM, Giovannucci E, Rosner B, Anderson KC, Colditz GA. 2007. Body mass index, physical activity, and risk of multiple myeloma. Cancer Epidemiol Biomarkers Prev. 16(7):1474–1478. 10.1158/1055-9965.EPI-07-0143 17627013
Boberg EW, Miller EC, Miller JA, Poland A, Liem A. 1983. Strong evidence from studies with brachymorphic mice and pentachlorophenol that 1′-sulfoöxysafrole is the major ultimate electrophilic and carcinogenic metabolite of 1′-hydroxysafrole in mouse liver. Cancer Res. 43(11):5163–5173. 6577945
Bolin CA, Smith ST. 2011. Life cycle assessment of pentachlorophenol-treated wooden utility poles with comparisons to steel and concrete utility poles. Renew Sust Energy Rev. 15(5):2475-2486. 10.1016/j.rser.2011.01.019
Bond GG, McLaren EA, Lipps TE, Cook RR. 1989. Update of mortality among chemical workers with potential exposure to the higher chlorinated dioxins. J Occup Med. 31(2):121–123. 2709162
Borysiewicz M. 2008. Pentachlorophenol. Warsaw, Poland: Institute of Environmental Protection.
Bradman A, Barr DB, Claus Henn BG, Drumheller T, Curry C, Eskenazi B. 2003. Measurement of pesticides and other toxicants in amniotic fluid as a potential biomarker of prenatal exposure: A validation study. Environ Health Perspect. 111(14):1779–1782. 10.1289/ehp.6259 14594631
Braun WH, Blau GE, Chenoweth MB. 1979. The metabolism/pharmacokinetics of PCP in man, and a comparison with the rat and monkey. In: Toxicology and Occupational Medicine. New York, NY: Elsevier. p. 289–296. 10.1016/B978-0-444-00288-4.50033-5
Braun WH, Sauerhoff MW. 1976. The pharmacolinetic profile of pentachlorophenol in monkeys. Toxicol Appl Pharmacol. 38(3):525–533. 10.1016/0041-008X(76)90184-8 827823
Braun WH, Young JD, Blau GE, Gehring PJ. 1977. The pharmacokinetics and metabolism of pentachlorophenol in rats. Toxicol Appl Pharmacol. 41(2):395–406. 10.1016/0041-008X(77)90041-2 898206
Buhler DR, Rasmussen ME, Nakane HS. 1973. Occurrence of hexachlorophene and pentachlorophenol in sewage and water. Environ Sci Technol. 7(10):929–934. 10.1021/es60082a006
Bundesamt für Umweltschutz. 1983. [Polychlorinated organic compounds in Rheinfelden (Switzerland). Investigation of dust, soil, and grass samples: Results and evaluation]. Bern, Switzerland: Bundesamt für Umweltschutz. Schriftenreihe Umweltschutz 18.
Buser HR. 1975. Analysis of polychlorinated dibenzo-p-dioxins and dibenzofurans in chlorinated phenols by mass fragmentography. J Chromatogr. 107(2):295–310. 10.1016/0021-9673(75)80005-7 805791
Cabral JRP, Mollner T, Raitano F, Shubik P. 1979. Carcinogenesis of hexachlorobenzene in mice. Int J Cancer. 23(1):47–51. 10.1002/ijc.2910230110 759379
Cabral JRP, Shubik P, Mollner T, Raitano F. 1977. Carcinogenic activity of hexachlorobenzene in hamsters. Nature. 269(5628):510–511. 10.1038/269510a0 198674
Carreón T, Butler MA, Ruder AM, Waters MA, Davis-King KE, Calvert GM, Schulte PA, Connally B, Ward EM, Sanderson WT, et al. 2005. Gliomas and farm pesticide exposure in women: The Upper Midwest Health Study. Environ Health Perspect. 113(5):546–551. 10.1289/ehp.7456 15866761
Casarett LJ, Bevenue A, Yauger WL Jr, Whalen SA. 1969. Observations on pentachlorophenol in human blood and urine. Am Ind Hyg Assoc J. 30(4):360–366. 10.1080/00028896909343138 5798790
Cautreels W, van Couwenberghe K, Guzman LA. 1977. Comparison between the organic fraction of suspended matter at a background and an urban station. Sci Total Environ. 8(1):79–88. 10.1016/0048-9697(77)90063-8
Centers for Disease Control and Prevention (CDC). 2009. Fourth national report on human exposure to environmental chemicals. Atlanta, GA: Centers for Disease Control and Prevention.
Centers for Disease Control and Prevention (CDC). 2011. National Health and Nutrition Examination Survey, 2003-2004 data documentation, codebook and frequencies. Urinary current use pesticides (formerly priority pesticides, non-persistent pesticide metabolites). Atlanta, GA: Center for Disease Control and Prevention. https://www.cdc.gov/nchs/nhanes/nhanes2003-2004/L26UPP_C.htm. [Accessed: August 15, 2013]
Centers for Disease Control and Prevention (CDC). 2013 a. Fourth national report on human exposure to environmental chemicals. Atlanta, GA: Centers for Disease Control and Prevention.
Centers for Disease Control and Prevention (CDC). 2013b. National Biomonitoring Program, biomonitoring summary: Pentachlorophenol. Atlanta, GA: Centers for Disease Control and Prevention. https://www.cdc.gov/biomonitoring/Pentachlorophenol_BiomonitoringSummary.html. [Accessed: February 7, 2014]
Chang WC, Jeng JH, Shieh CC, Tsai YC, Ho YS, Guo HR, Liu HI, Lee CC, Ho SY, Wang YJ. 2003. Skin tumor-promoting potential and systemic effects of pentachlorophenol and its major metabolite tetrachlorohydroquinone in CD-1 mice. Mol Carcinog. 36(4):161–170. 10.1002/mc.10113 12669308
ChemIDplus. 2013. ChemIDplus advanced. Bethesda, MD: National Library of Medicine. http://chem.sis.nlm.nih.gov/chemidplus/chemidheavy.jsp and select Registry Number and search on CAS number. [Accessed: February 4, 2013]
Chhabra RS, Maronpot RM, Bucher JR, Haseman JK, Toft JD, Hejtmancik MR. 1999. Toxicology and carcinogenesis studies of pentachlorophenol in rats. Toxicol Sci. 48(1):14–20. 10.1093/toxsci/48.1.14 10330679
Chung N, Aust SD. 1995. Veratryl alcohol-mediated indirect oxidation of pentachlorophenol by lignin peroxidase. Arch Biochem Biophys. 322(1):143–148. 10.1006/abbi.1995.1446 7574669
Cline RE, Hill RH Jr, Phillips DL, Needham LL. 1989. Pentachlorophenol measurements in body fluids of people in log homes and workplaces. Arch Environ Contam Toxicol. 18(4):475–481. 10.1007/BF01055012 2774665
Coad S, Newhook RC. 1992. PCP exposure for the Canadian general population: A multimedia analysis. J Expo Anal Environ Epidemiol. 2(4):391–413. 1483028
Cogliano VJ, Baan R, Straif K, Grosse Y, Lauby-Secretan B, El Ghissassi F, Bouvard V, Benbrahim-Tallaa L, Guha N, Freeman C, et al. 2011. Preventable exposures associated with human cancers. J Natl Cancer Inst. 103(24):1827–1839. 10.1093/jnci/djr483 22158127
Cohen SM, Storer RD, Criswell KA, Doerrer NG, Dellarco VL, Pegg DG, Wojcinski ZW, Malarkey DE, Jacobs AC, Klaunig JE, et al. 2009. Hemangiosarcoma in rodents: Mode-of-action evaluation and human relevance. Toxicol Sci. 111(1):4–18. 10.1093/toxsci/kfp131 19525443
Collins JJ. 2013. Occupational studies of workers in pentachlorophenol production. Midland, MI: Dow Chemical Company.
Collins JJ, Bodner K, Aylward LL, Wilken M, Bodnar CM. 2009 a. Mortality rates among trichlorophenol workers with exposure to 2,3,7,8-tetrachlorodibenzo-p-dioxin. Am J Epidemiol. 170(4):501–506. 10.1093/aje/kwp153 19561065
Collins JJ, Bodner K, Aylward LL, Wilken M, Swaen G, Budinsky R, Rowlands C, Bodnar CM. 2009 b. Mortality rates among workers exposed to dioxins in the manufacture of pentachlorophenol. J Occup Environ Med. 51(10):1212–1219. 10.1097/JOM.0b013e3181badd4e 19786897
Collins JJ, Bodner K, Haidar S, Wilken M, Burns CJ, Lamparski LL, Budinsky RA, Martin GD, Carson ML. 2008. Chlorinated dibenzo-p-dioxins, dibenzofurans, and biphenyl profiles of workers with trichlorophenol and pentachlorophenol exposures. Chemosphere. 73(1 Suppl):S284–S289. 10.1016/j.chemosphere.2007.12.034 18442847
Collins JJ, Bodner KM, Wilken M, Haidar S, Burns CJ, Budinsky RA, Martin GD, Carson ML, Rowlands JC. 2007. Serum concentrations of chlorinated dibenzo-p-dioxins and dibenzofurans among former Michigan trichlorophenol and pentachlorophenol workers. J Expo Sci Environ Epidemiol. 17(6):541–548. 10.1038/sj.jes.7500558 17426737
Collins JJ, Budinsky RA, Burns CJ, Lamparski LL, Carson ML, Martin GD, Wilken M. 2006. Serum dioxin levels in former chlorophenol workers. J Expo Sci Environ Epidemiol. 16(1):76–84. 10.1038/sj.jea.7500439 16015278
Cranmer M, Freal J. 1970. Gas chromatographic analysis of pentachlorophenol in human urine by formation of alkyl ethers. Life Sci. 9(3):121–128. 10.1016/0024-3205(70)90304-8 5434354
Cravedi JP, Lafuente A, Baradat M, Hillenweck A, Perdu-Durand E. 1999. Biotransformation of pentachlorophenol, aniline and biphenyl in isolated rainbow trout (Oncorhynchus mykiss) hepatocytes: Comparison with in vivo metabolism. Xenobiotica. 29(5):499–509. 10.1080/004982599238506 10379987
Crosby DG, Beynon KI, Greve PA, Korte F, Still GG, Vonk JW. 1981. IUPAC reports on pesticides 14. Environmental chemistry of pentachlorophenol. Pure Appl Chem. 53(5):1051–1080. 10.1351/pac198153051051
Dahlgren J, Takhar H, Schecter A, Schmidt R, Horsak R, Paepke O, Warshaw R, Lee A, Anderson-Mahoney P. 2007. Residential and biological exposure assessment of chemicals from a wood treatment plant. Chemosphere. 67(9):S279–S285. 10.1016/j.chemosphere.2006.05.109 17234249
Dahlhaus M, Almstadt E, Appel KE. 1994. The pentachlorophenol metabolite tetrachloro-p-hydroquinone induces the formation of 8-hydroxy-2-deoxyguanosine in liver DNA of male B6C3F1 mice. Toxicol Lett. 74(3):265–274. 10.1016/0378-4274(94)90085-X 7871550
Dahlhaus M, Almstadt E, Henschke P, Luttgert S, Appel KE. 1995. Induction of 8-hydroxy-2-deoxyguanosine and single-strand breaks in DNA of V79 cells by tetrachloro-p-hydroquinone. Mutat Res. 329(1):29–36. 10.1016/0027-5107(95)00014-A 7770074
Dahlhaus M, Almstadt E, Henschke P, Lüttgert S, Appel KE. 1996. Oxidative DNA lesions in V79 cells mediated by pentachlorophenol metabolites. Arch Toxicol. 70(7):457–460. 10.1007/s002040050299 8740541
Dai J, Sloat AL, Wright MW, Manderville RA. 2005. Role of phenoxyl radicals in DNA adduction by chlorophenol xenobiotics following peroxidase activation. Chem Res Toxicol. 18(4):771–779. 10.1021/tx0500023 15833038
Dai J, Wright MW, Manderville RA. 2003. An oxygen-bonded C8-deoxyguanosine nucleoside adduct of pentachlorophenol by peroxidase activation: Evidence for ambient C8 reactivity by phenoxyl radicals. Chem Res Toxicol. 16(7):817–821. 10.1021/tx034084b 12870883
Daimon H, Sawada S, Asakura S, Sagami F. 1997. Inhibition of sulfotransferase affecting in vivo genotoxicity and DNA adducts induced by safrole in rat liver. Teratog Carcinog Mutagen. 17(6):327–337. 10.1002/(SICI)1520-6866(1997)17:6<327::AID-TCM3>3.0.CO;2-J 9485541
Daniel V, Huber W, Bauer K, Opelz G. 1995. Impaired in-vitro lymphocyte responses in patients with elevated pentachlorophenol (PCP) blood levels. Arch Environ Health. 50(4):287–292. 10.1080/00039896.1995.9935956 7677428
Daniel V, Huber W, Bauer K, Suesal C, Conradt C, Opelz G. 2001 a. Associations of blood levels of PCB, HCHS, and HCB with numbers of lymphocyte subpopulations, in vitro lymphocyte response, plasma cytokine levels, and immunoglobulin autoantibodies. Environ Health Perspect. 109(2):173–178. 10.1289/ehp.01109173 11266329
Daniel V, Huber W, Bauer K, Suesal C, Mytilineos J, Melk A, Conradt C, Opelz G. 2001 b. Association of elevated blood levels of pentachlorophenol (PCP) with cellular and humoral immunodeficiencies. Arch Environ Health. 56(1):77–83. 10.1080/00039890109604057 11256860
Deichmann WB, Machle W, Kitzmiller KV, Thomas G. 1942. Acute and chronic effects of pentachlorophenol and sodium pentachlorophenate upon experimental animals. J Pharmacol Exp Ther. 76(2):104–117.
Delclos KB, Miller EC, Miller JA, Liem A. 1986. Sulfuric acid esters as major ultimate electrophilic and hepatocarcinogenic metabolites of 4-aminoazobenzene and its N-methyl derivatives in infant male C57BL/6J x C3H/HeJ F1 (B6C3F1) mice. Carcinogenesis. 7(2):277–287. 10.1093/carcin/7.2.277 2419005
DeMarini DM, Brooks HG, Parkes DG Jr. 1990. Induction of prophage lambda by chlorophenols. Environ Mol Mutagen. 15(1):1–9. 10.1002/em.2850150102 2137084
Demers PA. 2013. Epidemiologic studies of pentachlorophenol users. Toronto, Canada: Occupational Cancer Research Centre.
Demers PA, Davies HW, Friesen MC, Hertzman C, Ostry A, Hershler R, Teschke K. 2006. Cancer and occupational exposure to pentachlorophenol and tetrachlorophenol (Canada). Cancer Causes Control. 17(6):749–758. 10.1007/s10552-006-0007-9 16783603
Detrick RS. 1977. Pentachlorophenol, possible sources of human exposure. Forest Proc J. 27(6):13-16.
Dietz F, Traud J. 1978. [On the analysis of phenols, particularly chlorophenols, in water by means of gas chromatography - methods and results]. Vom Wasser. 51:235–257.
Dobbs AJ, Williams N. 1983. Indoor air pollution from pesticides used in wood remedial treatments. Environ Pollut. 6(4):271–296. 10.1016/0143-148X(83)90014-9
Donnelly KC, Claxton LD, Huebner HJ, Capizzi JL. 1998. Mutagenic interactions of model chemical mixtures. Chemosphere. 37(7):1253–1261. 10.1016/S0045-6535(98)00123-4 9734320
Dorsey WC, Tchounwou PB. 2004. Pentachlorophenol-induced cytotoxic, mitogenic, and endocrine-disrupting activities in channel catfish, Ictalurus punctatus. Int J Environ Res Public Health. 1(2):90–99. 10.3390/ijerph2004020090 16696183
Dorsey WC, Tchounwou PB, Ford BD. 2006. Neuregulin 1-beta cytoprotective role in AML 12 mouse hepatocytes exposed to pentachlorophenol. Int J Environ Res Public Health. 3(1):11–22. 10.3390/ijerph2006030002 16823072
Dorsey WC, Tchounwou PB, Ishaque AB, Shen E. 2002. Transcriptional activation of stress genes and cytotoxicity in human liver carcinoma (HepG2) cells exposed to pentachlorophenol. Int J Mol Sci. 3(9):992–1007. 10.3390/i3090992
Dorsey WC, Tchounwou PB, Sutton D. 2004. Mitogenic and cytotoxic effects of pentachlorophenol to AML 12 mouse hepatocytes. Int J Environ Res Public Health. 1(2):100–105. 10.3390/ijerph2004020100 16696184
Dougherty RC, Piotrowska K. 1976. Screening by negative chemical ionization mass spectrometry for environmental contamination with toxic residues: Application to human urines. Proc Natl Acad Sci USA. 73(6):1777–1781. 10.1073/pnas.73.6.1777 1064850
Dubois M, Grosse Y, Thomé JP, Kremers P, Pfohl-Leszkowicz A. 1997. Metabolic activation and DNA adducts detection as biomarkers of chlorinated pesticide exposures. Biomarkers. 2(1):17–24. 10.1080/135475097231922 23899150
Dubois M, Plaisance H, Thomé JP, Kremers P. 1996. Hierarchical cluster analysis of environmental pollutants through P450 induction in cultured hepatic cells. Ecotoxicol Environ Saf. 34(3):205–215. 10.1006/eesa.1996.0065 8812189
Duchak SA, Malanichev V, Shatalov V, Vulykh N. 2002. Application of EMEP transport models to assessment of long-range transport potential and overall persistence. OECD Environment, Health and Safety Publications Series on Testing and Assessment No. 36. Report of the OECD/UNEP Workshop on the Use of Multimedia Models for Estimating Overall Environmental Persistence and Long Range Transport in the Context of PBTS/POPS Assessment. ENV/JM/MONO(2002)15.
Duggan RE, Corneliussen PE. 1972. Dietary intake of pesticide chemicals in the United States. 3. June 1968—April 1970. Pestic Monit J. 5(4):331–341. 4133965
Dunn KL. 2013. Overview of occupational exposures to pentachlorophenol. Cincinnati, OH: National Institute for Occupational Safety and Health.
Eastin WC, Haseman JK, Mahler JF, Bucher JR. 1998. The National Toxicology Program evaluation of genetically altered mice as predictive models for identifying carcinogens. Toxicol Pathol. 26(4):461–473. 10.1177/019262339802600401 9715504
Edgerton TR, Moseman RF, Linder RE, Wright LH. 1979. Multi-residue method for the determination of chlorinated phenol metabolites in urine. J Chromatogr. 170(2):331–342. 10.1016/S0021-9673(00)95458-X 546845
Ehrlich W. 1990. The effect of pentachlorophenol and its metabolite tetrachlorohydroquinone on cell growth and the induction of DNA damage in Chinese hamster ovary cells. Mutat Res. 244(4):299–302. 10.1016/0165-7992(90)90076-V 2385245
Eling TE, Thompson DC, Foureman GL, Curtis JF, Hughes MF. 1990. Prostaglandin H synthase and xenobiotic oxidation. Annu Rev Pharmacol Toxicol. 30:1–45. 10.1146/annurev.pa.30.040190.000245 2111654
Emond C, Birnbaum LS, DeVito MJ. 2006. Use of a physiologically based pharmacokinetic model for rats to study the influence of body fat mass and induction of CYP1A2 on the pharmacokinetics of TCDD. Environ Health Perspect. 114(9):1394–1400. 10.1289/ehp.8805 16966094
Engst R, Macholz RM, Kujawa M, Lewerenz HJ, Plass R. 1976. The metabolism of lindance and its metabolites gamma-2,3,4,5,6-pentachlorocyclohexene, pentachlorobenzene, and pentachlorophenol in rats and the pathways of lindance metabolism. J Environ Sci Health B. 11(2):95–117. 10.1080/03601237609372028 57975
Environment Canada. 1979. Monitoring environmental contamination from chlorophenol contaminated wastes generated in the wood preservation industry. Ottawa, Canada: Environmental Protection Bureau, Environmental Protection Service, Pacific and Yukon Region. Regional Program Report No. 79-24, Prepared by Can Test Ltd and EVS Consultants Ltd, DSS File No. 075B, KE 114-8-1935.
Environment Canada. 1990. Detroit Incerinator Monitoring Program. Data report #4. Windsor air sampling site, September 1988-October 1989. WaljXlle Island air sampling site, August 1988-October 1989. Ottawa, Canada: Conservation and Protection, Environment Canada. PMD 90-8.
Eriksson M, Hardell L, Adami HO. 1990. Exposure to dioxins as a risk factor for soft tissue sarcoma: A population-based case-control study. J Natl Cancer Inst. 82(6):486–490. 10.1093/jnci/82.6.486 2313720
Eriksson M, Hardell L, Berg NO, Moller T, Axelson O. 1981. Soft-tissue sarcomas and exposure to chemical substances: A case-referent study. Br J Ind Med. 38(1):27–33. 10.1136/oem.38.1.27 7470401
Ernst W, Weber K. 1978. [The fate of pentachlorophenol in the Weser estuary and the German Bight]. Veröff Inst Meeresforsch Bremerh. 17:45–53.
Estreicher H. 2013. H. Estreicher, Keller and Heckman LLP, Washington, D.C. letter to R. Lunn, National Toxicology Program, Research Triangle Park, N.C., August 15, 2013.
Fahrig R. 1974. Comparative mutagenicity studies with pesticides. IARC Sci Publ. (10):161–181.
Fahrig R, Nilsson CA, Rappe C. 1978. Genetic activity of chlorophenols and chlorophenol impurities. In: Rao KR, editor. Pentachlorophenol: Chemistry, Pharmacology and Environmental Toxicology. New York, NY: Plenum Press. p. 325–338. 10.1007/978-1-4615-8948-8_28
Feng L, Wu C, Tam L, Sutherland AJ, Clark JJ, Rosenfeld PE. 2011. Dioxin furan blood lipid and attic dust concentrations in populations living near four wood treatment facilities in the United States. J Environ Health. 73(6):34–46. 21306093
Fenske RA, Horstman SW, Bentley RK. 1987. Assessment of dermal exposure to chlorophenols in timber mills. Appl Ind Hyg. 2(4):143-147. 10.1080/08828032.1987.10390541
Filipovich AH, Spector BD, Kersey J. 1980. Immunodeficiency in humans as a risk factor in the development of malignancy. Prev Med. 9(2):252–259. 10.1016/0091-7435(80)90083-3 7383991
Fingerhut MA, Sweeney MH, Halperin WE, Schnorr TM. 1991. The epidemiology of populations exposed to dioxin. IARC Sci Publ. (108):31–50. 1817104
Fischer A, Slemrova J. 1978. [The contamination of the river Rhine with chlorophenols.]. Vom Wasser. 51:33–46.
Fountaine JE, Joshipura PB, Keliher PN. 1976. Some observations regarding pentachlorophenol levels in Haverford Township, Pennsylvania. Water Res. 10(3):185–188. 10.1016/0043-1354(76)90125-1
French J, Storer RD, Donehower LA. 2001. The nature of the heterozygous Trp53 knockout model for identification of mutagenic carcinogens. Toxicol Pathol. 29 Suppl:24–29. 10.1080/019262301753178456 11695559
Fries GF, Feil VJ, Zaylskie RG, Bialek KM, Rice CP. 2002. Treated wood in livestock facilities: Relationships among residues of pentachlorophenol, dioxins, and furans in wood and beef. Environ Pollut. 116(2):301–307. 10.1016/S0269-7491(01)00122-1 11806459
Fries GF, Paustenbach DJ, Mather DB, Luksemburg WJ. 1999. A congener specific evaluation of transfer of chlorinated dibenzo-p-dioxins and dibenzofurans to milk of cows following ingestion of pentachlorophenol-treated wood. Environ Sci Technol. 33(8):1165–1170. 10.1021/es981153d
Friesen MC, Davies HW, Teschke K, Ostry AS, Hertzman C, Demers PA. 2007. Impact of the specificity of the exposure metric on exposure-response relationships. Epidemiology. 18(1):88–94. 10.1097/01.ede.0000249558.18960.6b 17130686
Fuhrman J, Shafer L, Repertinger S, Chan T, Hansen LA. 2005. Mechanisms of SEPA 0009-induced tumorigenesis in v-rasHa transgenic Tg.AC mice. Toxicol Pathol. 33(6):623–630. 10.1080/01926230500278975 16176921
Galloway SM, Armstrong MJ, Reuben C, Colman S, Brown B, Cannon C, Bloom AD, Nakamura F, Ahmed M, Duk S, et al. 1987. Chromosome aberrations and sister chromatid exchanges in Chinese hamster ovary cells: Evaluations of 108 chemicals. Environ Mol Mutagen. 10 Suppl 10:1–175. 10.1002/em.2850100502 3319609
Garrett CL. 1980. Fraser River Estuary Study. Water quality series. Toxic organic contaminants. Ottawa, Canada: Environmental Protection Service, Pacific and Yukon Region, Environment Canada.
Gebefügi I. 1981. [Our present knowledge of the occurrence of pentachlorophenol in the environment]. In: Report on the 1980 Symposium of the Institute for Ecological Chemistry. Münich, Germany: Society for Radiation and Environmental Research (GSF). p. 25-33.
Gebefügi I, Oxynos K, Korte F. 1983. [Long-term behaviour of pentachlorophenol in closed rooms]. Chemosphere. 12(1):59–63. 10.1016/0045-6535(83)90180-7
Gebefügi I, Parlar H, Korte F. 1979. Occurrence of pentachlorophenol in closed environments. Ecotoxicol Environ Saf. 3(3):269–300. 10.1016/0147-6513(79)90017-4 499031
Gerhard I, Frick A, Monga B, Runnebaum B. 1999. Pentachlorophenol exposure in women with gynecological and endocrine dysfunction. Environ Res. 80(4):383–388. 10.1006/enrs.1998.3934 10330312
Geyer HJ, Scheunert I, Korte F. 1987. Distribution and bioconcentration potential of the environmental chemical pentachlorophenol (PCP) in different tissues of humans. Chemosphere. 16(4):887–899. 10.1016/0045-6535(87)90022-1
Goldstein JA, Friesen M, Linder RE, Hickman P, Hass JR, Bergman H. 1977. Effects of pentachlorophenol on hepatic drug-metabolizing enzymes and porphyria related to contamination with chlorinated dibenzo-p-dioxins and dibenzofurans. Biochem Pharmacol. 26(17):1549–1557. 10.1016/0006-2952(77)90068-5 901575
Gómez-Catalán J, To-Figueras J, Planas J, Rodamilans M, Corbella J. 1987. Pentachlorophenol and hexachlorobenzene in serum and urine of the population of Barcelona. Hum Toxicol. 6(5):397–400. 10.1177/096032718700600509 3679248
Gómez-Catalán J, To-Figueras J, Rodamilans M, Corbella J. 1991. Transport of organochlorine residues in the rat and human blood. Arch Environ Contam Toxicol. 20(1):61–66. 10.1007/BF01065329 1996912
Goodman G. 2001. Chapter 65: Pentachlorophenol. In: Krieger RI, Krieger WC, editors. Handbook of Pesticide Toxicology. Vol. 2. 2nd ed. San Diego, CA: Academic Press. p. 1481–1509. 10.1016/B978-012426260-7.50068-9
Gopalaswamy UV, Nair CK. 1992. DNA binding and mutagenicity of lindane and its metabolites. Bull Environ Contam Toxicol. 49(2):300–305. 10.1007/BF00191771 1377069
Gray RE, Gilliland RD, Smith EE, Lockard VG, Hume AS. 1985. Pentachlorophenol intoxication: Report of a fatal case, with comments on the clinical course and pathologic anatomy. Arch Environ Health. 40(3):161–164. 10.1080/00039896.1985.10545910 4026386
Grimm HG, Schellman B, Schaller KH, et al. 1981. [Pentachlorophenol concentrations in tissues and bodyfluids of normal persons]. Zentralbl Bakteriol Mikrobiol Hyg B. 174:77–90. 7324621
Gunderson EL. 1988. FDA Total Diet Study, April 1982-April 1984, dietary intakes of pesticides, selected elements, and other chemicals. J Assoc Off Anal Chem. 71(6):1200–1209. 10.1093/jaoac/71.6.1200 3240978
Gunter BJ, Thoburn TW. 1980. Health hazard evaluation report: Flathead Post and Pole Yard, Dixon, Montana, December 1980. Cincinnati, OH: National Institutes of Occupational Safety and Health. HHE 80-207-786.
Guvenius DM, Aronsson A, Ekman-Ordeberg G, Bergman A, Norén K. 2003. Human prenatal and postnatal exposure to polybrominated diphenyl ethers, polychlorinated biphenyls, polychlorobiphenylols, and pentachlorophenol. Environ Health Perspect. 111(9):1235–1241. 10.1289/ehp.5946 12842779
Guyton KZ, Kyle AD, Aubrecht J, Cogliano VJ, Eastmond DA, Jackson M, Keshava N, Sandy MS, Sonawane B, Zhang L, et al. 2009. Improving prediction of chemical carcinogenicity by considering multiple mechanisms and applying toxicogenomic approaches. Mutat Res. 681(2-3):230–240. 10.1016/j.mrrev.2008.10.001 19010444
Hardell L. 1979. Malignant lymphoma of histiocytic type and exposure to phenoxyacetic acids or chlorophenols. Lancet. 313(8106):55–56. 10.1016/S0140-6736(79)90509-9 83511
Hardell L. 1981. Relation of soft-tissue sarcoma, malignant lymphoma and colon cancer to phenoxy acids, chlorophenols and other agents. Scand J Work Environ Health. 7(2):119–130. 10.5271/sjweh.2557 7313616
Hardell L. 2008. Pesticides, soft-tissue sarcoma and non-Hodgkin lymphoma—historical aspects on the precautionary principle in cancer prevention. Acta Oncol. 47(3):347–354. 10.1080/02841860701753697 18347998
Hardell L, Axelson O. 1998. Environmental and occupational aspects on the etiology of non-Hodgkin’s lymphoma. Oncol Res. 10(1):1–5. 9613451
Hardell L, Eriksson M. 1988. The association between soft tissue sarcomas and exposure to phenoxyacetic acids. A new case-referent study. Cancer. 62(3):652–656. 10.1002/1097-0142(19880801)62:3<652::AID-CNCR2820620334>3.0.CO;2-4 3390800
Hardell L, Eriksson M. 1999. A case-control study of non-Hodgkin lymphoma and exposure to pesticides. Cancer. 85(6):1353–1360. 10.1002/(SICI)1097-0142(19990315)85:6<1353::AID-CNCR19>3.0.CO;2-1 10189142
Hardell L, Eriksson M, Degerman A. 1994. Exposure to phenoxyacetic acids, chlorophenols, or organic solvents in relation to histopathology, stage, and anatomical localization of non-Hodgkin’s lymphoma. Cancer Res. 54(9):2386–2389. 8162585
Hardell L, Eriksson M, Degerman A. 1995. Metaanalysis of 4 Swedish case-control studies on exposure to pesticides as risk-factor for soft-tissue sarcoma including the relation to tumor-localization and histopathological type. Int J Oncol. 6(4):847–851. 10.3892/ijo.6.4.847 21556610
Hardell L, Eriksson M, Lenner P, Lundgren E. 1981. Malignant lymphoma and exposure to chemicals, especially organic solvents, chlorophenols and phenoxy acids: A case-control study. Br J Cancer. 43(2):169–176. 10.1038/bjc.1981.25 7470379
Hardell L, Eriksson M, Nordström M. 2002. Exposure to pesticides as risk factor for non-Hodgkin’s lymphoma and hairy cell leukemia: Pooled analysis of two Swedish case-control studies. Leuk Lymphoma. 43(5):1043–1049. 10.1080/10428190290021560 12148884
Hardell L, Lindström G, van Bavel B, Fredrikson M, Liljegren G. 1998. Some aspects of the etiology of non-Hodgkin’s lymphoma. Environ Health Perspect. 106 Suppl 2:679–681. 9599716
Hardell L, Sandstrom A. 1979. Case-control study: Soft-tissue sarcomas and exposure to phenoxyacetic acids or chlorophenols. Br J Cancer. 39(6):711–717. 10.1038/bjc.1979.125 444410
Hattemer-Frey HA, Travis CC. 1989. Pentachlorophenol: Environmental partitioning and human exposure. Arch Environ Contam Toxicol. 18(4):482–489. 10.1007/BF01055013 2673066
Hattula ML, Knuutinen J. 1985. Mutagenesis of mammalian cells in culture by chlorophenols, chlorocatechols and chloroguaiacols. Chemosphere. 14(10):1617–1625. 10.1016/0045-6535(85)90015-3
Haworth S, Lawlor T, Mortelmans K, Speck W, Zeiger E. 1983. Salmonella mutagenicity test results for 250 chemicals. Environ Mutagen. 5 Suppl 1:1–142. 10.1002/em.2860050703 6365529
Heacock H, Hertzman C, Demers PA, Gallagher R, Hogg RS, Teschke K, Hershler R, Bajdik CD, Dimich-Ward H, Marion SA, et al. 2000. Childhood cancer in the offspring of male sawmill workers occupationally exposed to chlorophenate fungicides. Environ Health Perspect. 108(6):499–503. 10.1289/ehp.00108499 10856022
Helleday T, Tuominen KL, Bergman A, Jenssen D. 1999. Brominated flame retardants induce intragenic recombination in mammalian cells. Mutat Res. 439(2):137–147. 10.1016/S1383-5718(98)00186-7 10023042
Hensley AR, Scott A, Rosenfeld PE, Clark JJ. 2007. Attic dust and human blood samples collected near a former wood treatment facility. Environ Res. 105(2):194–199. 10.1016/j.envres.2007.03.011 17517389
Hernandez C, Strassman S. 1980. Pentachlorophenol in log homes - Kentucky. MMWR Morb Mortal Wkly Rep. 29(36):431–437.
Hertzman C, Teschke K, Dimich-Ward H, Ostry A. 1988. Validity and reliability of a method for retrospective evaluation of chlorophenate exposure in the lumber industry. Am J Ind Med. 14(6):703–713. 10.1002/ajim.4700140609 3232688
Hertzman C, Teschke K, Ostry A, Hershler R, Dimich-Ward H, Kelly S, Spinelli JJ, Gallagher RP, McBride M, Marion SA. 1997. Mortality and cancer incidence among sawmill workers exposed to chlorophenate wood preservatives. Am J Public Health. 87(1):71–79. 10.2105/AJPH.87.1.71 9065230
Hill AB. 1965. The environment and disease: Association or causation? Proc R Soc Med. 58(5):295–300. 10.1177/003591576505800503 14283879
Hill RH Jr, Head SL, Baker S, Gregg M, Shealy DB, Bailey SL, Williams CC, Sampson EJ, Needham LL. 1995. Pesticide residues in urine of adults living in the United States: Reference range concentrations. Environ Res. 71(2):99–108. 10.1006/enrs.1995.1071 8977618
Hill RH Jr, To T, Holler JS, Fast DM, Smith SJ, Needham LL, Binder S. 1989. Residues of chlorinated phenols and phenoxy acid herbicides in the urine of Arkansas children. Arch Environ Contam Toxicol. 18(4):469–474. 10.1007/BF01055011 2774664
Hoben HJ, Ching SA, Casarett LJ. 1976 a. A study of inhalation of pentachlorophenol by rats III. Inhalation toxicity study. Bull Environ Contam Toxicol. 15(4):463–465. 10.1007/BF01685073 1260154
Hoben HJ, Ching SA, Casarett LJ. 1976 b. A study of inhalation of pentachlorophenol by rats IV. Distribution and excretion of inhaled pentachlorophenol. Bull Environ Contam Toxicol. 15(4):466–474. 10.1007/BF01685074 1260155
Hogberg HT, Kinsner-Ovaskainen A, Hartung T, Coecke S, Bal-Price AK. 2009. Gene expression as a sensitive endpoint to evaluate cell differentiation and maturation of the developing central nervous system in primary cultures of rat cerebellar granule cells (CGCs) exposed to pesticides. Toxicol Appl Pharmacol. 235(3):268–286. 10.1016/j.taap.2008.12.014 19146868
Holsapple MP, McNerney PJ, McCay JA. 1987. Effects of pentachlorophenol on the in vitro and in vivo antibody response. J Toxicol Environ Health. 20(3):229–239. 10.1080/15287398709530977 3820337
Horstman SW, Rossner A, Kalman DA, Morgan MS. 1989. Penetration of pentachlorophenol and tetrachlorophenol through human skin. J Environ Sci Health A Environ Sci Eng. 24(3):229-242. 10.1080/10934528909375477
Hosenfeld JM. 1986. Pentachlorophenol in log homes: A study of environmental and clinical aspects. Washington, DC: U.S. Environmental Protection Agency. EPA-560/5-87-001A.
Hurd T, Walker J, Whalen MM. 2012. Pentachlorophenol decreases tumor-cell-binding capacity and cell-surface protein expression of human natural killer cells. J Appl Toxicol. 32(8):627–634. 10.1002/jat.1781 22912977
Huwe JK, Davison K, Feil VJ, Larsen G, Lorentzsen M, Zaylskie R, Tiernan TO. 2004. Levels of polychlorinated dibenzo-p-dioxins and dibenzofurans in cattle raised at agricultural research facilities across the USA and the influence of pentachlorophenol-treated wood. Food Addit Contam. 21(2):182–194. 10.1080/02652030310001639503 14754641
Innes JR, Ulland BM, Valerio MG, Petrucelli L, Fishbein L, Hart ER, Pallotta AJ, Bates RR, Falk HL, Gart JJ, et al. 1969. Bioassay of pesticides and industrial chemicals for tumorigenicity in mice: A preliminary note. J Natl Cancer Inst. 42(6):1101–1114. 5793189
International Agency for Research on Cancer (IARC). 1991. Pentachlorophenol. In: Occupational Exposures in Insecticide Application, and Some Pesticides. IARC Monographs on the Evaluation of Carcinogenic Risks to Humans. Vol. 53. Lyon, France: International Agency for Research on Cancer. p. 371–402.
International Agency for Research on Cancer (IARC). 1997. Polychlorinated dibenzo-para-dioxins and polychlorinated dibenzofurans. IARC Monographs on the Evaluation of Carcinogenic Risks to Humans. Vol. 69. Lyon, France: International Agency for Research on Cancer.
International Agency for Research on Cancer (IARC). 1999. Polychloropenols and their sodium salts. In: Re-evaluation of Some Organic Chemicals, Hydrazine and Hydrogen Peroxide. IARC Monographs on the Evaluation of Carcinogenic Risks to Humans. Vol. 71. Lyon, France: International Agency for Research on Cancer. p. 769–816.
International Agency for Research on Cancer (IARC). 2012. 2,3,7,8-Tetrachlorodibenzo-para-dioxin, 2,3,4,7,8-pentachlorodibenzofuran, and 3,3′, 4,4′,5-pentachlorobiphenyl. In: A Review of Human Carcinogens, Part F: Chemical Agents and Related Occupations. IARC Monographs on the Evaluation of Carcinogenic Risks to Humans. Vol. 100F. Lyon, France: International Agency for Research on Cancer. p. 339–378.
Ishidate M. 1988. Data book of chromosomal aberration test in vitro. Revised ed. Amsterdam, Netherlands: Elsevier.
Jakobson I, Yllner S. 1971. Metabolism of 14C-pentachlorophenol in the mouse. Acta Pharmacol Toxicol (Copenh). 29(5-6):513–524. 10.1111/j.1600-0773.1971.tb00625.x 4940582
Jansson K, Jansson V. 1986. Inability of chlorophenols to induce 6-thioguanine-resistant mutants in V79 Chinese hamster cells. Mutat Res. 171(2-3):165–168. 10.1016/0165-1218(86)90050-9 3748065
Jansson K, Jansson V. 1991. Induction of mutation in V79 Chinese hamster cells by tetrachlorohydroquinone, a metabolite of pentachlorophenol. Mutat Res. 260(1):83–87. 10.1016/0165-1218(91)90083-X 2027344
Jansson K, Jansson V. 1992. Induction of micronuclei in V79 Chinese hamster cells by tetrachlorohydroquinone, a metabolite of pentachlorophenol. Mutat Res. 279(3):205–208. 10.1016/0165-1218(92)90068-B 1377336
Johnson RD, Manske DD. 1977. Pesticides in food and feed. Pesticide and other chemical residues in total diet samples (XI). Pestic Monit J. 11(3):116–131. 609510
Jones PA. 1981. Chlorophenols and their impurities in the Canadian environment. Ottawa, Canada: Environmental Protection Service, Environment Canada. Economic and Technical Review Report, EPS 3-EC-81-2.
Jones RD, Winter DP, Cooper AJ. 1986. Absorption study of pentachlorophenol in persons working with wood preservatives. Hum Toxicol. 5(3):189–194. 10.1177/096032718600500307 2872154
Juhl U, Witte I, Butte W. 1985. Metabolism of pentachlorophenol to tetrachlorohydroquinone by human liver homogenate. Bull Environ Contam Toxicol. 35(5):596–601. 10.1007/BF01636560 4074922
Kalman DA. 1984. Determination of pentachlorophenol and 2,3,4,6-tetrachlorophenol in human urine by high resolution gas chromatography. J Chromatogr Sci. 22(10):452–455. 10.1093/chromsci/22.10.452 6501528
Kalman DA, Horstman SW. 1983. Persistence of tetrachlorophenol and pentachlorophenol in exposed woodworkers. J Toxicol Clin Toxicol. 20(4):343–352. 10.3109/15563658308990601 6655774
Karouna-Renier NK, Rao KR, Lanza JJ, Davis DA, Wilson PA. 2007. Serum profiles of PCDDs and PCDFs, in individuals near the Escambia Wood Treating Company superfund site in Pensacola, FL. Chemosphere. 69(8):1312–1319. 10.1016/j.chemosphere.2007.05.028 17614120
Kauppinen T, Lindroos L. 1985. Chlorophenol exposure in sawmills. Am Ind Hyg Assoc J. 46(1):34–38. 10.1080/15298668591394347 4025149
Kazunga C, Aitken MD, Gold A. 1999. Primary product of the horseradish peroxidase-catalyzed oxidation of pentachlorophenol. Environ Sci Technol. 33(9):1408–1412. 10.1021/es981126n
Kerkvliet NI, Baecher-Steppan L, Claycomb AT, Craig AM, Sheggeby GG. 1982 a. Immunotoxicity of technical pentachlorophenol (PCP-T): Depressed humoral immune responses to T-dependent and T-independent antigen stimulation in PCP-T exposed mice. Fundam Appl Toxicol. 2(2):90–99. 10.1016/S0272-0590(82)80121-8 6764429
Kerkvliet NI, Baecher-Steppan L, Schmitz JA. 1982 b. Immunotoxicity of pentachlorophenol (PCP): Increased susceptibility to tumor growth in adult mice fed technical PCP-contaminated diets. Toxicol Appl Pharmacol. 62(1):55–64. 10.1016/0041-008X(82)90101-6 6278678
Kerkvliet NI, Brauner JA. 1987. Mechanisms of 1,2,3,4,6,7,8-heptachlorodibenzo-p-dioxin (HpCDD)-induced humoral immune suppression: Evidence of primary defect in T-cell regulation. Toxicol Appl Pharmacol. 87(1):18–31. 10.1016/0041-008X(87)90080-9 3492063
Kerkvliet NI, Brauner JA, Baecher-Steppan L. 1985 a. Effects of dietary technical pentachlorophenol exposure on T cell, macrophage and natural killer cell activity in C57Bl/6 mice. Int J Immunopharmacol. 7(2):239–247. 10.1016/0192-0561(85)90032-3 3159692
Kerkvliet NI, Brauner JA, Matlock JP. 1985 b. Humoral immunotoxicity of polychlorinated diphenyl ethers, phenoxyphenols, dioxins and furans present as contaminants of technical grade pentachlorophenol. Toxicology. 36(4):307–324. 10.1016/0300-483X(85)90033-2 4049436
Kimbrough RD, Linder RE. 1978. The effect of technical and purified pentachlorophenol on the rat liver. Toxicol Appl Pharmacol. 46(1):151–162. 10.1016/0041-008X(78)90146-1 725940
Klemmer HW, Wong L, Sato MM, Reichert EL, Korsak RJ, Rashad MN. 1980. Clinical findings in workers exposed to pentachlorophenol. Arch Environ Contam Toxicol. 9(6):715–725. 10.1007/BF01055546 7469482
KMG Chemicals. 2011. Annual report pursuant to Section 13 or 15(d) of the Securities Exchange Act of 1934 for the fiscal year ended July 31, 2011. KMG Chemicals, Inc. Washington, DC: United Securities and Exchange Commission.
Kociba RJ, Keyes DG, Beyer JE, Carreon RM, Wade CE, Dittenber DA, Kalnins RP, Frauson LE, Park CN, Barnard SD, et al. 1978. Results of a two-year chronic toxicity and oncogenicity study of 2,3,7,8-tetrachlorodibenzo-p-dioxin in rats. Toxicol Appl Pharmacol. 46(2):279–303. 10.1016/0041-008X(78)90075-3 734660
Kogevinas M, Kauppinen T, Winkelmann R, Becher H, Bertazzi PA, Bueno-de-Mesquita HB, Coggon D, Green L, Johnson E, Littorin M, et al. 1995. Soft tissue sarcoma and non-Hodgkin’s lymphoma in workers exposed to phenoxy herbicides, chlorophenols, and dioxins: Two nested case-control studies. Epidemiology. 6(4):396–402. 10.1097/00001648-199507000-00012 7548348
Kogevinas M, Saracci R, Bertazzi PA, Bueno-de-Mesquita HB, Coggon D, Green LM, Kauppinen T, Littorin M, Lynge E, Mathews JD, et al. 1992. Cancer mortality from soft tissue sarcoma and malignant lymphomas in an international cohort of workers exposed to chlorophenoxy herbicides and chlorophenols. Chemosphere. 25(7-10):1071–1076. 10.1016/0045-6535(92)90109-5
Krause C. 1982. [Active ingredients of wood preservatives used in homes]. In: Aurand K, Seifert B, Wegner J, editors. Air Quality in Interiors. Stuttgart, Germany: Gustav-Fischer-Verlag. p. 309–316.
Krause C, Chutsch M, Englert N. 1989. Pentachlorophenol exposure through indoor use of wood preservatives in the Federal Republic of Germany. Environ Int. 15(1-6):443–447. 10.1016/0160-4120(89)90060-3
Krause C, Englert N. 1980. [Health evaluation of PCP (pentachlorophenol) containing wood preservatives in rooms]. Holz Roh- Werkst. 38:429–432. 10.1007/BF02610441
Kutz FW, Cook BT, Carter-Pokras OD, Brody D, Murphy RS. 1992. Selected pesticide residues and metabolites in urine from a survey of the U.S. general population. J Toxicol Environ Health. 37(2):277–291. 10.1080/15287399209531670 1404486
Lang D, Mueller-Ruchholtz W. 1991. Human lymphocyte reactivity after in vitro exposure to technical and analytical grade pentachlorophenol. Toxicology. 70(3):271–282. 10.1016/0300-483X(91)90002-I 1771635
Larsen RV, Kirsch LE, Shaw SM, Christian JE, Born GS. 1972. Excretion and tissue distribution of uniformly labeled 14 C-pentachlorophenol in rats. J Pharm Sci. 61(12):2004–2006. 10.1002/jps.2600611229 4638118
Lee SA, Gunter BJ. 1986. Health hazard evaluation report: Montana log home residents, Kalispell, Montana. Cincinnati, OH: National Institute for Occupational Safety and Health. HETA 84-043. HETA 84-425-1680.
Lee SA, Lucas C. 1983. Health hazard evaluation report: Fort Stanwix National Monument, Rome, New York. Cincinnati, OH: National Institute for Occupational Safety and Health. HETA 83-090-1326.
Lewis RG, Fortmann RC, Camann DE. 1994. Evaluation of methods for monitoring the potential exposure of small children to pesticides in the residential environment. Arch Environ Contam Toxicol. 26(1):37–46. 10.1007/BF00212792 8110022
Liebl B, Mayer R, Kashube M, Wächter H. 1996. [Pentachlorphenol - Ergebnisse aus einem bayerischen human-monitoring-programm]. Gesundheitswesen. 58:332–338. 8766848
Lilienblum W. 1985. Formation of pentachlorophenol glucuronide in rat and human liver microsomes. Biochem Pharmacol. 34(6):893–894. 10.1016/0006-2952(85)90771-3 3977960
Lin PH, La DK, Upton PB, Swenberg JA. 2002. Analysis of DNA adducts in rats exposed to pentachlorophenol. Carcinogenesis. 23(2):365–369. 10.1093/carcin/23.2.365 11872646
Lin PH, Nakamura J, Yamaguchi S, La DK, Upton PB, Swenberg JA. 2001 a. Induction of direct adducts, apurinic/apyrimidinic sites and oxidized bases in nuclear DNA of human HeLa S3 tumor cells by tetrachlorohydroquinone. Carcinogenesis. 22(4):635–639. 10.1093/carcin/22.4.635 11285200
Lin PH, Nakamura J, Yamaguchi S, Upton PB, La DK, Swenberg JA. 2001 b. Oxidative damage and direct adducts in calf thymus DNA induced by the pentachlorophenol metabolites, tetrachlorohydroquinone and tetrachloro-1,4-benzoquinone. Carcinogenesis. 22(4):627–634. 10.1093/carcin/22.4.627 11285199
Lin PH, Waidyanatha S, Pollack GM, Rappaport SM. 1997. Dosimetry of chlorinated quinone metabolites of pentachlorophenol in the livers of rats and mice based upon measurement of protein adducts. Toxicol Appl Pharmacol. 145(2):399–408. 10.1006/taap.1997.8207 9266814
Lin PH, Waidyanatha S, Pollack GM, Swenberg JA, Rappaport SM. 1999. Dose-specific production of chlorinated quinone and semiquinone adducts in rodent livers following administration of pentachlorophenol. Toxicol Sci. 47(1):126–133. 10.1093/toxsci/47.1.126 10048161
Lin PH, Waidyanatha S, Rappaport SM. 1996. Investigation of liver binding of pentachlorophenol based upon measurement of protein adducts. Biomarkers. 1(4):232–243. 10.3109/13547509609079363 23888990
Lin YP, Zhu BZ, Yang MC, Frei B, Pan MH, Lin JK, Wang YJ. 2004. Bcl-2 overexpression inhibits tetrachlorohydroquinone-induced apoptosis in NIH3T3 cells: A possible mechanism for tumor promotion. Mol Carcinog. 40(1):24–33. 10.1002/mc.20021 15108327
Littorin M, Hansson M, Rappe C, Kogevinas M. 1994. Dioxins in blood from Swedish phenoxy herbicide workers. Lancet. 344(8922):611–612. 10.1016/S0140-6736(94)91995-X 7914976
Lores EM, Edgerton TR, Moseman RF. 1981. Method for the confirmation of chlorophenols in human urine by LC with an electrochemical detector. J Chromatogr Sci. 19(9):466–469. 10.1093/chromsci/19.9.466 7298793
Ma X, Buffler PA, Layefsky M, Does MB, Reynolds P. 2004. Control selection strategies in case-control studies of childhood diseases. Am J Epidemiol. 159(10):915–921. 10.1093/aje/kwh136 15128601
Manske DD, Johnson RD. 1977. Residues in food and feed. Pesticide and other chemical residues in total diet samples (X). Pestic Monit J. 10(4):134–148. 857241
Markel HL, Ligo RN, Lucas JB. 1977. Health hazard evaluation determination: Koppers Company, Incorporated, North Little Rock, Arkansas. Cincinnati, OH: National Institute for Occupational Safety and Health. Report No. 75-117-372.
Markel HL, Lucas JB. 1975. Health hazard evaluation determination: Weyerhaeuser Treating Plant, De Queen, Arkansas. Cincinnati, OH: National Institute for Occupational Safety and Health. Report No. 74-117-251.
Markiewicz KV, Howie LE, Safe SH, Donnelly KC. 1996. Mutagenic potential of binary and complex mixtures using different enzyme induction systems. J Toxicol Environ Health. 47(5):443–451. 10.1080/009841096161591 8614014
Marlow D, Fingerhut M. 1985a. Dioxin registry report: Walk-through survey of pentachlorophenol production facility at Vulcan Materials Company, Wichita, Kansas. Cincinnati, OH: National Institute for Occupational Safety and Health. Report No. 117.19.
Marlow DA. 1986. An exposure matrix for the NIOSH dioxin registry. Chemosphere. 15(9-12):1753–1764. 10.1016/0045-6535(86)90464-9
Marlow DA, Fingerhut M. 1985b. Site visit report, Reichold Chemicals Inc., Tacoma, Washington. Cincinnati, OH: National Institutes of Occupational Safety and Health. Report No. IWS-117-17.
Marlow DA, Fingerhut M, Blade LM, Piacitelli L, Roberts D. 1991. Dioxin registry report of the Dow Chemical Company, Midland, Michigan. Cincinnati, OH: National Institute for Occupational Safety and Health. Report No. 117.15.
Marlow DA, Fingerhut MA, Piacitelli LA. 1997. Dioxin registry report of Monsanto Company, Sauget, Illinois. Cincinnati, OH: National Institute of Occupational Safety and Health. Report No. 117-23.
Maronpot RR, Zeiger E, McConnell EE, Kolenda-Roberts H, Wall H, Friedman MA. 2009. Induction of tunica vaginalis mesotheliomas in rats by xenobiotics. Crit Rev Toxicol. 39(6):512–537. 10.1080/10408440902969430 19545199
Matsumoto G. 1982. Comparative study on organic constituents in polluted and unpolluted inland aquatic environments. III. Phenols and aromatic acids in polluted and unpolluted waters. Water Res. 16(5):551–557. 10.1016/0043-1354(82)90075-6
Matsumoto G, Ishiwatari R, Hanya T. 1977. Gas chromatographic-mass spectrometric identification of phenols and aromatic acids in river waters. Water Res. 11(8):693–698. 10.1016/0043-1354(77)90109-9
McConnachie PR, Zahalsky AC. 1991. Immunological consequences of exposure to pentachlorophenol. Arch Environ Health. 46(4):249–253. 10.1080/00039896.1991.9937456 2069434
McConnell EE, Huff JE, Hejtmancik M, Peters AC, Persing R. 1991. Toxicology and carcinogenesis studies of two grades of pentachlorophenol in B6C3F1 mice. Fundam Appl Toxicol. 17(3):519–532. 10.1016/0272-0590(91)90202-F 1794655
McLean D, Eng A, Dryson E, Walls C, Harding E, Wong KC, Cheng S, Mannetje A, Ellison-Loschmann L, Slater T, et al. 2009 a. Morbidity in former sawmill workers exposed to pentachlorophenol (PCP): A cross-sectional study in New Zealand. Am J Ind Med. 52(4):271–281. 10.1002/ajim.20677 19152355
McLean D, Eng A, Mannetje A, Walls C, Dryson E, Cheng S, Wong K, Pearce N. 2007. Health outcomes in former New Zealand timber workers exposed to pentachlorophenol (PCP). Wellington, New Zealand: Massey University.
McLean D, Eng A, Walls C, Dryson E, Harawira J, Cheng S, Wong KC, Mannetje A, Gray M, Shoemack P, et al. 2009 b. Serum dioxin levels in former New Zealand sawmill workers twenty years after exposure to pentachlorophenol (PCP) ceased. Chemosphere. 74(7):962–967. 10.1016/j.chemosphere.2008.10.017 19036402
Meemken HA, Fuerst P, Habersaat K. 1982. [Analysis of pentachlorophenol in cultured champignons]. Dtsch Lebensmitt Rundsch. 78:282–287.
Meerman JH, Sterenborg HM, Mulder GJ. 1983. Use of pentachlorophenol as long-term inhibitor of sulfation of phenols and hydroxamic acids in the rat in vivo. Biochem Pharmacol. 32(10):1587–1593. 10.1016/0006-2952(83)90332-5 6860346
Mehmood Z, Williamson MP, Kelly DE, Kelly SL. 1996. Metabolism of organochlorine pesticides: The role of human cytochrome P450 3A4. Chemosphere. 33(4):759–769. 10.1016/0045-6535(96)00212-3 8759309
Michałowicz J. 2010. Pentachlorophenol and its derivatives induce oxidative damage and morphological changes in human lymphocytes (in vitro). Arch Toxicol. 84(5):379–387. 10.1007/s00204-010-0515-y 20127076
Michałowicz J, Majsterek I. 2010. Chlorophenols, chlorocatechols and chloroguaiacols induce DNA base oxidation in human lymphocytes (in vitro). Toxicology. 268(3):171–175. 10.1016/j.tox.2009.12.009 20025924
Michałowicz J, Sicińska P. 2009. Chlorophenols and chlorocatechols induce apoptosis in human lymphocytes (in vitro). Toxicol Lett. 191(2-3):246–252. 10.1016/j.toxlet.2009.09.010 19766705
Ministry of Agriculture Fisheries and Food.1989. Report of the working party on pesticide residues: 1985-88. London, England: Ministry of Agriculture, Fisheries and Food. Food Surveillance Paper No. 25.
Mirvish SS, Nickols J, Weisenburger DD, Johnson D, Joshi SS, Kaplan P, Gross M, Tong HY. 1991. Effects of 2,4,5-trichlorophenoxyacetic acid, pentachlorophenol, methylprednisolone, and Freund’s adjuvant on 2-hydroxyethylnitrosourea carcinogenesis in MRC-Wistar rats. J Toxicol Environ Health. 32(1):59–74. 10.1080/15287399109531465 1987363
Monteith DK. 1992. Inhibition of sulfotransferase affecting unscheduled DNA synthesis induced by 2-acetylaminofluorene: An in vivo and in vitro comparison. Mutat Res. 282(4):253–258. 10.1016/0165-7992(92)90131-Z 1379687
Moorthy B, Randerath K. 1996. Pentachlorophenol enhances 9-hydroxybenzo [a] pyrene-induced hepatic DNA adduct formation in vivo and inhibits microsomal epoxide hydrolase and glutathione S-transferase activities in vitro: Likely inhibition of epoxide detoxication by pentachlorophenol. Arch Toxicol. 70(11):696–703. 10.1007/s002040050330 8896715
Morgade C, Barquet A, Pfaffenberger CD. 1980. Determination of polyhalogenated phenolic compounds in drinking-water, human blood-serum, and adipose tissue. Bull Environ Contam Toxicol. 24(2):257–264. 10.1007/BF01608106 7362906
Morton LM, Hartge P, Holford TR, Holly EA, Chiu BC, Vineis P, Stagnaro E, Willett EV, Franceschi S, La Vecchia C, et al. 2005. Cigarette smoking and risk of non-Hodgkin lymphoma: A pooled analysis from the International Lymphoma Epidemiology Consortium (InterLymph). Cancer Epidemiol Biomarkers Prev. 14(4):925–933. 10.1158/1055-9965.EPI-04-0693 15824165
Mulder GJ, Scholtens E. 1977. Phenol sulphotransferase and uridine diphosphate glucuronyltransferase from rat liver in vivo and in vitro. 2,6-Dichloro-4-nitrophenol as selective inhibitor of sulphation. Biochem J. 165(3):553–559. 10.1042/bj1650553 411489
Murata-Kamiya N, Tsutsui T, Fujino A, Kasai H, Kaji H. 1997. Determination of carcinogenic potential of mineral fibers by 8-hydroxydeoxyguanosine as a marker of oxidative DNA damage in mammalian cells. Int Arch Occup Environ Health. 70(5):321–326. 10.1007/s004200050225 9352335
Murray HE, Ray LE, Giam CS. 1981. Analysis of marine sediment, water, and biota for selected organic pollutants. Chemosphere. 10(11-12):1327–1334. 10.1016/0045-6535(81)90051-5
Naito S, Ono Y, Somiya I, Inoue S, Ito K, Yamamoto K, Kawanishi S. 1994. Role of active oxygen species in DNA damage by pentachlorophenol metabolites. Mutat Res. 310(1):79–88. 10.1016/0027-5107(94)90011-6 7523887
National Cancer Institute (NCI). 1979. Bioassay of a 4,4,6-trichlorophenol for possible carcinogenicity (CAS no. 88-06-2). Bethesda, MD: National Institutes of Health. Technical Report Series No. 155. NIH Publication No. 80-1758.
National Cancer Institute (NCI). 2013. A snapshot of myeloma. Bethesda, MD: National Institutes of Health. https://www.cancer.gov/researchandfunding/snapshots/myeloma. [Accessed: July 10, 2014]
National Institute for Occupational Safety and Health (NIOSH). 1990. National Occupational Hazard Survey (1981-1983). Cincinnati, OH: National Institute for Occupational Safety and Health. https://www.cdc.gov/noes/noes4/54160sco.html.
National Response Center (NRC). 2013. National Response Center. Washington, DC: United States Coast Guard. http://www.nrc.uscg.mil.
National Toxicology Program (NTP). 1980a. Bioassay of a mixture of 1, 2, 3, 6, 7, 8-hexachlorodibenzo-p-dioxin and 1, 2, 3, 7, 8, 9-hexachlorodibenzo-p-dioxin (dermal study) for possible carcinogenicity. Research Triangle Park, NC: National Toxicology Program. Technical Report Series No. 202. NIH Publication No. 80-1758.
National Toxicology Program (NTP). 1980b. Bioassay of a mixture of 1, 2, 3, 6, 7, 8-hexachlorodibenzo-p-dioxin and 1, 2, 3, 7, 8, 9-hexachlorodibenzo-p-dioxin (gavage study) for possible carcinogenicity. Research Triangle Park, NC: National Toxicology Program. Technical Report Series No. 198. NIH Publication No. 80-1754.
National Toxicology Program (NTP). 1982. Carcinogenesis bioassay of 2,3,7,8-tetrachlorodibenzo-p-dioxin (CAS no. 1746-01-6) in Osborne-Mendel rats and B6C3F1 mice. Research Triangle Park, NC: National Toxicology Program. Technical Report Series No. 209. NIH Publication No. 80-1765.
National Toxicology Program (NTP). 1989. Toxicology and carcinogenesis studies of two pentachlorophenol technical-grade mixtures(CAS no. 87-86-5) administered in B6C3F1 mice (feed studies). Research Triangle Park, NC: National Toxicology Program. Technical Report Series No. 349. NIH Publication No. 89-2804.
National Toxicology Program (NTP). 1999. Toxicology and carcinogenesis studies of pentachlorophenol (CAS no. 87-86-5) in F344/N rats (feed studies). Research Triangle Park, NC: National Toxicology Program. Technical Report Series No. 483. NIH Publication No. 99-3973.
National Toxicology Program (NTP). 2011. 12th report on carcinogens. Research Triangle Park, NC: National Toxicology Program. https://ntp.niehs.nih.gov/go/roc12.
Nishimura H, Nishimura N, Oshima H. 1982 a. Effects of pentachlorophenol on the levels of hepatic glycogen. Sangyo Igaku. 24(4):398–399. 10.1539/joh1959.24.398 7143812
Nishimura N, Nishimura H, Oshima H. 1982 b. Survey on mutagenicity of pesticides by the Salmonella-microsome test. J Aichi Med Univ Assoc. 10(4):305–312.
Nishimura N, Oshima H. 1983. [Mutagenicity of pentachlorophenol, dinitro-o-cresol and their related compounds]. Sangyo Igaku. 25(6):510–511. 10.1539/joh1959.25.510 6379230
Nnodu U, Whalen MM. 2008. Pentachlorophenol decreases ATP levels in human natural killer cells. J Appl Toxicol. 28(8):1016–1020. 10.1002/jat.1367 18623605
Nordström M, Hardell L, Magnuson A, Hagberg H, Rask-Andersen A. 1998. Occupational exposures, animal exposure and smoking as risk factors for hairy cell leukaemia evaluated in a case-control study. Br J Cancer. 77(11):2048–2052. 10.1038/bjc.1998.341 9667691
Norén K, Sjövall J. 1987. Analysis of pentachlorophenol in water and urine by enrichment with Lipidex 5000. J Chromatogr. 414(1):55–63. 10.1016/0378-4347(87)80024-5 2437139
Ott MG, Olson RA, Cook RR, Bond GG. 1987. Cohort mortality study of chemical workers with potential exposure to the higher chlorinated dioxins. J Occup Med. 29(5):422–429. 2439670
Ozaki A, Yamaguchi Y, Fujita T, Kuroda K, Endo G. 2004. Chemical analysis and genotoxicological safety assessment of paper and paperboard used for food packaging. Food Chem Toxicol. 42(8):1323–1337. 10.1016/j.fct.2004.03.010 15207384
Päpke O, Ball M, Lis A. 1992. Various PCDD/PCDF patterns in human blood resulting from different occupational exposures. Chemosphere. 25(7-10):1101–1108. 10.1016/0045-6535(92)90114-7
Park JS, Bergman A, Linderholm L, Athanasiadou M, Kocan A, Petrik J, Drobna B, Trnovec T, Charles MJ, Hertz-Picciotto I. 2008. Placental transfer of polychlorinated biphenyls, their hydroxylated metabolites and pentachlorophenol in pregnant women from eastern Slovakia. Chemosphere. 70(9):1676–1684. 10.1016/j.chemosphere.2007.07.049 17764717
Pavlica M, Klobučar GI, Mojaš N, Erben R, Papeš D. 2001. Detection of DNA damage in haemocytes of zebra mussel using comet assay. Mutat Res. 490(2):209–214. 10.1016/S1383-5718(00)00162-5 11342246
Pavlica M, Klobučar GI, Vetma N, Erben R, Papeš D. 2000. Detection of micronuclei in haemocytes of zebra mussel and great ramshorn snail exposed to pentachlorophenol. Mutat Res. 465(1-2):145–150. 10.1016/S1383-5718(99)00222-3 10708980
Pavlica M, Vasilevska J, Papĕs D. 1998. Genotoxicity of pentachlorophenol revealed by allium chromosome aberration assay. Acta Biol Crac. 40:85–90.
Pearce NE, Sheppard RA, Smith AH, Teague CA. 1987. Non-Hodgkin’s lymphoma and farming: An expanded case-control study. Int J Cancer. 39(2):155–161. 10.1002/ijc.2910390206 3804490
Pearce NE, Smith AH, Howard JK, Sheppard RA, Giles HJ, Teague CA. 1986 a. Case-control study of multiple myeloma and farming. Br J Cancer. 54(3):493–500. 10.1038/bjc.1986.202 3756085
Pearce NE, Smith AH, Howard JK, Sheppard RA, Giles HJ, Teague CA. 1986 b. Non-Hodgkin’s lymphoma and exposure to phenoxyherbicides, chlorophenols, fencing work, and meat works employment: A case-control study. Br J Ind Med. 43(2):75–83. 10.1136/oem.43.2.75 3753879
Pekari K, Luotamo M, Järvisalo J, Lindroos L, Aitio A. 1991. Urinary excretion of chlorinated phenols in saw-mill workers. Int Arch Occup Environ Health. 63(1):57–62. 10.1007/BF00406199 1856025
Peper M, Ertl M, Gerhard I. 1999. Long-term exposure to wood-preserving chemicals containing pentachlorophenol and lindane is related to neurobehavioral performance in women. Am J Ind Med. 35(6):632–641. 10.1002/(SICI)1097-0274(199906)35:6<632::AID-AJIM10>3.0.CO;2-R 10332516
Pierce RH Jr, Brent CR, Williams HP, Reeves SG. 1977. Pentachlorophenol distribution in a fresh water ecosystem. Bull Environ Contam Toxicol. 18(2):251–258. 10.1007/BF01686075 890162
Pu X, Carlson G, Lee L. 2003. Oral bioavailability of pentachlorophenol from soils of varying characteristics using a rat model. J Toxicol Environ Health A. 66(21):2001–2013. 10.1080/15287390390227615 14555398
Purschke M, Jacobi H, Witte I. 2002. Differences in genotoxicity of H(2)O(2) and tetrachlorohydroquinone in human fibroblasts. Mutat Res. 513(1-2):159–167. 10.1016/S1383-5718(01)00311-4 11719101
Qiao GL, Brooks JD, Riviere JE. 1997. Pentachlorophenol dermal absorption and disposition from soil in swine: Effects of occlusion and skin microorganism inhibition. Toxicol Appl Pharmacol. 147(2):234–246. 10.1006/taap.1997.8288 9439719
Qiao GL, Riviere JE. 2002. Systemic uptake and cutaneous disposition of pentachlorophenol in a sequential exposure scenario: Effects of skin preexposure to benzo[a]pyrene. J Toxicol Environ Health A. 65(18):1307–1331. 10.1080/00984100290071577 12227954
Ramel C, Magnusson J. 1979. Chemical induction of nondisjunction in drosophila. Environ Health Perspect. 31:59–66. 10.1289/ehp.793159 499128
Ramlow JM, Spadacene NW, Hoag SR, Stafford BA, Cartmill JB, Lerner PJ. 1996. Mortality in a cohort of pentachlorophenol manufacturing workers, 1940-1989. Am J Ind Med. 30(2):180–194. 10.1002/(SICI)1097-0274(199608)30:2<180::AID-AJIM9>3.0.CO;2-4 8844048
Reed A, Dzon L, Loganathan BG, Whalen MM. 2004. Immunomodulation of human natural killer cell cytotoxic function by organochlorine pesticides. Hum Exp Toxicol. 23(10):463–471. 10.1191/0960327104ht477oa 15553171
Reigner BG, Bois FY, Tozer TN. 1992 a. Assessment of pentachlorophenol exposure in humans using the clearance concept. Hum Exp Toxicol. 11(1):17–26. 10.1177/096032719201100103 1354455
Reigner BG, Gungon RA, Bois FY, Zeise L, Tozer TN. 1992 b. Pharmacokinetic concepts in assessing intake of pentachlorophenol by rats after exposure through drinking water. J Pharm Sci. 81(11):1113–1118. 10.1002/jps.2600811115 1447716
Reigner BG, Gungon RA, Hoag MK, Tozer TN. 1991. Pentachlorophenol toxicokinetics after intravenous and oral administration to rat. Xenobiotica. 21(12):1547–1558. 10.3109/00498259109044404 1785202
Reigner BG, Rigod JF, Tozer TN. 1992 c. Disposition, bioavailability, and serum protein binding of pentachlorophenol in the B6C3F1 mouse. Pharm Res. 9(8):1053–1057. 10.1023/A:1015810629245 1409377
Renner G. 1989. Urinary excretion of pentachlorophenol (PCP) and its metabolite tetrachlorohydroquinone (TCH) in rats. Toxicol Environ Chem. 25(1):29–32. 10.1080/02772248909357502
Renner G, Hopfer C. 1990. Metabolic studies on pentachlorophenol (PCP) in rats. Xenobiotica. 20(6):573–582. 10.3109/00498259009046872 2219952
Repetto G, Jos A, Hazen MJ, Molero ML, del Peso A, Salguero M, Castillo PD, Rodríguez-Vicente MC, Repetto M. 2001. A test battery for the ecotoxicological evaluation of pentachlorophenol. Toxicol In Vitro. 15(4-5):503–509. 10.1016/S0887-2333(01)00055-8 11566584
Robinson CF, Fowler D, Brown DP, Lemen RA. 1987. Plywood mill workers’ mortality patterns 1945-1977 (revised March 1987). Cincinnati, OH: National Institute for Occupational Safety and Health. NTIS PB 90-147075.
Rosensteel RE. 1978. Hazard evaluation and technical assistance report: United States Department of the Interior, National Park Service, Fort Stanwix National Monument, Rome, New York. Cincinnati, OH: National Institute for Occupational Safety and Health. Report No. TA 77–63.
Rozman T, Ballhorn L, Rozman K, Klaassen C, Greim H. 1982. Effect of cholestyramine on the disposition of pentachlorophenol in rhesus monkeys. J Toxicol Environ Health. 10(2):277–283. 10.1080/15287398209530250 7143481
Ruder AM, Carreón T, Butler MA, Calvert GM, Davis-King KE, Waters MA, Schulte PA, Mandel JS, Morton RF, Reding DJ, et al. 2009. Exposure to farm crops, livestock, and farm tasks and risk of glioma: The Upper Midwest Health Study. Am J Epidemiol. 169(12):1479–1491. 10.1093/aje/kwp075 19403843
Ruder AM, Sweeney MH. 2009. Pentachlorophenol production workers mortality study. Am J Epidemiol. 169 Suppl:S91.
Ruder AM, Waters MA, Butler MA, Carreón T, Calvert GM, Davis-King KE, Schulte PA, Sanderson WT, Ward EM, Connally LB, et al. 2004. Gliomas and farm pesticide exposure in men: The Upper Midwest Health Study. Arch Environ Health. 59(12):650–657. 10.1080/00039890409602949 16789473
Ruder AM, Waters MA, Carreón T, Butler MA, Davis-King KE, Calvert GM, Schulte PA, Ward EM, Connally LB, Lu J, et al. 2006. The Upper Midwest Health Study: A case-control study of primary intracranial gliomas in farm and rural residents. J Agric Saf Health. 12(4):255–274. 10.13031/2013.22013 17131948
Ruder AM, Yiin JH. 2011. Mortality of US pentachlorophenol production workers through 2005. Chemosphere. 83(6):851–861. 10.1016/j.chemosphere.2011.02.064 21440286
Rudling L. 1970. Determination of pentachlorophenol in organic tissues and water. Water Res. 4(8):533–537. 10.1016/0043-1354(70)90003-5
Ryan JJ. 1983. Higher chlorinated dioxins implicated in the mortality of young pigs kept on a pentachlorophenol-treated wooden floor. Can Vet J. 24(3):72–75. 17422233
Ryan JJ, Lizotte R, Sakuma T, Mori B. 1985. Chlorinated dibenzo-p-dioxins, chlorinated dibenzofurans, and pentachlorophenol in Canadian chicken and pork samples. J Agric Food Chem. 33(6):1021–1026. 10.1021/jf00066a003
Sai K, Kang KS, Hirose A, Hasegawa R, Trosko JE, Inoue T. 2001. Inhibition of apoptosis by pentachlorophenol in v-myc-transfected rat liver epithelial cells: Relation to down-regulation of gap junctional intercellular communication. Cancer Lett. 173(2):163–174. 10.1016/S0304-3835(01)00616-4 11597791
Sai K, Kanno J, Hasegawa R, Trosko JE, Inoue T. 2000. Prevention of the down-regulation of gap junctional intercellular communication by green tea in the liver of mice fed pentachlorophenol. Carcinogenesis. 21(9):1671–1676. 10.1093/carcin/21.9.1671 10964098
Sai K, Upham BL, Kang KS, Hasegawa R, Inoue T, Trosko JE. 1998. Inhibitory effect of pentachlorophenol on gap junctional intercellular communication in rat liver epithelial cells in vitro. Cancer Lett. 130(1-2):9–17. 10.1016/S0304-3835(98)00082-2 9751251
Sai-Kato K, Takagi A, Umemura T, Hasegawa R, Kurokawa Y. 1995 a. Role of oxidative stress in non-genotoxic carcinogenesis with special reference to liver tumors induced by peroxisome proliferators. Biomed Environ Sci. 8(3):269–279. 8561928
Sai-Kato K, Umemura T, Takagi A, Hasegawa R, Tanimura A, Kurokawa Y. 1995 b. Pentachlorophenol-induced oxidative DNA damage in mouse liver and protective effect of antioxidants. Food Chem Toxicol. 33(10):877–882. 10.1016/0278-6915(95)00056-8 7590532
Samokyszyn VM, Freeman JP, Maddipati KR, Lloyd RV. 1995. Peroxidase-catalyzed oxidation of pentachlorophenol. Chem Res Toxicol. 8(3):349–355. 10.1021/tx00045a005 7578920
Sandau CD, Ayotte P, Dewailly E, Duffe J, Norstrom RJ. 2000. Analysis of hydroxylated metabolites of PCBs (OH-PCBs) and other chlorinated phenolic compounds in whole blood from Canadian Inuit. Environ Health Perspect. 108(7):611–616. 10.1289/ehp.00108611 10903613
Sangster B, Wegman RC, Hofstee AW. 1982. Non-occupational exposure to pentachlorophenol: Clinical findings and plasma-PCP-concentrations in three families. Hum Toxicol. 1(2):123–133. 10.1177/096032718200100204 7173893
Santodonato J. 1986. Monograph on human exposure to chemicals in the workplace: Pentachlorophenol. Bethesda, MD: National Cancer Institute. NTIS PB86-B155116.
Saracci R, Kogevinas M, Bertazzi PA, Bueno de Mesquita BH, Coggon D, Green LM, Kauppinen T, L’Abbé KA, Littorin M, Lynge E, et al. 1991. Cancer mortality in workers exposed to chlorophenoxy herbicides and chlorophenols. Lancet. 338(8774):1027–1032. 10.1016/0140-6736(91)91898-5 1681353
Saur JM, Walcheski PJ, Nicholas DD, Gjovik LR. 1982. The concentration of airborne pentachlorophenol within treated wood structures. Proc Ann Meet Am Wood Preserv Assoc. 78:169-173.
Schecter A, Jiang K, Päpke O, Fürst P, Fürst C. 1994. Comparison of dibenzodioxin levels in blood and milk in agricultural workers and others following pentachlorophenol exposure in China. Chemosphere. 29(9-11):2371–2380. 10.1016/0045-6535(94)90406-5 7850386
Schmid E, Bauchinger M, Dresp J. 1982. Chromosome analyses of workers from a pentachlorophenol plant. Prog Clin Biol Res. 109:471–477. 7167559
Schnelle-Kreis J, Scherb H, Gebefügi I, Kettrup A, Weigelt E. 2000. Pentachlorophenol in indoor environments. Correlation of PCP concentrations in air and settled dust from floors. Sci Total Environ. 256(2-3):125–132. 10.1016/S0048-9697(00)00476-9 10902840
Schwetz BA, Keeler PA, Gehring PJ. 1974. The effect of purified and commercial grade pentachlorophenol on rat embryonal and fetal development. Toxicol Appl Pharmacol. 28(1):151–161. 10.1016/0041-008X(74)90141-0 4854776
Schwetz BA, Quast IF, Keeler PA, Humiston CG, Kociba RJ. 1978. Results of two-year toxicity and reproduction studies on pentachlorophenol in rats. In: Rao KR, editor. Pentachlorophenol: Chemistry, Pharmacology, and Environmental Toxicology. New York, NY: Plenum Press. p. 301–309. 10.1007/978-1-4615-8948-8_26
Seiler JP. 1991. Pentachlorophenol. Mutat Res. 257(1):27–47. 10.1016/0165-1110(91)90018-Q 1987456
Shatalov V. 2002. Contribution of EMEP/MSC-East to the report Health Risks of POPs from LRTAP. Moscow, Russia: EMEP Meteorological Synthesizing Centre.
Shore RF, Myhill DG, French MC, Leach DV, Stebbings RE. 1991. Toxicity and tissue distribution of pentachlorophenol and permethrin in pipistrelle bats experimentally exposed to treated timber. Environ Pollut. 73(2):101–118. 10.1016/0269-7491(91)90017-Q 15092084
Siegwart Y. 1983. [Control of foodstuff in Switzerland in the year 1982]. Mitt Geb Lebensm Hyg. 74:179–319.
Smarte.org. 2008. Understanding units of measurement. http://www.smarte.org/smarte/resource/sn-units-of-measure.xml.
Smith AH, Lopipero P. 2001. Evaluation of the toxicity of dioxins and dioxin-like PCBs: A health risk appraisal for the New Zealand population. Wellington, New Zealand: New Zealand Ministry for the Environment. ME No. 351.
Smith AH, Pearce NE, Fisher DO, Giles HJ, Teague CA, Howard JK. 1984. Soft tissue sarcoma and exposure to phenoxyherbicides and chlorophenols in New Zealand. J Natl Cancer Inst. 73(5):1111–1117. 6593487
Smith JE, Loveless LE, Belden EA. 1996. Pentachlorophenol poisoning in newborn infants—St. Louis, Missouri, April-August 1967. MMWR Morb Mortal Wkly Rep. 45(25):545–549. 9132572
Smith JG, Christophers AJ. 1992. Phenoxy herbicides and chlorophenols: A case control study on soft tissue sarcoma and malignant lymphoma. Br J Cancer. 65(3):442–448. 10.1038/bjc.1992.90 1558802
Smith JG, Lee SF, Netzer A. 1976. Model studies in aqueous chlorination: The chlorination of phenols in dilute aqueous solutions. Water Res. 10(11):985–990. 10.1016/0043-1354(76)90077-4
Spalding JW, French JE, Stasiewicz S, Furedi-Machacek M, Conner F, Tice RR, Tennant RW. 2000. Responses of transgenic mouse lines p53(+/-) and Tg.AC to agents tested in conventional carcinogenicity bioassays. Toxicol Sci. 53(2):213–223. 10.1093/toxsci/53.2.213 10696769
SRI Consulting. 2012. Directory of chemical producers. Database edition. Menlo Park, CA: SRI Consulting; [Accessed: January 11, 2012].
Stang A, Witte I. 2010. The ability of the high-throughput comet assay to measure the sensitivity of five cell lines toward methyl methanesulfonate, hydrogen peroxide, and pentachlorophenol. Mutat Res. 701(2):103–106. 10.1016/j.mrgentox.2010.04.011 20399888
Stedman TM Jr, Booth NH, Bush PB, Page RK, Goetsch DD. 1980. Toxicity and bioaccumulation of pentachlorophenol in broiler chickens. Poult Sci. 59(5):1018–1026. 10.3382/ps.0591018 7393838
Stewart FP, Smith AG. 1986. Metabolism of the “mixed” cytochrome P-450 inducer hexachlorobenzene by rat liver microsomes. Biochem Pharmacol. 35(13):2163–2170. 10.1016/0006-2952(86)90587-3 3729973
Suzuki T, Komatsu M, Isono H. 1997. Cytotoxicity of organochlorine pesticides and lipid peroxidation in isolated rat hepatocytes. Biol Pharm Bull. 20(3):271–274. 10.1248/bpb.20.271 9084885
Tasaki M, Kuroiwa Y, Inoue T, Hibi D, Matsushita K, Ishii Y, Maruyama S, Nohmi T, Nishikawa A, Umemura T. 2013. Oxidative DNA damage and in vivo mutagenicity caused by reactive oxygen species generated in the livers of p53-proficient or -deficient gpt delta mice treated with non-genotoxic hepatocarcinogens. J Appl Toxicol. 33(12):1433–1441. 10.1002/jat.2807 22972318
Tasaki M, Kuroiwa Y, Inoue T, Hibi D, Matsushita K, Kijima A, Maruyama S, Nishikawa A, Umemura T. 2014. Lack of nrf2 results in progression of proliferative lesions to neoplasms induced by long-term exposure to non-genotoxic hepatocarcinogens involving oxidative stress. Exp Toxicol Pathol. 66(1):19–26. 10.1016/j.etp.2013.07.003 23988840
Tashiro S, Sasamoto T, Aikawa T, Tokunaga S, Taniguchi E, Eto M. 1970. [Metabolism of pentachlorophenol in mammals]. Nippon Nogeikagaku Kaishi. 44(3):124–129. 10.1271/nogeikagaku1924.44.124
Taylor TR, Tucker T, Whalen MM. 2005. Persistent inhibition of human natural killer cell function by ziram and pentachlorophenol. Environ Toxicol. 20(4):418–424. 10.1002/tox.20127 16007644
Temme A, Buchmann A, Gabriel HD, Nelles E, Schwarz M, Willecke K. 1997. High incidence of spontaneous and chemically induced liver tumors in mice deficient for connexin32. Curr Biol. 7(9):713–716. 10.1016/S0960-9822(06)00302-2 9285723
Teschke K, Hertzman C, Dimich-Ward H, Ostry A, Blair J, Hershler R. 1989. A comparison of exposure estimates by worker raters and industrial hygienists. Scand J Work Environ Health. 15(6):424–429. 10.5271/sjweh.1831 2617258
Teschke K, Marion SA, Ostry A, Hertzman C, Hershler R, Dimich-Ward H, Kelly S. 1996. Reliability of retrospective chlorophenol exposure estimates over five decades. Am J Ind Med. 30(5):616–622. 10.1002/(SICI)1097-0274(199611)30:5<616::AID-AJIM10>3.0.CO;2-6 8909611
Teschke K, Ostry A, Hertzman C, Demers PA, Barroetavena MC, Davies HW, Dimich-Ward H, Heacock H, Marion SA. 1998. Opportunities for a broader understanding of work and health: Multiple uses of an occupational cohort database. Can J Public Health. 89(2):132–136. 10.1007/BF03404406 9583257
Thind KS, Karmali S, House RA. 1991. Occupational exposure of electrical utility linemen to pentachlorophenol. Am Ind Hyg Assoc J. 52(12):547–552. 10.1080/15298669191365180 1781434
Thomasson G, Capizzi J, Dost F, Morrell J, Miller D. 2006. Wood preservation and wood products treatment: Training manual. Corvallis, OR: Oregon State University.
Thompson GE, Husain H, Parry J, Wardrop WL, Gilbride PJ.1978. Hydrogeological control and clean-up of soil and groundwater contaminants at Northern Wood Preservers, Ltd. In: Proceedings of the Ontario Industrial Waste Conference, Toronto, June 18-21, Winnipeg, Manitoba. Engineering Consultants.
Thompson TS, Treble RG. 1994. Preliminary results of a survey of pentachlorophenol levels in human urine. Bull Environ Contam Toxicol. 53(2):274–279. 10.1007/BF00192044 8086711
Thompson TS, Treble RG. 1996. Pentachlorophenol levels in human urine. Bull Environ Contam Toxicol. 56(4):520–526. 10.1007/s001289900075 8645905
Tisch M, Faulde MK, Maier H. 2005. Genotoxic effects of pentachlorophenol, lindane, transfluthrin, cyfluthrin, and natural pyrethrum on human mucosal cells of the inferior and middle nasal conchae. Am J Rhinol. 19(2):141–151. 10.1177/194589240501900206 15921213
To-Figueras J, Sala M, Otero R, Barrot C, Santiago-Silva M, Rodamilans M, Herrero C, Grimalt J, Sunyer J. 1997. Metabolism of hexachlorobenzene in humans: Association between serum levels and urinary metabolites in a highly exposed population. Environ Health Perspect. 105(1):78–83. 10.1289/ehp.9710578 9074885
TOXMAP. 2013. TOXMAP: Environmental health e-maps. Bethesda, MD: National Library of Medicine. http://toxmap.nlm.nih.gov/toxmap/main/index.jsp and search pentachlorophenol. [Accessed: July 2, 2013]
Treble RG, Thompson TS. 1996. Normal values for pentachlorophenol in urine samples collected from a general population. J Anal Toxicol. 20(5):313–317. 10.1093/jat/20.5.313 8872241
Tsai CH, Lin PH, Waidyanatha S, Rappaport SM. 2001. Characterization of metabolic activation of pentachlorophenol to quinones and semiquinones in rodent liver. Chem Biol Interact. 134(1):55–71. 10.1016/S0009-2797(00)00318-5 11248222
Tsai CH, Lin PH, Waidyanatha S, Rappaport SM. 2002. Fractionation of protein adducts in rats and mice dosed with [14C]pentachlorophenol. Arch Toxicol. 76(11):628–633. 10.1007/s00204-002-0394-y 12415425
Uhl S, Schmid P, Schlatter C. 1986. Pharmacokinetics of pentachlorophenol in man. Arch Toxicol. 58(3):182–186. 10.1007/BF00340979 3964082
Umemura T, Kai S, Hasegawa R, Kanki K, Kitamura Y, Nishikawa A, Hirose M. 2003 a. Prevention of dual promoting effects of pentachlorophenol, an environmental pollutant, on diethylnitrosamine-induced hepato- and cholangiocarcinogenesis in mice by green tea infusion. Carcinogenesis. 24(6):1105–1109. 10.1093/carcin/bgg053 12807750
Umemura T, Kai S, Hasegawa R, Sai K, Kurokawa Y, Williams GM. 1999. Pentachlorophenol (PCP) produces liver oxidative stress and promotes but does not initiate hepatocarcinogenesis in B6C3F1 mice. Carcinogenesis. 20(6):1115–1120. 10.1093/carcin/20.6.1115 10357797
Umemura T, Kodama Y, Kanki K, Iatropoulos MJ, Nishikawa A, Hirose M, Williams GM. 2003 b. Pentachlorophenol (but not phenobarbital) promotes intrahepatic biliary cysts induced by diethylnitrosamine to cholangio cystic neoplasms in B6C3F1 mice possibly due to oxidative stress. Toxicol Pathol. 31(1):10–13. 10.1080/01926230390173806 12597444
Umemura T, Kuroiwa Y, Kitamura Y, Ishii Y, Kanki K, Kodama Y, Itoh K, Yamamoto M, Nishikawa A, Hirose M. 2006. A crucial role of Nrf2 in in vivo defense against oxidative damage by an environmental pollutant, pentachlorophenol. Toxicol Sci. 90(1):111–119. 10.1093/toxsci/kfj076 16352618
Umemura T, Sai-Kato K, Takagi A, Hasegawa R, Kurokawa Y. 1996. Oxidative DNA damage and cell proliferation in the livers of B6C3F1 mice exposed to pentachlorophenol in their diet. Fundam Appl Toxicol. 30(2):285–289. 10.1006/faat.1996.0066 8812277
United States International Trade Commission (USITC). 2013. USITC interactive tariff and trade dataweb. Washington, DC: United States International Trade Commission. https://dataweb.usitc.gov/scripts/user_set.asp and search on HTS nos. 3808, 2908, 290811 and 380850. [Accessed: March 7, 2013]
U.S. Environmental Protection Agency (USEPA). 1980. Exposure and risk assessment for pentachlorophenol. Washington, DC: U.S. Environmental Protection Agency. NTIS PB85–B211944. EPA 440/4-81-021.
U.S. Environmental Protection Agency (USEPA). 1999. Pentachlorophenol integrated RED science documeny. Washington, DC: U.S. Environmental Protection Agency.
U.S. Environmental Protection Agency (USEPA). 2008 a. Occupational and residential exposure chapter of the pentachlorophenol (PCP) reregistration eligibility decision (RED) document. Washington, DC: U.S. Environmental Protection Agency.
U.S. Environmental Protection Agency (USEPA). 2008b. Reregistration eligibility decision for pentachlorophenol. Washington, DC: U.S. Environmental Protection Agency. EPA 739-R-08-008.
U.S. Environmental Protection Agency (USEPA). 2010. Toxicological review of pentachlorophenol (CAS no. 87-86-5) in support of summary information on the Integrated Risk Information System (IRIS). Washington, DC: U.S. Environmental Protection Agency. EPA/635/R-09/004F.
U.S. Environmental Protection Agency (USEPA). 2013a. Inventory update reporting (IUR). Washington, DC: U.S. Environmental Protection Agency. https://www.epa.gov/iur/tools/data/index.html and search by CAS no. [Accessed: March 6, 2013]
U.S. Environmental Protection Agency (USEPA). 2013b. TRI explorer chemical report. Washington, DC: U.S. Environmental Protection Agency. https://www.epa.gov/triexplorer and select pentachlorophenol.
U.S. Food and Drug Administration (FDA). 2006. U.S. Food and Drug Administration - Total Diet Study market baskets 1991-3 through 2003-4. College Park, MD: U.S. Food and Drug Administration.
Valo R, Kitunen V, Salkinova-Salonen M, Raisanen S. 1984. Chlorinated phenols as contaminants of soil and water in the vicinity of 2 Finnish sawmills. Chemosphere. 13(8):835–844. 10.1016/0045-6535(84)90156-5
Van den Berg M, Birnbaum LS, Denison M, De Vito M, Farland W, Feeley M, Fiedler H, Hakansson H, Hanberg A, Haws L, et al. 2006. The 2005 World Health Organization reevaluation of human and mammalian toxic equivalency factors for dioxins and dioxin-like compounds. Toxicol Sci. 93(2):223–241. 10.1093/toxsci/kfl055 16829543
van Langeveld HEAM. 1975. Determination of pentachlorophenol in toy paints. J Assoc Off Anal Chem. 58(1):19–22. 10.1093/jaoac/58.1.19 1141150
van Ommen B, Adang A, Müller F, van Bladeren PJ. 1986 a. The microsomal metabolism of pentachlorophenol and its covalent binding to protein and DNA. Chem Biol Interact. 60(1):1–11. 10.1016/0009-2797(86)90013-X 3779880
van Ommen B, Hendriks W, Bessems JG, Geesink G, Müller F, van Bladeren PJ. 1989. The relation between the oxidative biotransformation of hexachlorobenzene and its porphyrinogenic activity. Toxicol Appl Pharmacol. 100(3):517–528. 10.1016/0041-008X(89)90299-8 2789443
van Ommen B, van Bladeren PJ, Temmink JH, Brader L, Müller F. 1986 b. The microsomal oxidation of hexachlorobenzene to pentachlorophenol: Effect of inducing agents. IARC Sci Publ. (77):323–324. 3596721
van Ommen B, Voncken JW, Müller F, van Bladeren PJ. 1988. The oxidation of tetrachloro-1,4-hydroquinone by microsomes and purified cytochrome P-450b. Implications for covalent binding to protein and involvement of reactive oxygen species. Chem Biol Interact. 65(3):247–259. 10.1016/0009-2797(88)90110-X 3132330
van Rensburg JFJ. 1981. Health aspects of organic substances in South African waters - opinions and realities. Water S Afr. 7(3):139–149.
Vena J, Boffetta P, Becher H, Benn T, Bueno-de-Mesquita HB, Coggon D, Colin D, Flesch-Janys D, Green L, Kauppinen T, et al. 1998. Exposure to dioxin and nonneoplastic mortality in the expanded IARC international cohort study of phenoxy herbicide and chlorophenol production workers and sprayers. Environ Health Perspect. 106 Suppl 2:645–653. 9599712
Vinken M, De Rop E, Decrock E, De Vuyst E, Leybaert L, Vanhaecke T, Rogiers V. 2009 a. Epigenetic regulation of gap junctional intercellular communication: More than a way to keep cells quiet? Biochim Biophys Acta. 1795(1):53-61. 10.1016/j.bbcan.2008.08.002 18801412
Vinken M, Doktorova T, Decrock E, Leybaert L, Vanhaecke T, Rogiers V. 2009 b. Gap junctional intercellular communication as a target for liver toxicity and carcinogenicity hepatic connexin channels and homeostatic imbalance. Crit Rev Biochem Mol Biol. 44(4):201–222. 10.1080/10409230903061215 19635038
Vogel E, Chandler JL. 1974. Mutagenicity testing of cyclamate and some pesticides in Drosophila melanogaster. Experientia. 30(6):621–623. 10.1007/BF01921506 4209504
Waidyanatha S, Lin PH, Rappaport SM. 1996. Characterization of chlorinated adducts of hemoglobin and albumin following administration of pentachlorophenol to rats. Chem Res Toxicol. 9(3):647–653. 10.1021/tx950172n 8728511
Waidyanatha S, McDonald TA, Lin PH, Rappaport SM. 1994. Measurement of hemoglobin and albumin adducts of tetrachlorobenzoquinone. Chem Res Toxicol. 7(3):463–468. 10.1021/tx00039a027 8075381
Waite DT, Gurprasad NP, Cessna AJ, Quiring DV. 1998. Atmospheric pentachlorophenol concentrations in relation to air temperature at five Canadian locations. Chemosphere. 37(9-12):2251–2260. 10.1016/S0045-6535(98)00287-2 9828341
Wang YJ, Ho YS, Chu SW, Lien HJ, Liu TH, Lin JK. 1997. Induction of glutathione depletion, p53 protein accumulation and cellular transformation by tetrachlorohydroquinone, a toxic metabolite of pentachlorophenol. Chem Biol Interact. 105(1):1–16. 10.1016/S0009-2797(97)00023-9 9233372
Wang YJ, Ho YS, Jeng JH, Su HJ, Lee CC. 2000. Different cell death mechanisms and gene expression in human cells induced by pentachlorophenol and its major metabolite, tetrachlorohydroquinone. Chem Biol Interact. 128(3):173–188. 10.1016/S0009-2797(00)00194-0 11064002
Wang YJ, Lin JK. 1995. Estimation of selected phenols in drinking water with in situ acetylation and study on the DNA damaging properties of polychlorinated phenols. Arch Environ Contam Toxicol. 28(4):537–542. 10.1007/BF00211639 7755407
Ward MH, Colt JS, Metayer C, Gunier RB, Lubin J, Crouse V, Nishioka MG, Reynolds P, Buffler PA. 2009. Residential exposure to polychlorinated biphenyls and organochlorine pesticides and risk of childhood leukemia. Environ Health Perspect. 117(6):1007–1013. 10.1289/ehp.0900583 19590698
Waters MD, Sandhu SS, Simmon VF, Mortelmans KE, Mitchell AD, Jorgenson TA, Jones DC, Valencia R, Garrett NE. 1982. Study of pesticide genotoxicity. Basic Life Sci. 21:275–326. 7150196
Wegman RC, Hofstee AWM. 1979. Chlorophenols in surface waters of the Netherlands (1976–1977). Water Res. 13(7):651–657. 10.1016/0043-1354(79)90015-0
Wester RC, Maibach HI, Sedik L, Melendres J, Wade M, DiZio S. 1993. Percutaneous absorption of pentachlorophenol from soil. Fundam Appl Toxicol. 20(1):68–71. 10.1006/faat.1993.1008 8432428
White KL Jr, Anderson AC. 1985. Suppression of mouse complement activity by contaminants of technical grade pentachlorophenol. Agents Actions. 16(5):385–392. 10.1007/BF01982877 4050617
Wild SR, Harrad SJ, Jones KC. 1992. Pentachlorophenol in the UK environment. I. A budget and source inventory. Chemosphere. 24(7):833–845. 10.1016/0045-6535(92)90003-A
Wild SR, Jones KC. 1992. Pentachlorophenol in the UK environment. II. Human exposure and an assessment of pathways. Chemosphere. 24(7):847–855. 10.1016/0045-6535(92)90004-B
Williams PL. 1982. Pentachlorophenol, an assessment of the occupational hazard. Am Ind Hyg Assoc J. 43(11):799–810. 10.1080/15298668291410602 6762824
Wilson NK, Chuang JC, Lyu C, Menton R, Morgan MK. 2003. Aggregate exposures of nine preschool children to persistent organic pollutants at day care and at home. J Expo Anal Environ Epidemiol. 13(3):187–202. 10.1038/sj.jea.7500270 12743613
Wilson NK, Chuang JC, Morgan MK, Lordo RA, Sheldon LS. 2007. An observational study of the potential exposures of preschool children to pentachlorophenol, bisphenol-A, and nonylphenol at home and daycare. Environ Res. 103(1):9–20. 10.1016/j.envres.2006.04.006 16750524
Wilson NK, Strauss WJ, Iroz-Elardo N, Chuang JC. 2010. Exposures of preschool children to chlorpyrifos, diazinon, pentachlorophenol, and 2,4-dichlorophenoxyacetic acid over 3 years from 2003 to 2005: A longitudinal model. J Expo Sci Environ Epidemiol. 20(6):546–558. 10.1038/jes.2009.45 19724304
Wilson RD, Ziprin RL, Clark DE, Elissalde MH. 1982. Absorption of pentachlorophenol by the ovine lymphatic system: A technical note. Vet Hum Toxicol. 24(1):12–14. 7058624
Wispriyono B, Matsuoka M, Igisu H. 2002. Effects of pentachlorophenol and tetrachlorohydroquinone on mitogen-activated protein kinase pathways in Jurkat T cells. Environ Health Perspect. 110(2):139–143. 10.1289/ehp.02110139 11836141
Witte I, Juhl U, Butte W. 1985. DNA-damaging properties and cytotoxicity in human fibroblasts of tetrachlorohydroquinone, a pentachlorophenol metabolite. Mutat Res. 145(1-2):71–75. 10.1016/0167-8817(85)90042-2 3974605
Wong AS, Crosby DG. 1978. Photolysis of pentachlorophenol in water. In: Rao KR, editor. Pentachlorophenol: Chemistry, Pharmacology and Environmental Toxicology. New York, NY: Plenum Press. p. 19–25.
Wong AS, Crosby DG. 1981. Photodecomposition of pentachlorophenol in water. J Agric Food Chem. 29(1):125–130. 10.1021/jf00103a032
Wood S, Rom WN, White GL Jr, Logan DC. 1983. Pentachlorophenol poisoning. J Occup Med. 25(7):527–530. 6886856
Woods JS, Polissar L, Severson RK, Heuser LS, Kulander BG. 1987. Soft tissue sarcoma and non-Hodgkin’s lymphoma in relation to phenoxyherbicide and chlorinated phenol exposure in western Washington. J Natl Cancer Inst. 78(5):899–910. 3471999
World Health Organization (WHO). 1987. Environmental health criteria 71. Pentachlorophenol. Geneva, Switzerland: World Health Organization. http://www.inchem.org/documents/ehc/ehc/ehc71.htm. [Accessed: August 31, 2011]
World Health Organization (WHO). 2004. Concise international chemical assessment document 60: Chlorobenzenes other than hexachlorobenzene - environmental aspects. Geneva, Switzerland: World Health Organization.
Wyllie JA, Gabica J, Benson WW, Yoder J. 1975. Exposure and contamination of the air and employees of a pentachlorophenol plant, Idaho—1972. Pestic Monit J. 9(3):150–153. 1241126
Xu J. 1996. In vivo test for chemical induction of micronucleated polychromatic erythrocytes in mouse bone marrow cells. Study conducted by SITEK Research Laboratories, Rockville, MD for the Pentachlorophenol Task Force c/o SRA International, Inc., Washington, DC. Submitted to the U.S. Environmental Protection Agency, Washington, DC. MRID 43911301. Unpublished report.
Yin D, Gu Y, Li Y, Wang X, Zhao Q. 2006. Pentachlorophenol treatment in vivo elevates point mutation rate in zebrafish p53 gene. Mutat Res. 609(1):92–101. 10.1016/j.mrgentox.2006.06.025 16904934
Yin R, Zhang D, Song Y, Zhu BZ, Wang H. 2013. Potent DNA damage by polyhalogenated quinones and H(2)O(2) via a metal-independent and Intercalation-enhanced oxidation mechanism. Sci Rep. 3:1269. 10.1038/srep01269 23429247
Young RHF, Lau LS, Konno SK, Lee HH. 1976. Water quality monitoring: Kaneohe Bay and selected watersheds, July to December 1975. Honolulu, HI: Water Resources Research Center, University of Hawaii. Technical Report No. 98.
Yuan JH, Goehl TJ, Murrill E, Moore R, Clark J, Hong HL, Irwin RD. 1994. Toxicokinetics of pentachlorophenol in the F344 rat. Gavage and dosed feed studies. Xenobiotica. 24(6):553–560. 10.3109/00498259409043258 7975721
Zheng R, Zhang Q, Zhang Q, Yang L, Zhang Z, Huang F. 2015. Occupational exposure to pentachlorophenol causing lymphoma and hematopoietic malignancy for two generations. Toxicol Ind Health. 31(4):328–342. 10.1177/0748233712472520 23315091
Zheng RZ, Zhang QH, He YX, Zhang Q, Yang LS, Zhang ZH, Zhang XJ, Hu JT, Huang F. 2013. Historical long-term exposure to pentachlorophenol causing risk of cancer - a community study. Asian Pac J Cancer Prev. 14(2):811–816. 10.7314/APJCP.2013.14.2.811 23621243
Zheng W, Wang X, Yu H, Tao X, Zhou Y, Qu W. 2011. Global trends and diversity in pentachlorophenol levels in the environment and in humans: A meta-analysis. Environ Sci Technol. 45(11):4668–4675. 10.1021/es1043563 21528888
Zheng W, Yu H, Wang X, Qu W. 2012. Systematic review of pentachlorophenol occurrence in the environment and in humans in China: Not a negligible health risk due to the re-emergence of schistosomiasis. Environ Int. 42:105–116. 10.1016/j.envint.2011.04.014 21601283
Zhu BZ, Fan RM, Qu N. 2011 a. A novel mechanism for metal-independent hydroxyl radical production by hydrogen peroxide and halogenated quinones. Mini Rev Org Chem. 8(4):434–437. 10.2174/157019311797440290
Zhu BZ, Kitrossky N, Chevion M. 2000. Evidence for production of hydroxyl radicals by pentachlorophenol metabolites and hydrogen peroxide: A metal-independent organic Fenton reaction. Biochem Biophys Res Commun. 270(3):942–946. 10.1006/bbrc.2000.2539 10772930
Zhu BZ, Shan GQ. 2009. Potential mechanism for pentachlorophenol-induced carcinogenicity: A novel mechanism for metal-independent production of hydroxyl radicals. Chem Res Toxicol. 22(6):969–977. 10.1021/tx900030v 19408893
Zhu BZ, Zhu JG, Fan RM, Mao L. 2011 b. Metal-independent pathways of chlorinated phenol/quinone toxicity. Adv Mol Toxicol. 5:1-43. 10.1016/B978-0-444-53864-2.00001-3
Ziegler JL, Beckstead JA, Volberding PA, Abrams DI, Levine AM, Lukes RJ, Gill PS, Burkes RL, Meyer PR, Metroka CE, et al. 1984. Non-Hodgkin’s lymphoma in 90 homosexual men. Relation to generalized lymphadenopathy and the acquired immunodeficiency syndrome. N Engl J Med. 311(9):565–570. 10.1056/NEJM198408303110904 6611504
Ziemsen B, Angerer J, Lehnert G. 1987. Sister chromatid exchange and chromosomal breakage in pentachlorophenol (PCP) exposed workers. Int Arch Occup Environ Health. 59(4):413–417. 10.1007/BF00405285 3610341
Zimmerli B, Marschall T, Marek B. 1979. [Preliminary studies on occurrence of pentachlorophenol in human urine]. Mitt Geb Lebensmittelunters Hyg. 70:443–450.