# Glossary

Ames assay: The Ames Salmonella/microsome mutagenicity assay is a short-term bacterial reverse mutation assay specifically designed to detect a wide range of chemical substances that can produce genetic damage that leads to gene mutations.
Biexponential process: A process of drug (or xenobiotic) clearance with two phases with different rates. The first phase often involves rapid distribution of a drug to peripheral tissues, while the second phase represents clearance mechanisms that eliminate the drug from the body. (See “Two-compartment pharmacokinetic model.”)
Biodegradation: Biotransformation; the conversion within an organism of molecules from one form to another. A change often associated with change in pharmacologic activity.
Boiling point: The boiling point of the anhydrous substance at atmospheric pressure (101.3 kPa) unless a different pressure is stated. If the substance decomposes below or at the boiling point, this is noted (dec). The temperature is rounded off to the nearest °C.
Cochran-Armitage trend test: A statistical test used in categorical data analysis when the aim is to assess for the presence of an association between a variable with two categories and a variable with k categories. It modifies the chi-square test to incorporate a suspected ordering in the effects of the k categories of the second variable.
Comet assay: Single cell gel electrophoresis for assessment of DNA damage in presumptive target tissues.
Connexin proteins: A group of transmembrane proteins that form the intermembrane channels of gap junctions. They are used by inorganic ions and most small organic molecules to pass through cell interiors.
Critical temperature: The temperature at and above which a gas cannot be liquefied, no matter how much pressure is applied.
Differential selection: Selective pressure for self-renewal. Gene mutations that confer a growth or survival advantage on the cells that express them will be selectively enriched in the genome of tumors.
Dioxin congeners: Members of the same family of chemicals (i.e., polychlorinated dibenzo-p-dioxins) with different configurations. Dioxin congeners differ in terms of the number, position, and combination of chlorine atoms on the molecule.
Disposition: The description of absorption, distribution, metabolism, and excretion of a chemical in the body.
Dowicide EC-7: A technical-grade formulation of pentachlorophenol.
Ecological study: A study in which the units of analysis are populations or groups of people rather than individuals.
Epigenetic mechanisms: Changes in gene function that do not involve a change in DNA sequence but are nevertheless mitotically and/or meiotically heritable. Examples include DNA methylation, alternative splicing of gene transcripts, and assembly of immunoglobulin genes in cells of the immune system.
Fisher’s exact test: The test for association in a two-by-two table that is based on the exact hypergeometric distribution of the frequencies within the table.
Follow-up: Observation over a period of time of a person, group, or initially defined population whose appropriate characteristics have been assessed to observe changes in health status or health-related variables.
Freund’s adjuvant: A water-in-oil emulsion injected with immunogen (Freund's incomplete adjuvant) or with immunogen and killed mycobacteria (Freund's complete adjuvant) to enhance the immune response to the immunogen.
Genomic instability: An increased propensity for genomic alterations that often occurs in cancer cells. During the process of cell division (mitosis) the inaccurate duplication of the genome in parent cells or the improper distribution of genomic material between daughter cells can result from genomic instability.
Glioma: A cancer of the brain that begins in glial cells (cells that surround and support nerve cells).
Hairy-cell leukemia: A rare type of leukemia in which abnormal B-lymphocytes (a type of white blood cell) are present in the bone marrow, spleen, and peripheral blood. When viewed under a microscope, these cells appear to be covered with tiny hair-like projections.
Hemangiosarcoma: A type of cancer that begins in the cells that line blood vessels.
Henry’s Law constant: The ratio of the aqueous-phase concentration of a chemical to its equilibrium partial pressure in the gas phase. The larger the Henry’s law constant the less soluble it is (i.e., greater tendency for vapor phase). The relationship is defined for a constant temperature, e.g., 25°C.
Hepatoma: A liver tumor.
Loss of heterozygosity: If there is one normal and one abnormal allele at a particular locus, as might be seen in an inherited autosomal dominant cancer susceptibility disorder, loss of the normal allele produces a locus with no normal function. When the loss of heterozygosity involves the normal allele, it creates a cell that is more likely to show malignant growth if the altered gene is a tumor suppressor gene.
Melting point: The melting point of the substance at atmospheric pressure (101.3 kPa). When there is a significant difference between the melting point and the freezing point, a range is given. In case of hydrated substances (i.e., those with crystal water), the apparent melting point is given. If the substance decomposes at or below its melting point, this is noted (dec). The temperature is rounded off to the nearest °C.
Metabolic activation: The chemical alteration of an exogenous substance by or in a biological system. The alteration may inactivate the compound, or it may result in the production of an active metabolite of an inactive parent compound.
Micronuclei: Small nuclei separate from, and additional to, the main nucleus of a cell, produced during the telophase of mitosis or meiosis by lagging chromosomes or chromosome fragments derived from spontaneous or experimentally induced chromosomal structural changes.
Miscible: A physical characteristic of a liquid that forms one liquid phase with another liquid (e.g., water) when they are mixed in any proportion.
Molecular weight: The molecular weight of a substance is the weight in atomic mass units of all the atoms in a given formula. The value is rounded to the nearest tenth.
Multiple myeloma: A type of cancer that begins in plasma cells (white blood cells that produce antibodies). Also called Kahler disease, myelomatosis, and plasma cell myeloma.
Mutations: A change in the structure of a gene, resulting from the alteration of single base units in DNA, or the deletion, insertion, or rearrangement of larger sections of genes or chromosomes. The genetic variant can be transmitted to subsequent generations.
Nasal conchae: The three thin bony plates on the lateral wall of the nasal cavity.
National Health and Nutrition Examination Survey: A program of studies designed to assess the health and nutritional status of adults and children in the United States. The survey is unique in that it combines interviews and physical examinations.
National Priorities List: The list of national priorities among the known releases or threatened releases of hazardous substances, pollutants, or contaminants throughout the United States and its territories. The National Priorities List is intended primarily to guide the U.S. Environmental Protection Agency in determining which sites warrant further investigation.
NIOSH Dioxin Registry: A compilation of demographic and work history information for all U.S. production workers who have synthesized products known to be contaminated with polychlorinated dibenzo-p-dioxins, and in particular the isomers 2,3,7,8-tetrachlorodibenzo-p-dioxin (TCDD) or hexachlorodibenzo-p-dioxins (HxCDD).
Non-Hodgkin lymphoma: A heterogeneous group of malignant lymphomas; the only common feature being an absence of the giant Reed-Sternberg cells characteristic of Hodgkin disease.
Normochromatic erythrocyte: A mature erythrocyte that lacks ribosomes and can be distinguished from immature, polychromatic erythrocytes by stains selective for RNA.
Nrf2: A protein that controls how certain genes are expressed. These genes help protect the cell from damage caused by free radicals (unstable molecules made during normal cell metabolism). Also called NFE2L2 and nuclear factor (erythroid-derived 2)-like 2.
One-compartment model: A pharmacokinetic modeling approach that models the entire body as a single compartment into which a drug is added by a rapid single dose, or bolus. It is assumed that the drug concentration is uniform in the body compartment at all times and is eliminated by a first order process that is described by a first order rate constant.
Osmotic mini pump: A miniature implantable infusion pump that is used to continuously infuse laboratory animals with a drug or other material. Absorption of water from surrounding tissues by osmosis through an outer rigid shell provides the means by which the material is forced out of a collapsible internal chamber at a constant rate.
Papilloma: A small solid benign tumor with a clear-cut border that projects above the surrounding tissue.
Pericardial fat: A type of fat that surrounds the heart.
Phenoxy herbicide: A category of systemic weed killers that have a chemical structure composed of six carbon atoms joined together in a ring formation. Two examples are 2,4-D (2,4-dichlorophenoxyacetic acid) and mecoprop (MCPP).
Plate incorporation: A commonly used procedure for performing a bacterial reverse mutation test. Suspensions of bacterial cells are exposed to the test substance in the presence and in the absence of an exogenous metabolic activation system. In the plate-incorporation method, these suspensions are mixed with an overlay agar and plated immediately onto minimal medium. After two or three days of incubation, revertant colonies are counted and compared with the number of spontaneous revertant colonies on solvent control plates.
Poly-3 trend test: A survival-adjusted statistical test that takes survival differences into account by modifying the denominator in the numerical (quantal) estimate of lesion incidence to reflect more closely the total number of animal years at risk.
Polychromatic erythrocyte: A newly formed erythrocyte (reticulocyte) containing RNA.
Prills: Hailstone-like pellets of pentachlorophenol.
Prophage lambda (λ): A virus in Escherichia coli (E. coli) bacteria that has integrated itself into the host E. coli DNA.
Pyrolysis: The chemical and physical decomposition of organic material that occurs at high temperatures in the absence of oxygen.
QUOSA: A collection of scientific literature management software and services for researchers and information professionals in the life sciences and related scientific and medical areas designed to retrieve, organize, and analyze full-text articles and documents.
Schistosomiasis: A chronic, parasitic disease caused by blood flukes (trematode worms) of the genus Schistosoma.
Sister-chromatid exchange: The exchange during mitosis of homologous genetic material between sister chromatids; increased as a result of inordinate chromosomal fragility due to genetic or environmental factors.
Soft tissue sarcoma: A cancer that begins in the muscle, fat, fibrous tissue, blood vessels, or other supporting tissue of the body.
Solubility: The ability of a substance to dissolve in another substance and form a solution. The Report on Carcinogens uses the following definitions (and concentration ranges) for degrees of solubility: (1) miscible (see definition), (2) freely soluble- capable of being dissolved in a specified solvent to a high degree (>1,000 g/L), (3) soluble- capable of being dissolved in a specified solvent (10–1,000 g/L), (4) slightly soluble- capable of being dissolved in a specified solvent to a limited degree (1–10 g/L), and (5) practically insoluble- incapable of dissolving to any significant extent in a specified solvent (<1 g/L).
Specific gravity: The ratio of the density of a material to the density of a standard material, such as water at a specific temperature; when two temperatures are specified, the first is the temperature of the material and the second is the temperature of water.
Spot test: Qualitative assay in which a small amount of test chemical is added directly to a selective agar medium plate seeded with the test organism, e.g., Salmonella. As the chemical diffuses into the agar, a concentration gradient is formed. A mutagenic chemical will give rise to a ring of revertant colonies surrounding the area where the chemical was applied; if the chemical is toxic, a zone of growth inhibition will also be observed.
T-helper cell: A type of immune cell that stimulates killer T cells, macrophages, and B cells to make immune responses. A helper T cell is a type of white blood cell and a type of lymphocyte. Also called CD4-positive T lymphocyte.
Tg.AC: A transgenic mouse model with the ability to mount a tumorigenic response within 6 months in skin paint assays when dosed topically with nonmutagenic carcinogens.
Time-weighted average: The average exposure concentration of a chemical measured over a period of time (not an instantaneous concentration).
Toxic equivalents: A method used to report the toxicity-weighted masses of mixtures of dioxins; the sum of the products of the concentration of each compound multiplied by its toxic equivalency factor (TEF) value, which represents an estimate of the total 2,3,7,8-TCDD-like activity of the mixture.
Toxicokinetics: The mathematical description (toxicokinetic models) of the time course of disposition of a chemical in the body.
TOXMAP: A Geographic Information System from the National Library of Medicine that uses maps of the United States to help users visually explore data from EPA’s TRI and Superfund programs.
Transitions: DNA nucleotide substitution mutation in which a purine base is substituted for another purine base (adenine → guanine or guanine → adenine) or a pyrimidine base for another pyrimidine base (cytosine → thymine or thymine → cytosine).
Transversions: DNA nucleotide substitution mutation in which a purine base (adenine or guanine) is substituted for a pyrimidine base (cytosine or thymine) or vice versa.
Tunica vaginalis: The serous membranous covering of the testis.
Two-compartment pharmacokinetic model: A two-compartment pharmacokinetic model resolves the body into a central compartment and a peripheral compartment. The central compartment generally comprises tissues that are highly perfused such as heart, lungs, kidneys, liver, and brain. The peripheral compartment comprises less well-perfused tissues such as muscle, fat, and skin. A two-compartment model assumes that, following drug administration into the central compartment, the drug distributes between that compartment and the peripheral compartment. However, the drug does not achieve instantaneous distribution (i.e., equilibrium), between the two compartments. After a time interval (t), distribution equilibrium is achieved between the central and peripheral compartments, and elimination of the drug is assumed to occur from the central compartment.
Vapor density, relative: A value that indicates how many times a gas (or vapor) is heavier than air at the same temperature. If the substance is a liquid or solid, the value applies only to the vapor formed from the boiling liquid.
Vapor pressure: The pressure of the vapor over a liquid (and some solids) at equilibrium, usually expressed as mm Hg at a specific temperature (°C).