# Introduction and Methods

Pentachlorophenol (PCP, CASRN 87-86-5) is a chlorinated aromatic compound whose current uses in the United States are limited to the treatment of utility poles, cross arms, wooden pilings (e.g., wharf pilings), fence posts, and lumber or timbers for construction. In the past, pentachlorophenol also was used as a biocide and was found in ropes, paints, adhesives, leather, canvas, insulation, and brick walls. Pentachlorophenol as it is used commercially is a mixture of pentachlorophenol and by-products formed or present during production. Pentachlorophenol and by-products of its synthesis (hereinafter referred to collectively as “pentachlorophenol”) includes higher chlorinated dioxins and furans, polychlorinated phenols, hexachlorobenzene and other by-products. People exposed to pentachlorophenol are also exposed to its by-products, thus, the listing is for this complex mixture. Pentachlorophenol has been selected as a candidate substance for review for possible listing in the RoC based on current or past U.S. exposure and an adequate database of cancer studies in both animals and humans.

## Monograph Contents

This RoC monograph on pentachlorophenol (PCP) reviewed the relevant scientific information and assesses its quality, applied the RoC listing criteria to the scientific information, and recommends an RoC listing status for pentachlorophenol. The PCP monograph provides information on the following topics: human exposure and chemical properties (Section 1), disposition and toxicokinetics (Section 2), cancer studies in humans (Section 3), cancer studies in experimental animals (Section 4), and mechanistic data and other related effects (Section 5), including studies of relevant toxicological effects, genetic toxicology, and potential mechanisms of carcinogenicity. The information in Section 6 is a synthesis of Sections 2 through 5.

The information reviewed in Sections 2 through 5 must come from publicly available, peer-reviewed sources. Information in Section 1, including chemical and physical properties, analytical methods, production, use, occurrence, and exposure, may come from publicly available, peer-reviewed or non-peer-reviewed sources.

The cancer evaluation for PCP focuses on the evaluation of the human cancer studies, animal tumor studies, and mechanistic data.

## Process for Conducting the Cancer Evaluation

The process for conducting the cancer evaluation included approaches for obtaining public and scientific input and using systematic methods (e.g., standardized methods for identifying the literature (see Appendix A), inclusion/exclusion criteria, extraction of data and evaluation of study quality using specific guidelines, and assessment of the level of evidence for carcinogenicity using established criteria).

The Office of the Report on Carcinogens (ORoC) followed the approaches outlined in the concept document, which discusses the scientific issues and questions relevant to the evaluation of PCP carcinogenicity, the scope and focus of the evaluation and the approaches to obtain scientific and public input to address the key scientific questions and issues . The ORoC presented the draft concept document for pentachlorophenol to the NTP Board of Scientific Counselors (BSC) at the June 21–22, 2012 meeting that provided opportunity for written and oral public comments and is available on the RoC website (https://ntp.niehs.nih.gov/go/37897), after which the concept was finalized and pentachlorophenol was approved by the NTP Director as a candidate substance for review.

### Key Scientific Questions and Issues Relevant for the Cancer Evaluation

The key scientific issues concern the evaluation of cancer studies in humans and experimental animals, and mechanistic data. They are as follows:

- What is the level of evidence (sufficient, limited, or inadequate) for the carcinogenicity of PCP from studies in humans? What are the tissue sites?
  - What are the major potential confounders for evaluating PCP risk in these studies?
  - Can an association between any cancer site and exposure to PCP be explained by exposure to these co-exposures or other risk factors for cancer?
- What is the level of evidence (sufficient or not sufficient) for the carcinogenicity of PCP from studies in experimental animals? What are the tissue sites? What are the tumor sites that contribute to the sufficient evidence in experimental animals?
- What are the potential mechanisms by which PCP may cause cancer?
- Is there evidence that these mechanisms occur in humans? If so, what is the level of the evidence (strong, moderate, or weak)?

### Approach for Obtaining Scientific and Public Input

Additional scientific input was obtained for exposure, human cancer studies, and disposition and toxicokinetics of PCP Technical advisors are identified on the “About This Report” page.

One of the key issues identified in the concept document concerns differentiating effects of pentachlorophenol from its contaminants in the cancer studies in both humans and experimental animals. In order to receive public and scientific input on this matter, the ORoC held a webinar titled, “Human cancer studies on exposure to pentachlorophenol (PCP): Differentiating potential cancer effects of PCP exposure from effects due to occupational co-exposures or PCP contaminants” on April 11, 2013. The ORoC also convened an information group consisting of several scientists within and outside of NTP with substance-specific expertise to independently review the experimental animal data. Based on this input, NTP has defined the candidate substance as “pentachlorophenol and by-products of its synthesis.”

Public comments on scientific issues were requested at several times prior to the development of the draft RoC monograph, including the request for information on the nomination, and the request for comment on the draft concept document, which outlined the rationale and approach for conducting the scientific review. In addition, NTP posted its protocol for reviewing the human cancer studies and studies in experimental animals for public input on the ORoC webpage for pentachlorophenol (available at https://ntp.niehs.nih.gov/go/37897) prior to the release of the draft monograph. Five public comments on PCP were received from the public as of the date on this document.

### Methods for Writing the Monograph

The procedures by which relevant literature was identified, data were systematically extracted and summarized, and the draft monograph was written, together with the processes for scientific review, quality assurance, and assessment and synthesis of data, are described below.

The preparation of the RoC monograph on pentachlorophenol began with development of a literature search strategy to obtain information relevant to the topics listed above for Sections 1 through 5 using search terms developed in collaboration with a reference librarian (see Appendix A) for a detailed description of the literature search strategy). The citations (N = 4,332) identified from these searches were uploaded to a web-based systematic review software for evaluation by two separate reviewers using inclusion/exclusion criteria, and 413 references were selected for final inclusion in the draft monograph using these criteria. Studies identified from the literature searches but excluded from the review include publications on chemicals other than pentachlorophenol (or relevant structurally related compounds such as pentachlorophenol metabolites and analogues or by-products of synthesis of pentachlorophenol), and studies involving exposure to pentachlorophenol that reported results for topics not covered in this monograph (see ‘Monograph contents’).

Information for the exposure, relevant cancer, and mechanistic sections was systematically extracted in tabular format and/or summarized in the text, following specific procedures developed by ORoC, from studies selected for inclusion in the monograph. All sections of the monograph underwent scientific review and quality assurance (QA) (i.e., assuring that all the relevant data and factual information extracted from the publications have been reported accurately) by a separate reviewer. Any discrepancies between the writer and the reviewer were resolved by mutual discussion in reference to the original data source.

Strengths, weaknesses, and study quality of the cancer studies for PCP in humans (see Appendix C) or experimental animals (see Appendix D) were assessed based on a series of a priori questions. For the cancer studies in humans and experimental animals, these questions and the guidelines for answering the questions were available in the protocols (available at https://ntp.niehs.nih.gov/go/37897). Relevant genotoxicity and mechanistic studies were also assessed for their strengths and weaknesses.

Human exposure information was assessed to determine whether the evidence indicates that a significant number of persons residing in the United States are exposed to PCP (see Foreword for information regarding the congressional mandate for the RoC). However, for many substances, this information is not available, and typically, U.S. exposure can be inferred from data on use, production volume, occupational monitoring, environmental occurrence, estimated daily intake, and biomonitoring. Because cancer has a long latency period, past exposure is also considered in the assessment.

RoC listing criteria (see text box) were applied to the available database of carcinogenicity data to assess the level of evidence (sufficient, limited, or inadequate) for the carcinogenicity of PCP from studies in humans and the level of evidence (sufficient, not sufficient) from studies in experimental animals. The approach for synthesizing the evidence across studies and reaching a level of evidence conclusion was outlined in the protocol. The initial conclusions do not integrate the conclusions from the human cancer studies, or experimental animal cancer studies with the mechanistic data. The evaluation of the mechanistic data included a complete discussion and assessment of the strength of evidence for potential modes of action for PCP -induced neoplasia, including metabolic activation, cytotoxicity, genetic-related effects, and epigenetic effects. The RoC listing criteria were then applied to the body of knowledge (cancer studies in humans and experimental animals and mechanistic data) for PCP .

RoC Listing Criteria

##### Known to Be Human Carcinogen:

There is sufficient evidence of carcinogenicity from studies in humans*, which indicates a causal relationship between exposure to the agent, substance, or mixture, and human cancer.

##### Reasonably Anticipated to Be Human Carcinogen:

There is limited evidence of carcinogenicity from studies in humans*, which indicates that causal interpretation is credible, but that alternative explanations, such as chance, bias, or confounding factors, could not adequately be excluded, OR

there is sufficient evidence of carcinogenicity from studies in experimental animals, which indicates there is an increased incidence of malignant and/or a combination of malignant and benign tumors (1) in multiple species or at multiple tissue sites, or (2) by multiple routes of exposure, or (3) to an unusual degree with regard to incidence, site, or type of tumor, or age at onset, OR

there is less than sufficient evidence of carcinogenicity in humans or laboratory animals; however, the agent, substance, or mixture belongs to a well-defined, structurally related class of substances whose members are listed in a previous Report on Carcinogens as either known to be a human carcinogen or reasonably anticipated to be a human carcinogen, or there is convincing relevant information that the agent acts through mechanisms indicating it would likely cause cancer in humans.

Conclusions regarding carcinogenicity in humans or experimental animals are based on scientific judgment, with consideration given to all relevant information. Relevant information includes, but is not limited to, dose response, route of exposure, chemical structure, metabolism, pharmacokinetics, sensitive sub-populations, genetic effects, or other data relating to mechanism of action or factors that may be unique to a given substance. For example, there may be substances for which there is evidence of carcinogenicity in laboratory animals, but there are compelling data indicating that the agent acts through mechanisms which do not operate in humans and would therefore not reasonably be anticipated to cause cancer in humans.

*This evidence can include traditional cancer epidemiology studies, data from clinical studies, and/or data derived from the study of tissues or cells from humans exposed to the substance in question that can be useful for evaluating whether a relevant cancer mechanism is operating in people.