# Appendix F Mechanistic Data for By-products of Pentachlorophenol Production

Table F-1 Results of Analyses for By-products in Pentachlorophenol^a^

| Mice (TR 349 NTP (1989)) | | Rats (TR 483 NTP (1999))
Impurity^b^ | Technical Grade | Dowicide EC-7 | Pure
Dichlorophenol^c^ | – | – | NR
Trichlorophenol (TCP)^c^ | 0.01% | 0.007% | NR
Tetrachlorophenol^c^ | 3.8% | 9.4% | NR
Hexachlorobenzene (HCB) | 50 ppm | 65 ppm | 113.3 ppm
Tetrachlorodibenzodioxin (TCDD) | – | <0.04 ppm | –
Hexachlorodibenzodioxin (HxCDD) | 10.1 ppm | 0.19 ppm | –
Heptachlorodibenzodioxin (HpCDD) | 296 ppm | 0.53 ppm | 0.03 ppm
Octachlorodibenzodioxin (OCDD) | 1,386 ppm | 0.69 ppm | ≥0.32 ppm
Pentachlorodibenzofuran (PeCDF) | 1.4 ppm | – | –
Hexachlorodibenzofuran (HxCDF) | 9.9 ppm | 0.13 ppm | –
Heptachlorodibenzofuran (HoCDF) | 88 ppm | 0.15 ppm | –
Octachlorodibenzofuran (OCDF) | 43 ppm | – | ≥0.10 ppm
Heptachlorohydroxydiphenyl ether | 0.11% | – | NR
Octachlorohydroxydiphenyl ether | 1.91% | – | NR
Nonachlorohydroxydiphenyl ether | 3.56% | – | NR
Hexachlorohydroxydibenzofuran | 0.16% | – | NR
Heptachlorohydroxydibenzofuran | 0.47% | – | NR
Pentachlorodibenzodioxin (PeCDD) | NR | NR | –
Tetrachlorodibenzofuran (TCDF) | NR | NR | –
Pentachlorobenzene (PCB) | NR | NR | 17.0 ppm
Not quantitated | – | – | –

Sources: NTP (1989)- TR 349, NTP (1999)- TR 483.

NR = not reported; – = below detection limit.

^a^ McConnell et al. (1991) reported impurities similar to those shown above for technical grade and Dowicide EC-7 in NTP-TR 349 (NTP 1989).

^b^ This analysis is on the obtained chemicals and not on the food preparations.

^c^ Also metabolite of PCP.

Table F-2 Comparison of Liver Neoplasm Percent Incidences in 2,4,6-Trichlorophenol (2,4,6-TCP) NCI (1979) Studies in Male B6C3F_1_ Mice

2,4,6-TCP (in Feed for 105 Weeks)
Dose, ppm | Incidence of Liver Tumors (%)
Dose, ppm | Adenoma | Carcinoma | Combined
vehicle control | 3/20 (15) | 1/20 (5) | 4/20 (20)
5,000 | 22/49 (45)^a^* | 10/49 (20) | 32/49 (65)***
10,000 | 32/47 (68)^a^*** | 7/47 (15) | 39/47 (83)***
Trend | N.R. | N.S. | p < 0.001

* p ≤ 0.05; ***p ≤ 0.001.

N.R. = not reported; N.S. = not significant.

^a^ P value calculated by Fisher’s exact test by RoC Group.

Table F-3 Comparison of Liver Neoplasm Percent Incidences in Hexachlorobenzene (HCB) Cabral et al. (1979) Studies in Male Swiss Mice

HCB (in Feed for 101–120 Weeks)
Dose, ppm | Incidence of Liver-Cell Tumors^a^ (%)
vehicle control | 0/47 (0)
50 | 0/30 (0)
100 | 3/29 (10)
200 | 7/44 (16)**
300^b^ | 1/16 (6)
Trend | p = 0.0053

** p ≤ 0.01.

^a^ Effective number of mice based on number of survivors at moment of appearance of first tumor (of any type) in each group.

^b^ Mice exposed to 300 ppm for 15 weeks only.

^c^ P values calculated by Fisher’s exact test by RoC Group and trend by the Cochran-Armitage trend test by NTP.

Table F-4 Comparison of Liver Neoplasm Percent Incidences in Hexachloro-p-dibenzodioxin^a^ (HCDD) NTP (1980a) Studies in Male B6C3F_1_ Mice

HCDD (Gavage 2× per Week for 104 Weeks)
Dose, μg/kg/wk | Incidence of Liver Tumors (%)
Dose, μg/kg/wk | Adenoma | Carcinoma | Combined
vehicle control | 7/73 (10) | 8/73 (11) | 15/73 (21)
1.25 | 5/50 (10) | 9/50 (18) | 14/50 (28)
2.5 | 9/49 (18) | 5/49 (10) | 14/49 (29)
5.0 | 15/48 (31)** | 9/48 (19) | 24/48 (50)***
Trend | p = 0.001 | N.S. | p = 0.001

** p ≤ 0.01; ***p ≤ 0.001.

^a^ Mixture of 1,2,3,7,8,9- and 1,2,3,6,7,8-HxCDD.

Table F-5 Comparison of Liver Neoplasm Incidences in Male B6C3F_1_ Mice in the Hexachlorodibenzo-p-dioxin Studies (NTP 1980b) and in the Pentachlorophenol Studies (NTP 1989)

HxCDD (Gavage) | | Technical Grade PCP (Feed)^a^ | | | Dowicide EC-7 (Feed)^b^
Dose of HxCDD (μg/kg/wk) | Percent Incidence of Liver Tumors | Technical-grade PCP ppm | Dose of HxCDD (μg/kg/wk) | Percent Incidence of Liver Tumors | EC-7 ppm | Dose of HxCDD (μg/kg/wk) | Percent Incidence of Liver Tumors
0.0 | 21 | 0 | 0 | 22 | 0 | 0.000 | 17
1.25 | 28 | 100 | 0.77 | 55 | 100 | 0.014 | 40
2.50 | 29 | 200 | 1.54 | 77 | 200 | 0.028 | 44
5.00 | 50 | – | – | – | 600 | 0.070 | 69

^a^ 35 mg PCP/kg bw/d in feed; based on high dose of 200 ppm.

^b^ 118 mg PCP/kg bw/d in feed based on high dose of 600 ppm.

Table F-6 TEF Values of Compounds

Compound | Formula | TEF
Tetrachlorodibenzodioxin | 2,3,7,8-TCDD | 1
Hexachlorodibenzodioxin | 1,2,3,4,7,8-HxCDD | 0.1
Hexachlorodibenzodioxin | 1,2,3,6,7,8-HxCDD | 0.1
Hexachlorodibenzodioxin | 1,2,3,7,8,9-HxCDD | 0.1
Heptachlorodibenzodioxin | 1,2,3,4,6,7,8-HpCDD | 0.01
Octachlorodibenzodioxin | OCDD | 0.0003
Pentachlorodibenzodioxin | 1,2,3,7,8-PeCDD | 1
Tetrachlorodibenzofuran | 2,3,7,8-TCDF | 0.1
Pentachlorodibenzofuran | 1,2,3,7,8-PeCDF | 0.03
Pentachlorodibenzofuran | 2,3,4,7,8-PeCDF | 0.3
Hexachlorodibenzofuran | 1,2,3,4,7,8-HxCDF | 0.1
Hexachlorodibenzofuran | 1,2,3,6,7,8-HxCDF | 0.1
Hexachlorodibenzofuran | 1,2,3,7,8,9-HxCDF | 0.1
Hexachlorodibenzofuran | 2,3,4,6,7,8-HxCDF | 0.1
Heptachlorodibenzofuran | 1,2,3,4,6,7,8-HpCDF | 0.01
Heptachlorodibenzofuran | 1,2,3,4,7,8,9-HpCDF | 0.01
Octachlorodibenzofuran | OCDF | 0.0003

Source: Van den Berg et al. (2006).

TEF = toxic equivalency factor.

Table F-7 Exposure of Male Mice to By-products with TEFs in 2-yr PCP Feed Studies^a^ (Worst Case, High Dose)

Impurity | TEF^b^ | Technical Grade (200 mg/kg Feed) | | Dowicide EC-7 (600 mg/kg Feed)
Impurity | TEF^b^ | Dose μg/kg bw/d | TEQ/kg bw/d | Dose μg/kg bw/d | TEQ/kg bw/d
Tetrachlorodibenzodioxin | 1 | – | NA | – | NA
Hexachlorodibenzodioxin | 0.1 | 0.23 | 0.023 | 0.01 | 0.001
Heptachlorodibenzodioxin | 0.01 | 6.7 | 0.067 | 0.04 | 0.0004
Octachlorodibenzodioxin | 0.0003 | 31 | 0.0093 | 0.05 | 0.000015
Pentachlorodibenzofuran | 0.3 | 0.03 | 0.009 | – | NA
Hexachlorodibenzofuran | 0.1 | 0.24 | 0.024 | 0.009 | 0.0009
Heptachlorodibenzofuran | 0.01 | 2.0 | 0.020 | 0.01 | 0.0001
Octachlorodibenzofuran | 0.0003 | 1.0 | 0.0003 | – | NA
Pentachlorodibenzodioxin | 1 | NR | NA | NR | NA
Tetrachlorodibenzofuran | 0.1 | NR | NA | NR | NA
Sum of TEQs | | – | 0.1526 μg TEQ/kg bw/d | | 0.002415 μg TEQ/kg bw/d

Source: NTP (1989)TR-349, Table 23, pp 66-67.

NA = not applicable; TEF = toxic equivalency factor; TEQ = toxic equivalent; – = below level of detection.

^a^ The dose in feed of each chemical per kg body weight per day for males and females was reported in TR 349.

^b^ From Van den Berg et al. (2006).

Table F-8 Exposure of Female Mice to By-products with TEFs in 2-yr PCP Feed Studies^a^ (Worst Case, High Dose)

Impurity | TEF^b^ | Technical Grade (200 mg/kg Feed)^c^ | | Dowicide EC-7 (600 mg/kg Feed)^d^
Impurity | TEF^b^ | Dose (μg/kg/d) | TEQ/kg bw/d | Dose (μg/kg/d) | TEQ/kg bw/d
Tetrachlorodibenzodioxin | 1 | | NA | – | NA
Hexachlorodibenzodioxin | 0.1 | 0.22 | 0.022 | 0.01 | 0.001
Heptachlorodibenzodioxin | 0.01 | 6.5 | 0.065 | 0.03 | 0.0003
Octachlorodibenzodioxin | 0.0003 | 31 | 0.0093 | 0.05 | 0.000015
Pentachlorodibenzofuran | 0.3 | 0.03 | 0.009 | – | NA
Hexachlorodibenzofuran | 0.1 | 0.22 | 0.022 | 0.008 | 0.0008
Heptachlorodibenzofuran | 0.01 | 1.9 | 0.019 | 0.01 | 0.0001
Octachlorodibenzofuran | 0.0003 | 1.0 | 0.0003 | – | NA
Pentachlorodibenzodioxin | 1 | NR | NA | NR | NA
Tetrachlorodibenzofuran | 0.1 | NR | NA | NR | NA
Sum of TEQs | | NA | 0.1466 μg/kg/d | NA | 0.00221 μg/kg/d

Source: NTP (1989)- TR-349, Table 23, pp 66-67.

NA = not applicable; NR = not reported; TEF = toxic equivalency factor; TEQ = toxic equivalent; – = below level of detection.

^a^ The dose in feed of each chemical per kg body weight per day for males and females was reported in TR 349.

^b^ From Van den Berg et al. (2006).

^c^ 35 mg PCP/kg bw/d in feed; based on high dose of 200 ppm.

^d^ 118 mg PCP/kg bw/d in feed based on high dose of 600 ppm.

Table F-9 Comparison of Liver Neoplasm Percent Incidences in PCP (NTP 1989) and in TCDD (NTP 1982) Studies in Male B6C3F_1_ Mice

Dose | TEQ^a^ μg/kg/wk | Incidence of Liver Tumors (%)
Dose | TEQ^a^ μg/kg/wk | Adenoma | Carcinoma | Combined
TCDD (gavage twice a week)
vehicle control | NA | 7/73(10) | 8/73(11) | 15/73(21)
0.01 μg/kg/wk | NA | 3/49(6) | 9/49(18) | 12/49(24)
0.05 μg/kg/wk | NA | 5/49(10) | 8/4 (16) | 13/49(27)
0.5 μg/kg/wk | NA | 10/50(20) | 17/50(34)** | 27/50(54)***
Trend | | p ≤ 0.05 | p ≤ 0.01 | p ≤ 0.001
Technical-Grade PCP (feed)^b^
0 ppm | NA | 5/32 (16) | 2/32 (6) | 7/32 (22)
100 ppm | 0.534 | 20/47 (43)** | 10/47 (21) | 26/47 (55)**
200 ppm | 1.068 | 33/48 (69)*** | 12/48(25)* | 37/48 (77)***
Trend | | p ≤ 0.001 | p ≤ 0.05 | p ≤ 0.001
Dowicide EC-7 (feed)^c^
0 ppm | NA | 5/35 (14) | 1/35 (3) | 6/35 (17)
100 ppm | 0.0028 | 13/48 (27) | 7/48 (15) | 19/48 (40)*
200 ppm | 0.0056 | 17/48 (35)* | 7/48 (15) | 21/48 (44)**
600 pm | 0.0169 | 32/49 (65)*** | 9/49 (18)* | 34/49 (69)***
Trend | | p ≤ 0.001 | | p ≤ 0.001

* p < 0.05; **p < 0.01; ***p < 0.001.

Source: NTP (1989)TR-349, Table F3 page 231.

TEQ = toxic equivalent; NA = not applicable.

^a^ To obtain these TEQ values: Table F-7 (males) and Table F-8 (females) calculated these values for the high dose (200 ppm for technical grade, 600 ppm for EC-7). This value was multiplied by 7 to obtain μg/kg/wk for the high doses, then reduced based on relative amount in feed for the other exposures.

^b^ Technical grade PCP: 100 ppm = 17 mg/kg bw/d; 200 ppm = 35 mg/kg bw/d.

^c^ Dowicide EC-7: 100 ppm = 19.8 mg/kg bw/d; 200 ppm = 37 mg/kg bw/d; 600 ppm = 118 mg/kg bw/d.

Table F-10 Comparison of Liver Neoplasm Percent Incidences in PCP (NTP 1989) and in TCDD (NTP 1982) Studies in Female B6C3F_1_ Mice

Dose | TEQ^a^ μg/kg/wk | Incidence of Liver Tumors (%)
Dose | TEQ^a^ μg/kg/wk | Adenoma | Carcinoma | Combined
TCDD (gavage twice a week)
vehicle control | NA | 2/73 (3) | 1/73 (1) | 3/73 (4)
0.01 μg/kg/wk | NA | 4/50 (8) | 2/50 (4) | 6/50 (12)
0.2 μg/kg/wk | NA | 4/48 (8) | 2/48 (4) | 6/48 (13)
2.0 μg/kg/wk | NA | 5/47 (11) | 6/47 (13)* | 11/47 (23)**
Trend | | | p ≤ 0.01 | p ≤ 0.01
Technical-Grade PCP (feed)^b^
0 ppm | NA | 3/33 (9) | 0/30 (0) | 3/33 (9)
100 ppm | 0.513 | 8/49 (16) | 1/49 (2) | 9/49 (18)
200 ppm | 1.026 | 8/50 (16) | 1/50 (2) | 9/50 (18)
Dowicide EC-7 (feed)^c^
0 ppm | NA | 1/34 (2) | 0/34(0) | 1/34 (3)
100 ppm | 0.0026 | 3/50 (6) | 1/50 (2) | 4/50 (8)
200 ppm | 0.0052 | 6/49 (12) | 0/49 (0) | 6/49 (12)
600 ppm | 0.0155 | 30/48 (63) | 2/48 (4) | 31/48 (65)***
Trend | | p ≤ 0.001 | | p ≤ 0.001

* p < 0.05; **p < 0.01; ***p < 0.001.

Source: NTP (1989)TR-349, Table F3 page 231.

TEQ = toxic equivalent; NA = not applicable.

^a^ To obtain these TEQ values: Table F-7 (males) and Table F-8 (females) calculated these values for the high dose (200 ppm for technical grade, 600 ppm for EC-7). This value was multiplied by 7 to obtain μg/kg/wk for the high doses, then reduced based on relative amount in feed for the other exposures.

^b^ Technical grade PCP: 100 ppm = 17 mg/kg bw/d; 200 ppm = 35 mg/kg bw/d.

^c^ Dowicide EC-7: 100 ppm = 17 mg/kg bw/d; 200 ppm = 34 mg/kg bw/d; 600 ppm = 114 mg/kg bw/d.