# Appendix E Genotoxicity Studies

The tables on the following pages contain data discussed in the “Mechanisms and Other Relevant Effects” section (Section 5) for genetic and related effects (Section 5.1).

Data are reported for in vitro studies of pentachlorophenol, including mutagenicity and DNA damage in bacteria (Table E-1) and genotoxicity studies of pentachlorophenol in non-mammalian eukaryotes (Table E-2) and mammalian cells (Table E-3). Studies on the formation of adducts in cells or DNA treated with pentachlorophenol in vitro and animals treated in vivo are included in Table E-4 and Table E-5. In vivo studies of pentachlorophenol are shown for cytogenetic effects in rodents (Table E-6), as well as chromosomal aberrations (Table E-7) and sister chromatid exchange (Table E-8) in lymphocytes of occupationally exposed workers. A summary of genotoxicity studies of pentachlorophenol metabolites is provided in Table E-9.

Table E-1 In Vitro Studies of Pentachlorophenol Mutagenicity and DNA Damage in Bacteria

Reference | Effect | Test System/Strain (Method) | LED/HID (µg/Plate) | | Results | | Cytotoxicity | | Purity | Evaluation: Limitations and Conclusions
Reference | Effect | Test System/Strain (Method) | −S9 | +S9 | −S9 | +S9 | −S9 | +S9
USEPA (2010); Waters et al. (1982) | Mutation | Salmonella typhimurium TA98, TA100, TA1535, TA1537, TA1538 | 10 mg/ plate (all strains) | 10 mg/ plate (all strains) | − | − | | | | Negative all strains ±S9. Aroclor 1254-induced rat S9. Data tables not available; multiple doses tested but not specified; EPA cites HID as 10 µg/plate ±S9. [Note: Waters reported use of 10 mg/plate.]
Nishimura et al. (1982b) | Mutation | S. typhimurium TA98 TA100 (preincubation) | 26.6 µg/ plate^a^ NR | 5.3 µg/ plate^a^ NR | − − | + − | TA98 >16 µg/ plate^a^ | TA98 >16 µg/ plate^a^ | “Standard sample” (not commercial grade) | Positive in TA98 +S9; otherwise negative. Phenobarbital/benzoflavone-induced rat liver S9; significant induction of mutants above 5.3 g/plate with maximum induction at 10.7 µg/plate^a^. Statistical analysis not specified.
Nishimura and Oshima (1983), as cited in IARC (1999) (same group as above) | Mutation | S. typhimurium TA98 TA100 | NR | NR | − − | + − | | | | Positive in TA98 +S9 (phenobarbital/benzoflavone induced); otherwise negative. Results based on control vs. 10.7 µg/plate^a^ treatment (only dose for which data was reported); Nishimura group repeated their earlier experiment, confirming results reported in 1982 paper. Statistical analysis not specified.
Haworth et al. (1983); NTP (1999) | Mutation | S. typhimurium TA98, TA100, TA1535, TA1537 (preincubation) | 10 µg/ plate | 30 µg/ plate | − | − | All strains, slightly toxic at 10 µg/plate, total toxicity at 30 µg/plate | Not toxic at 30 µg/ plate | 91.6^b^ | Negative all strains ±S9. Tested 0.3, 1, 3, 10, 30 µg/plate; Aroclor 1254-induced rat or hamster S9; NTP 1989 reported same data and confirmed results in a second trial.
Gopalaswamy and Nair (1992) | Mutation | S. typhimurium TA98 (plate incorporation) | 100 µg/ plate | 50 µg/ plate | − | (+) | | | NR | Weakly positive TA98 +S9; negative −S9. Aroclor 1254-induced rat S9; only tested 50 and 100 µg/plate. Induced mutant frequency cannot be calculated due to incomplete reporting but authors report weak positive both doses +S9.
Markiewicz et al. (1996) | Mutation | S. typhimurium TA98 (Plate incorporation) | 100 µg/ plate | 100 µg/ plate | − | − | None noted | None noted | NR | Negative for all induction compounds: 30% S9 induced in male Sprague-Dawley rats: phenobarbital, commercial and prepared Aroclor and TCDD.
Donnelly et al. (1998) | Mutation | S. typhimurium TA97a, TA98, TA100 (Plate incorporation) | 200 µg/ plate | 200 µg/ plate | − | − | None reported (all strains) | None reported (all strains) | >98% | Negative all strains ±S9. Tested 2, 20, 50, 100, 200 µg/plate; Aroclor-induced rat S9 (30%); no toxicity observed up to and including highest dose tested.
DeMarini et al. (1990) | Prophage λ induction | Escherichia coli | NR | 3.4 µg/ mL^c^ | (+) | + | 12.5 µg/mL | 25 µg/mL | 92% | Positive +S9; weakly positive −S9. Aroclor 1254-induced rat S9.
Waters et al. (1982) | DNA damage | E. coli (polA–) | | | − | ND
Waters et al. (1982) | DNA damage | Bacillus subtilis | | | + | ND
Ozaki et al. (2004) | DNA damage (Rec-assay) | Bacillus subtilis M45 Rec- and H17 Rec+ | µg/disc 3.0 6.0 | | + + | | | | >99% | Positive in both strains.
Witte et al. (1985) | DNA damage (strand breaks) | Bacteriophage PM2 DNA | 100 mM | | − | | | | NR | Negative. Data not shown.

LED/HID = lowest effective dose/highest ineffective dose; NR = not reported; NT = not tested; + = positive; (+) = weak positive; − = negative.

^a^ Data for LED/HID estimated from figure; to facilitate comparison with other studies, data reported by these authors as µmol/plate were converted to µg/plate by NTP.

^b^ Although Haworth et al. (1983) noted 96% purity, NTP reported 91.6%.

^c^ To facilitate comparison with other studies, doses reported by these authors as µM were converted to µg by NTP.

Table E-2 Studies of Pentachlorophenol in Non-mammalian Eukaryotes

Reference | Effect | Test System/Strain | | Concentration (LEC or HIC) µg/mL | Cytotoxicity | Results | | Evaluation: Limitations and Conclusions
Reference | Effect | Test System/Strain | | Concentration (LEC or HIC) µg/mL | Cytotoxicity | −S9 | +S9 | Evaluation: Limitations and Conclusions
Yeast
Fahrig et al. (1978) | Forward mutation | Saccharomyces cerevisiae MP-1 | | 400 | 59% survival | + [underlined: Convertants/10^7^ survivors] Control Treated 0.61 2.00* | NT | Positive. Purity 99% Only tested one dose.
Fahrig (1974) | DNA damage (gene conversion) | S. cerevisiae D4 | | 50.6^a^ | 30% survival | + [underlined: Convertants/10^5^survivors] Control Treated ade2 0.45 6.62*** trp5 0.36 4.31*** | NT | Positive. Solvent 1% DMSO, 6-hr treatment, 8 expts; positive mitotic gene conversion at two loci.
Fahrig et al. (1978) | DNA damage (gene conversion) | S. cerevisiae MP-1 | | 400 | 59% survival | + [underlined: Recombinants/10^7^ survivors] Control Treated trp5 2.93 5.64*** ade2 0.49 0.47 | NT | Positive. Purity 99% Only tested one dose.
Waters et al. (1982) | DNA damage | S. cerevisiae D3 | | | | + | | Positive.
Invertebrates
Vogel and Chandler (1974) | Sex-linked recessive lethal mutations | | Drosophila melanogaster | 1,864^a^ in feed | | − | | Negative. Tested pentachlorophenol, sodium salt; purity not reported.
Ramel and Magnusson (1979) | Aneuploidy | | D. melanogaster | 400 in feed | | − | | Negative in XXY and XO offspring. Purity not reported.
Yin et al. (2006) | Point mutation (p53 gene) | | Tuebingen (zebrafish) | 5 µg/L in aquarium water | | + Conc Base Mutation (µg/L) Rate × 10^-4^ 0 2.12 0.5 3.15 5 7.33** 50 10.73** | | Positive. Purity >98%.
Pavlica et al. (2001) | DNA damage – haemocytes (comet assay) | | Dreissena polymorpha Pallas (zebra mussel) | 80 µg/L in aquarium water (7 d treatment) | Cell viability >87% in all treatment groups | + | | Positive. Purity not reported. Tested at 10, 80, 100 and 150 µg/L; all doses except lowest were significant to p < 0.01.
Pavlica et al. (2000) | Micronuclei induction | | D. polymorpha (mussel) Planorbarius corneus L. (great ramshorn snail) | (14 d treatment) Mussel: 10 Snail: 100 | | + | | Positive for both test animals. Purity not reported. Tested for 4, 7, 14 days Mussel: 10, 80, 100, 150 µg/L Snail: 10, 100, 450, 600 µg/L
Plants
Pavlica et al. (1998) | Chromosome aberrations and Micronucleus induction (MN) | | Allium ascalonicum | 0.001 | | + Conc % Aberrant MN (µg/mL) cells Control 0.9 3.0 0.001 3.0* 13.2* 0.01 5.6* 14.0* 0.1 7.7* 24.3* | | Positive. Purity not reported. % Aberrant cells at pH 6.0; MN at pH 8.0. MN results per 1,000 cells
Ateeq et al. (2002) | Chromosome aberrations | | Allium cepa | 0.5 | | + Conc % Aberrant (µg/mL) cells 0 1.33 0.5 7.15* 1 4.50* 2 6.73* 3 8.57* | | Positive. Purity 99%
Repetto et al. (2001) | Micronucleus induction (MN) | | Allium cepa | 1.33 | | + Conc MN (%) (µg/mL) 0 0.1 0.27 0.1 1.33 0.1**^b^ 2.66 1.7**^b^ | | Positive. Purity not reported. Data are expressed relative to mean value in unexposed controls.

* p < 0.05; **p < 0.01; ***p < 0.001.

NT = not tested.

^a^ To facilitate comparison with other studies, concentration reported by authors as 0.19 mM (Fahrig), 7.0 mM (Vogel and Chandler) and 1 to 10 µM (Repetto) were converted to µg/mL by NTP.

^b^ Significance levels as reported by study authors.

Table E-3 In Vitro Studies of Cytogenetic Effects of Pentachlorophenol in Mammalian Cells

Reference | Effect | Test System/Strain | Conc. µg/mL (LEC or HIC) | Cytotoxicity | Results | | Purity (%) | Evaluation: Limitations and Conclusions
Reference | Effect | Test System/Strain | Conc. µg/mL (LEC or HIC) | Cytotoxicity | −S9 | +S9 | Purity (%) | Evaluation: Limitations and Conclusions
Hattula and Knuutinen (1985), as cited in IARC (1999) | Mutation, hepatocyte-mediated | V79 Chinese hamster lung fibroblasts | 15 | Cloning efficiency 55.3% | − | NT | >99.95 | Negative. Information limited to that provided in review study.
Jansson and Jansson (1986) | Mutation (forward) | V79 Chinese hamster lung fibroblasts | 50 | Survival at top dose 27% (see comments) | − | NT | >99.5 | Negative. 0, 6.5, 12.5, 25 50 µg/mL; dose-dependent decrease in cell survival with increasing dose, i.e., 100%, 90%, 73%, 53%, and 27%.
Helleday et al. (1999) | Mutation (Intragenic recombination; reversion assay) | SPD8 and Sp5 (derived from V79 Chinese hamster lung cells) | SPD8: 35 Sp5: 40 | Viability (%) 8 15 | − Conc Reversion freq (µg/mL) (×10^−5^) SPD8 Sp5 0 2.0 3.4 10 1.7 4.1 20 2.1 2.3 30 4.1 3.2 35 4.9 ND 40 ND 3.2 | NT | NR | Negative. Authors report that no results from any doses in treated cultures were significantly different from control (p < 0.05) using Student’s t-test.
Dahlhaus et al. (1996) | DNA damage (single strand breaks) | Alkaline elution assay/V79 Chinese hamster lung fibroblasts | 6.6a | | − | NT | NR | Negative.
Ehrlich (1990) | DNA damage (single strand breaks) | Alkaline elution assay/Chinese hamster ovary cells | 10 | Slightly toxic 10 µg/mL; toxic 20 µg/mL | − | NT | NR | Negative. Tested 5, 10, 20 µg/mL.
Wang and Lin (1995) | DNA damage (single strand breaks) | Precipitation assay/mouse embryonic fibroblasts C3H10T1/2 | −S9: 59^b^ +S9: 37^b^ | Viability >67% | − | (+) | NR | Weakly positive +S9; negative −S9. Phenobarbital/ hydrocortisone-induced S9.
Michałowicz and Majsterek (2010) | DNA damage (single and double strand breaks) (comet assay) | Human lymphocytes | 0.2^a^ | Viability 67%^b^ at 125 ppm | + Conc Damaged (µg/mL) DNA (%)^c^ 0 0.2 0.2 0.7* 1 3.8** 5 5.6** | NT | 99.5 | Positive. Results based on 3–4 individual experiments; subjects (4) healthy male non-smokers
Michałowicz and Majsterek (2010) | DNA damage- pyrimidines (comet assay) | Human lymphocytes | 0.2 | | + Conc Damaged (µg/mL) DNA (%)^c^ 0 0.3 0.2 2.8* 1 6.0* 5 8.6* | NT | 99.5 | Positive.
Stang and Witte (2010) | DNA damage (comet assay, high-throughput) | V79 | 1.0^c^ | | NT | + | NT | Positive under all conditions tested. Purity not reported.
Stang and Witte (2010) | DNA damage (comet assay, high-throughput) | Human fibroblasts | 1.25^c^ | | NT | + | NT | Positive under all conditions tested. Purity not reported.
Stang and Witte (2010) | DNA damage (comet assay, high-throughput) | HeLa cells | 1.15^c^ | | NT | + | NT | Positive under all conditions tested. Purity not reported.
Stang and Witte (2010) | DNA damage (comet assay, high-throughput) | HepG2 cells | 1.0^c^ | | + | NT | NT | Positive under all conditions tested. Purity not reported.
Stang and Witte (2010) | DNA damage (comet assay, high-throughput) | Human lymphocytes | 0.5^c^ | | NT | + | NT | Positive under all conditions tested. Purity not reported.
Tisch et al. (2005) | DNA damage (single and double strand breaks) – DNA migration | Human epithelial (mucosal) nasal cells – microgel electrophoresis | For both inferior and middle nasal mucosa 1.2 mmol/mL (see comments) | From low to high dose, undamaged cell # decreased for both middle nasal concha | + Cell migration (µm) Conc middle inferior (mmol/mL) concha concha 0 29.1 25.9 0.3 40.3 30.7 0.75 63.1 45.3 1.2 81.6*** 60.1*** Undamaged cells decreased for middle (79.5% to 8%)*** and inferior nasal concha (85.6% to 36.6%)***, compared with controls. | NT | >99.5 | Positive. Authors reported test concentrations as 0.3, 0.75, 1.2 mmol/mL; results are given as µm cell migration. For inferior and middle nasal concha, significant DNA migration increase (92% and 64%, respectively, of cells exposed to 1.2 mmol/mL) and the number of undamaged cells decreased significantly with increasing dose.
Galloway et al. (1987); NTP (1999) | Chromosomal aberrations | Chinese hamster ovary cells | −S9 100 +S9 100 | NR | − | (+) high dose* and trend*** | 91.6 | Weakly positive +S9; negative −S9. Tested ±S9 to 100 µg/mL; weakly positive with +S9 at the highest dose and for p-trend. Results of repeat expt. +S9 were questionable.
Ishidate (1988), as cited in IARC (1999) | Chromosomal aberrations | V79 Chinese hamster lung fibroblasts | −S9 300 +S9 240 | −S9 NR +S9 300 | + | + | 99.9 | Positive, but only at high dose for both ±S9. Mouse S9 (chemical used to induce S9 NR). Limited reporting of protocol and data.
Ziemsen et al. (1987) | Chromosomal aberrations | Human lymphocytes from healthy male donors | 90 | Slowed cell proliferation at 60 µg/mL treatment | − | NT | 85 | Negative −S9.
Galloway et al. (1987), NTP (1999) | Sister chromatid exchange | Chinese hamster ovary cells | −S9 3 +S9 100 | NR | (+) | − | 91.6 | Weakly positive −S9; negative +S9. Tested (−S9): 1, 3, 10, 30 µg/mL; significantly increased at only one dose 3 µg/mL. Weakly positive, p-trend < 0.008. Tested (+S9): 3, 10, 30, 100 µg/mL, all negative.
Ziemsen et al. (1987) | Sister chromatid exchange | Human lymphocytes from healthy male donors | 90 | Slowed cell proliferation at 60 µg/mL treatment | − | NT | 85 | Negative −S9. Tested 30, 60, 90 µg/mL.
Monteith (1992) | Unscheduled DNA repair (UDS) | Hepatocytes from male Wistar rats treated with corn oil or 3-MC (80 mg/kg) | 0.003 | | − Net grains/ nucleus (±SD) Corn oil Control −1.0 ± 2.3 Treated −0.1 ± 2.0 3-MC Control 0.2 ± 2.0 Treated 0.2 ± 2.1 | | 99 | Negative. Hepatocytes were isolated from rats treated with 3-methyl-cholanthrene (3-MC) or corn oil; only one dose (0.003 µg/mL) of pentachlorophenol was used to treat hepatocytes.
Hogberg et al. (2009) | Gene expression | Rat primary neuronal cultured cells (cerebellum granule cells isolated from 7-d old animals) | 13.3^a^ | | + For 50 µM treatment, mRNA expression decreased by (%) NF-68 78*** NF-200 91*** NMDA-R 79*** GABA-R 46 S100β 41** Nestin 54*** | | | Positive. Most significant effect at 11 d in vitro (div) with 50 µM treatment, mRNA expression of all studied genes was decreased.
Wang et al. (2000) | Apoptosis and related gene expression | Human cell lines: Chang liver cells and T-24 bladder carcinoma cells | | Chang cells 500 µM T-24 cells 100 µM | − Hsp70, CAS, bcl-2, bax gene expression unchanged | | | Negative. Induced cell death, but was more like necrosis than apoptosis
Michałowicz and Sicińska (2009) | Apoptosis | Human lymphocytes | 25^a^ | | + Conc Apoptotic (µg/mL)^a^ cells (%)^c^ 0 1 5 2 25 5** 50 10** 100 27** | | 99.5 | Positive.
Wispriyono et al. (2002) | Apoptosis | Jurkat human T cells | 5.3^a^ | Viability: 99.8% (1.3 µg/mL), 97.5%, (2.7 µg/mL), 88.5% (5.3 µg/mL) | + Conc Apoptotic (µg/mL)^a^ cells (%)^c^ 0 2 1.3 3 2.7 8 5.3 20* | | | Positive.

* p < 0.05; **p < 0.01; ***p < 0.001.

Exp = Exposure; LEC/HIC = lowest effective concentration/highest ineffective concentration; ND = not done; NR = not reported; RTG = relative total growth; SD = standard deviation; + = positive; (+) = weak positive; − = negative.

^a^ To facilitate comparison with other studies, data reported by authors as µM or ppm were converted to µg/mL by NTP.

^b^ Values read from figures; to facilitate comparison with other studies, data reported by authors as 220 and 140 µM were converted to µg/mL by NTP.

^c^ Values read from figure.

Table E-4 In Vitro Studies of Adducts in Mammalian Cells (or DNA) Treated with Pentachlorophenol

Reference | Effect | Test System | Concentration µg/mL (LEC or HIC) | Cytotoxicity | Results | | Evaluation: Limitations and Conclusions
Reference | Effect | Test System | Concentration µg/mL (LEC or HIC) | Cytotoxicity | −S9 | +S9 | Evaluation: Limitations and Conclusions
Witte et al. (1985) | DNA adducts | Calf thymus DNA | 10 mM | | − | | Negative. Data not shown.
Dubois et al. (1997) | DNA adducts (covalent binding to DNA) | Fetal quail and fetal rat hepatocytes Human hepatoma (HepG2) cells | 13.3a | | + (10 adducts identified in three cell types) | NT | Positive. Purity 99% Tested with single dose. One adduct was dominant in rat hepatocytes and HepG2 cells (50% and 47% of total, respectively); quail cells had a different major adduct (46%); some adducts were specific to cell type, others were found in all types.
Dai et al. (2003) | DNA adducts (covalent binding to dG, deoxyguanosine) | Excess dG (2 mM) | 26.6a | NR | + O-bonded C8-dG adduct | − | Positive. Treatment in presence of horseradish peroxidase or myeloperoxidase (from human lymphocytes) and excess dG. Addition of S9 results in formation of alternative adduct.
Dai et al. (2005) | DNA adducts (covalent binding to DNA) | Calf thymus DNA (1 mg/mL) | 26.6a | NR | + O-bonded C8-dG adduct | NT | Positive. Treatment in presence of horseradish peroxidase
van Ommen et al. (1986b) | DNA adducts | Calf thymus DNA | 26.6a | | + Microsomal DNA adduct: 12 pmol/mg DA/min | | Covalent binding to DNA was less than for protein.
van Ommen et al. (1986b) | Protein adducts | Microsomal protein from induced male and female Wistar rat liver | 26.6a | | + Microsomal protein adduct: 63 pmol/mg/ protein/min | | Formed 1,4- and 1,2- tetrachloro-p-hydroquinone.

^a^ To facilitate comparison with other studies, data reported by authors as µM or ppm were converted to µg/mL by NTP.

Table E-5 In Vivo Studies of Adducts in Rodents Exposed to Pentachlorophenol

Reference | Endpoint (Cell Type) | Species/Sex/# in Dose Group | Exposure | Results | Evaluation: Limitations and Conclusions
Sai-Kato et al. (1995a) | DNA adducts (liver, kidney, and spleen) | Mouse (B6C3F_1_) male/5 | Treatment by gavage; 30, 60 or 80 mg/kg (daily) for one or five days (single 60 mg/kg dose only for kidney and spleen) | + 8-OH-dG levels for single and repeat doses significantly increased over controls in liver | Positive. Purity 98.6% Increase only in liver, not in kidney or spleen. Effects are blocked (30%–75% inhibition) by pre-treatment with antioxidants vitamin E and diallyl sulfide.
Umemura et al. (1996) | DNA adducts (liver) | Mouse (B6C3F_1_) male/5 | Treatment in food; 0.03%, 0.06%, 0.12% for 2 or 4 weeks | + 8-OH-dG levels significantly increased over controls (both time- and dose-dependent) | Positive. Purity 98.6%. BrdU labeling index and hepatic DNA content (hyper-proliferation) were also elevated; may be involved in carcinogenesis.
Umemura et al. (1999) | DNA adducts (liver) | Mouse (B6C3F_1_) male/5 | Treatment in food; 600 or 1,200 ppm for 8 weeks | + 8-OH-dG levels significantly increased over controls (dose dependent). | Positive. Purity 98.6%. Cell proliferation increased in a treatment dose-dependent manner.
Lin et al. (2002) | DNA adducts (liver) | Rat (F344) male/3-4 | Treatment by gavage; 30, 60 or 120 mg/kg (×1 day) or 30 or 60 mg/kg (×5 days); dietary 60 mg/kg/day 27-wk treatment | + 27-wk treatment increased 8-OH-dG 2× over controls; negative other treatments | Positive. Adduct may be derived from TCpBQ (metabolite of pentachlorophenol).
Tasaki et al. (2013) | DNA adducts (liver) | Mouse C57BL/6 p53 (^+/+^ and ^−/−^) male/5 | Treatment in food; 600 or 1,200 ppm, 13 weeks. | + Significant elevations of 8-OHdG levels for both genotypes. | Positive.
Tsai et al. (2002) | Protein adducts | Sprague-Dawley rats/male/3 and B6C3F_1_ mice/male/3 | Treatment by gavage; 20 mg/kg bw | + Radiolabel binding (% of total) Protein Rat Mouse Np 97.9 100 Cp 67.0 100* Alb 1.3 2.63* | Positive Purity >98%. Three protein solutions: liver nuclei (Np), liver cytosol (Cp) and albumin (Alb); covalent binding with cysteinyl adducts; mice metabolized 5x more than rats.

Table E-6 In Vivo Studies of Cytogenetic Effects of Pentachlorophenol in Rodents

Reference | Endpoint (Cell Type) | Species/Sex/# | Exposure | Results | Evaluation: Limitations and Conclusions
Fahrig et al. (1978) | Mouse spot test - mutation/ recombination | Mouse C57BL/6JHan x T-stock | Treatment i.p. 50 or 100 mg/kg bw | (+) | Weakly positive. Purity 99% Tested 50 and 100 mg/kg. Although limited to small numbers of offspring in study, considered a weak positive.
Xu (1996), as cited in USEPA (2010) | Micronuclei (bone marrow) | Mouse (CD-1)/ male and female/NR | Treatment by gavage: males 24, 60, 120 mg/kg; females 10, 50, 100 mg/kg | − | Negative. Unpublished report reviewed by EPA 2010; information is limited to that provided in review; purity 88.9%; number animals not given. No increase in micronuclei frequency was reported.
NTP (1999) | Micronuclei (bone marrow) | Mouse (B6C3F_1_) male/5 per dose group | Treatment i.p. 50, 100, 150 mg/kg (3× at 24-hr intervals) | − MN-PCEs/1000 Dose #Mice Mean ± SE 0 5 2.2 ± 0.3 50 3 1.0 ± 0.0 100 3 2.0 ± 0.8 | Negative. Purity 99% Corn oil control; high dose150 mg/kg lethal. 2000 polychromatic erythrocytes (PCEs) scored No increased micronucleated PCEs in treated animals.
NTP (1999) | Micronuclei (bone marrow) | Rat (F344/N)/ male/5 per dose group | Treatment i.p. 25, 50, 75 mg/kg (3× at 24-hr intervals) | − MN-PCEs/1000 Dose #Rats Mean ± SE 0 5 0.8 ± 0.3 25 4 0.8 ± 0.3 50 5 1.5 ± 0.4 | Negative. Purity 99% Corn oil control; high dose 75 mg/kg lethal. No increase in micronucleated polychromatic erythrocytes (PCEs) in treated animals.
Daimon et al. (1997) | Chromosomal aberrations (hepatocytes) | Rat (F344/Du Crj)/male/5 per dose group | Treatment i.p. 10 mg/kg bw (repeated ×5 days) | − Cells with aberrations (%) Control 2^a^ Treated 1.2 | Negative. Only one treatment dose, repeated 5 days. Evaluated 100 metaphase cells/animal. No increase in chromosome aberrations over controls.
Daimon et al. (1997) | Sister chromatid exchange (hepatocytes) | Rat (F344/Du Crj)/ male/5 per dose group | Treatment i.p. 10 mg/kg bw | + SCE/chromosome Control 0.59 Treated 0.71** | Positive. Only one treatment dose. Scored 25 second-division metaphase cells/animal. Treated had significant (p < 0.01) SCE induction.
Tasaki et al. (2013) | mRNA levels | Mouse C57BL/6 p53 ^(+/+)^ and ^(−/−)^ male/5 per dose group | Treatment in diet 600 or 1,200 ppm, 13 weeks. | + Significant decrease in CYP 2B10 in p53^−/−^ and increase in NQ01 mRNA levels for both genotypes | Positive. No effect on CYP1A1 or 1A2
Monteith (1992) | Unscheduled DNA repair (UDS) | Rats 3 control 2 treated (sex not reported) | Treatment i.p.; 10.7 mg/kg pentachlorophenol dissolved in propane-1,2-diol | + Net grains/ nucleus (±SD) Control 0.07 ± 1.96 Treated 3.30 ± 4.13*** | Positive. Purity 99% Significant increase for treated over control. Only tested one dose.

** p < 0.01 (t-test); ***p < 0.001 (t-test).

^a^ Value estimated from figure.

Table E-7 In Vivo Studies of Chromosomal Aberrations (CA) in Lymphocytes from Workers Occupationally Exposed to Pentachlorophenol

Reference (Location) | Study Population (Years Employed) | Number of Subjects | PCP Exposure Mean (Range) | | | Results Mean (Range) Exposure Response | Evaluation: Limitations and Conclusions
Reference (Location) | Study Population (Years Employed) | Number of Subjects | Air (µg/m^3^) | Blood Serum (µg/L) | Urine (µg/L) | Results Mean (Range) Exposure Response | Evaluation: Limitations and Conclusions
Wyllie et al. (1975)^a^ (Idaho, USA) | Wood treatment plant workers, overlapping job duties. (2–11 years) | Exposed 6 Controls 4 | 0.263–1.89 | 1,372.1 (348.4–3,963.0) 47.7 (38.0–68.0) (from single control subject) | 163.8 (41.3–760) 3.4 (2.6–4.3) (from single control subject) | − (% Cells with chromosome breaks) 1.1 (0.6–6.0) 0 (0–0.1) | Negative. Unmatched male controls but similar age range. Workers potentially exposed to other substances, smoking and other lifestyle variables not considered. Cells cultured 48 h; methods indicate 25 cells scored per individual; but data provided as % aberrations, i.e., per 150 cells; very small sample size. Serum exposure based on monthly assessment for workers during 5-month study Jan-May, but May-Oct has highest production; air exposure values are levels measured monthly at 11 sites. Non-statistically significant increase in chromosome aberrations; information also provided on gaps. Deficiencies in reporting (missing data and calculation errors); stated there four control workers, but serum and urine measurement data only provided for one. Statistics: not specified.
Bauchinger et al. (1982)^b^ (West Germany) [same study as reported by Schmid et al. (1982)] | PCP-producing factory, male workers (1–30 yr) Controls included 9 smokers and 13 non-smokers. | Exposed 22 (handled PCP (8) or Na-PCP (14)) Controls 22 (workers with no known exposure) | <100– >500 | PCP workers: 4,730 Na-PCP workers: 2,230 | 2,380 840 | + Cont. Exp. S-cells (%) 0.509 1.02*** [underlined: Types of CA] Chromatid 0.0020 0.0028 breaks Chromatid 0.0005 0.0008 exchange Acentric 0.0022 0.0057* fragments Dicentrics 0.0005 0.0016* | Positive. Matched controls, all subjects male. Workers not exposed to other industrial chemicals; 8 workers were sacking PCP and 14 were sacking Na-PCP; all 22 exposed workers and 9/22 of control subjects were smokers. Cell harvest 44 hr, 300 cells scored for exposed and 500 for controls. Structural chromosome changes (S-cells): dicentrics and acentric fragments were increased in the exposed group, compared with all controls or compared with only smokers in controls. No increase in chromatid-type aberrations (breaks and exchanges) or gap frequency due to exposure. Statistics: Mann-Whitney rank U test.
Ziemsen et al. (1987) (West Germany) | Wood preservative production plant, two groups of workers^d^ Group 1: Low exposure (6 to 34 yr) Group 2: High exposure (3 to 23 yr) | Group 1: 9 Group 2: 11 | All workers: 1.2 to 180 | Group 1: 23 to 116 Group 2: 59 to 775 | ND | − | Negative. Workers in two groups, low and high exposure, based on main type of exposure; gender not identified. Occupational history examined for other chemical exposure. Cell harvest time not indicated; scored 100 metaphases per subject. No effect of PCP exposure on CA frequency for all workers, for groups, or for smokers (14) vs. non-smokers (6). Individual data reported; types of CAs and total number of cells analyzed were reported for each worker but number of cells with aberrations was not, thus the % of cells with CAs cannot be calculated. Statistics: X^2^ test.

* p < 0.05; ***p < 0.005.

ND = not determined; NR = not reported.

^a^ To facilitate comparison with other studies, data reported by these authors as ng/m^3^ and ppb were converted to µg/m^3^ and µg/L respectively.

^b^ To facilitate comparison with other studies, air exposure data reported by these authors as mg/m^3^ were converted to µg/m^3^.

^c^ Chromosomal aberrations as measured by number of chromosome breaks.

^d^ Group 1 transported and weighed raw material – inhalation of dry dust, 96% pure, and technical water-soluble Na-PCP, 85% pure; Group 2 handled finished PCP solutions.

Table E-8 In Vivo Studies of Sister Chromatid Exchange (SCE) in Lymphocytes from Workers Occupationally Exposed to Pentachlorophenol

Reference (Location) | Study Population (Years Employed) | Number of Subjects | PCP Exposure Mean (Range) | | | Results SCE/Cell: Mean ± SE (Range) | Comments
Reference (Location) | Study Population (Years Employed) | Number of Subjects | Air (µg/m^3^) | Blood Serum (µg/L) | Urine (µg/L) | Results SCE/Cell: Mean ± SE (Range) | Comments
Bauchinger et al. (1982) ^a^ (West Germany) [same study as reported by Schmid et al. (1982)] | PCP-producing factory, male workers (1–30 yr) Controls included 9 smokers and 13 non-smokers. | Exposed (22) Controls (All 22) Controls (9 smokers) Controls (13 non-smokers) | <100– >500 | PCP workers: 4,730 Na-PCP workers: 2,230 | 2,380 840 | − Exposed (22) 9.41 ± 0.35 (6.68–12.8) 8.13 ± 0.26 8.89 ± 1.24 7.60 ± 0.95 | Negative. Matched controls, all subjects male. Workers not exposed to other industrial chemicals; all exposed workers and 9/22 of control subjects were smokers. Cultured 54 h; 50 M_2_ cells scored/individual. Workers were not exposed to other industrial chemicals, but all exposed workers and 9/22 of control subjects were smokers. Exposed workers had significantly higher SCE values when compared with all controls, but there was no effect when exposed workers were compared with control group smokers only; the control group smokers also had a significant higher incidence of SCEs. Thus, these SCE effects are attributable to smoking, not PCP exposure. Statistics: Mann-Whitney U-test.
Ziemsen et al. (1987) (West Germany) | Wood preservative production plant, two groups of workers^d^ Group 1: Low exposure (6 to 34 yr) Group 2: High exposure (3 to 23 yr) | Group 1: 9 Group 2: 11 | All workers: 1.2 to 180 | 23 to 116 59 to 775 | ND | − 7.49 ± 0.8^c^ (6.40–8.97) 7.65 ± 1.37^c^ (5.63–10.00) | Workers in two groups, low and high exposure, based on predominant type of exposure; gender not identified. Occupational history examined for other chemical exposure. Cultured 72 hrs; scored 60 metaphases per subject. No correlation between SCE frequency and any exposure index. No effect of smoking on SCE (6 non-smokers vs. 14 smokers). Means of two groups were not statistically different. Statistics: Student’s t-test.

NR = not reported; ND = not determined.

^a^ To facilitate comparison with other studies, air exposure data reported by these authors as mg/m^3^ were converted to µg/m^3^.

^b^ Group 1 transported and weighed raw material – inhalation of dry dust, 96% pure, and technical water-soluble Na-PCP, 85% pure; Group 2 handled finished PCP solutions.

^c^ Means and SDs in results for Ziemsen et al. (1987) were calculated by NTP from data provided in publication.

Table E-9 Summary of In Vitro and In Vivo Studies of Pentachlorophenol Metabolites

Test System | Effect | Tetrachloro-p-hydroquinone | Tetrachloro-catechol | Tetrachloro-p- or -o-benzoquinone
In vitro
Mammalian cells (non-human) | Mutation | +^a^ | −^b^
Mammalian cells (non-human) | DNA damage | + | −^b^ | +
Mammalian cells (non-human) | DNA adducts | +^c^ | | +^c^
Human cells | DNA damage | + | +^d^ | +^d^
Human cells | Apoptosis | +
In vivo
Mammals | DNA adducts | +^d^

Sources: USEPA (2010); IARC (1999).

+ = Positive in all or most of available studies; − = negative in all or most of available studies.

^a^ Positive at HPRT, but not Na/K-ATPase, locus.

^b^ Tested in V79 cells without metabolic activation.

^c^ Calf thymus DNA.

^d^ Result based on one study.