# Appendix D Assessment of the Quality of the Individual Animal Cancer Studies on Exposure to Pentachlorophenol and By-products of Its Synthesis

Twelve studies were identified in which experimental animals were exposed to pentachlorophenol and by-products of its synthesis for long-term durations (≥12 months for mice and rats), or they reported neoplastic lesions, or non-neoplastic lesions that are relevant to carcinogenicity (see Section 4, Cancer Studies in Experimental Animals). Some of these studies are reported in multiple publications and some publications report more than one study (Table D-1).

Table D-1 Overview of Studies of Exposure to Pentachlorophenol and By-products of Its Synthesis in Experimental Animals

Strain (Sex) | Substance | Experimental Design | Exposure Period/Study Duration | Reference
Rat: Diet
F344/N (M & F) | 99% pure PCP | Carcinogenicity | 2 yr/2 yr | Chhabra et al. (1999); NTP (1999)
F344/N (M & F) | 99% pure PCP | Carcinogenicity | 1 yr/2 yr | Chhabra et al. (1999); NTP (1999)
Sprague-Dawley (M & F) | Dowicide EC-7 | Carcinogenicity and reproductive | M: 22 mo/22 mo F: 24 mo/24 mo | Schwetz et al. (1978)
MRC-W (M & F) | Technical grade PCP | Co-carcinogen | 94 wk/94 wk | Mirvish et al. (1991)
Mouse: Diet
B6C3F_1_ (M & F) | Technical grade PCP | Carcinogenicity | 2 yr/2 yr | McConnell et al. (1991); NTP (1989)
B6C3F_1_ (M & F) | Dowicide EC-7 | Carcinogenicity | 2 yr/2 yr | McConnell et al. (1991); NTP (1989)
(C57BL/6xC3H/Anf) F_1_, (M & F) | Dowicide-7 | Carcinogenicity | 18 mo/18 mo | Innes et al. (1969)
(C57BL/6xAKR)F_1_ (M & F) | Dowicide-7 | Carcinogenicity | 18 mo/18 mo | Innes et al. (1969)
CD-1 (F) | 99% pure PCP | Mechanism^a^ | 12 mo/16 mo | Boberg et al. (1983)
CD-1 (F) | 99% pure PCP | Mechanism^a^ | 10 mo/17 mo | Delclos et al. (1986)
C57BL/6-Trp53(+/−) tm1Dol (M &F) | 99% pure PCP | Short-term p53 (+/−) knock-out carcinogenicity | 26 wk/26 wk | Spalding et al. (2000)
Mouse: Dermal
Tg•AC hemizygous (M & F)^b^ | 99% pure PCP | Short-term transgenic carcinogenicity | 20 wk/20 wk | Spalding et al. (2000)

M = male; F = female.

^a^ PCP inhibiting carcinogenic activation by sulfotransferase.

^b^ Zeta-globin promoted v-Ha-ras on a FVB background.

Each of these primary studies were systematically evaluated in a two-step process by first evaluating whether the level of detail reported for key elements of study design, experimental procedures, and cancer endpoints were adequate for evaluating its quality and interpreting its results. All twelve studies were adequately reported and further assessed for concerns of study quality that might negatively impact the ability to evaluate carcinogenicity (Table D-2, Table D-3). Quality assessment of studies with similar experimental design and exposure route reported in a single publication are shown in a single column; the two Spalding et al. (2000) studies from one publication are reported in two columns as the animal strain, exposure route, and tumor endpoints differ. Table D-2, Table D-3, and Section 4, Cancer Studies in Experimental Animals, discusses the results and study quality findings from all of the studies in Table D-1.

## D.1 Study Quality Assessment

Study quality was assessed using questions related to the following study performance elements: substance characterization, animal husbandry, study design, endpoint assessment, and data interpretation. In most cases, each question inquires whether there are concerns (minimal, some, major, and no information reported) that the quality of a specific study element is adequate for attributing any neoplastic endpoints to exposure of pentachlorophenol and by-products of its synthesis. In general, the ranking of the concerns for the study elements is based on how far each study element deviates from the ideal (see below).

The assessment of the overall quality of a study is based on consideration of the individual elements and how they impact the usefulness of that study in assessing carcinogenicity. Studies that were given the most weight in the evaluation (e.g., those with no or minimal concerns in key elements) are those with the following key characteristics:

1. Use a chemical that is representative of the candidate substance (in terms of purity and stability) so that any observed effects can be attributed to the candidate substance.
2. No evidence of poor animal husbandry conditions (such as high mortality due to infection). Often information on animal husbandry conditions is not known and while this information is desirable, it is not a requirement.
3. Exposure of animals to high enough doses (result in tolerable toxicities) for a sufficiently long duration (approaching the lifetime of the animal), but not to a dose that limits survival over the exposure period. The use of more than one dose level is ideal but is not a requirement.
4. Have an appropriate comparison group (e.g., ideally unexposed, sham treated concurrent controls). The absence of an appropriate control group, by itself, is sufficient for judging a study to be inadequate for cancer evaluation.
5. Have adequate statistical power to detect an effect, which is based on the number of animals used in a study, the incidence of tumors in control vs. treated group, and the rarity of the tumor.
6. Perform full necropsies and histopathological examinations on all tissues. Ideally, animals are exposed to multiple doses that allow for statistical comparisons to the control group and dose-response analysis.

An ideal study would have the following characteristics, which are related to interpreting the study. In general, with the exception of route of exposure, these do not contribute as much weight to the overall evaluation of the study as the characteristics related to the validity of the study discussed above.

7. The use of an exposure route comparable to human exposure.
8. The use of animal model that is sensitive for detecting tumors and does not have high background rates for the observed tumors. Studies in both sexes are more informative than those testing only one sex. Often this information is not available.
9. Availability of historical control data, which can be helpful in assessing the significance of a finding, especially in the case of rare tumors, lower powered studies, or assessment of background tumor incidences. Rare tumors will be considered in the assessment even if their incidences do not reach significance.
10. Appropriate reporting of incidence data and statistical methods. If statistical tests are not reported, the study should at a minimum present incidence data for specific tumors so that statistical tests can be run.

Study having elements that are judged to have some or major concerns may still be considered in the evaluation or can be considered to provide support to the more informative studies. It should also be noted that some concerns about a study element (such as inadequate observation and exposure period and statistical power) would decrease the sensitivity of a study to detect an effect; however, if despite these limitations, positive findings were described, these studies would inform a cancer assessment.

Table D-2 Assessment of the Quality of Cancer Studies in Rats

| NTP (1999) (Diet) | Schwetz et al. (1978) (Diet) | Mirvish et al. (1991) (Diet)
Substance characterization
Are there concerns that the purity solubility and stability of the chemical are not adequate for attributing any neoplastic effects to the substance? | Concerns: minimal | Concerns: some No stability testing | Concerns: some The substance contained 25 ppb of TCDD, no other studies reported detectable TCDD.
Animal husbandry
Are there concerns that the quality of the animal husbandry (e.g., care, diet, maintenance, and disease surveillance) is not adequate for attributing any neoplastic effects to the substance? | Concerns: minimal | No information reported | Concerns: minimal
Study design
Are there concerns that the study design did not include randomization of animals to dose groups and blinding of dose groups? | Concerns: minimal Rats were randomized, but blinding was not reported. | No information reported | Concerns: minimal Rats were randomized, but blinding was not reported.
Are there concerns that the dosing regimen (dose selection and dose groups, or other factors) is either not adequate for detecting a neoplastic effect (if present) or for attributing any tumor effects to the substance? | Concerns: some Only one dose level for the stop exposure study and tumor incidences suggest the doses were too low in the continuous exposure study. The dose levels were based on a 28-day dietary study. Significant loss of weight occurred, but survival was similar to controls. | Concerns: minimal Four doses used, no effect on mean food consumption or survival, except survival in males decreased the last two months. Body weights of females was significantly decreased. | Concerns: some Only one dose level tested and neither hematology, body weight, nor mean survival indicated significant toxicity, however survival could not be determined from report
Are there concerns that the study duration (exposure and observation) is not adequate to detect a neoplastic effect, if present? | Concerns: minimal | Concerns: minimal Duration near lifespan but cut short in control and exposed males by 2 mo (to 22 mo) due to high mortality. | Concerns: minimal
Are there concerns that the concurrent control group was not adequate for evaluating the study? | Concerns: minimal | Concerns: minimal | Concerns: minimal
Are there concerns that the study does not have adequate statistical power (number of animals per exposure and control group) to detect a neoplastic effect, if present? | Concern: minimal | Concerns: minimal Each sex and dose had 27 rats. | Concerns: some Low numbers of exposed rats (5 males and 9 females) and control rats (9 males and 18 females). Inadequate information on survival.
Endpoint assessment
Are there concerns that the assessment of study outcome (gross and microscopic tissue analysis) was not done blind? | Concerns: minimal Histological examination was not blinded. | No information reported | No information reported
Are there concerns that the methods to access tumor outcome and the pathology procedures (necropsy, histology, or diagnosis) are not adequate for attributing the effects? | Concerns: minimal | Concerns: minimal | Concerns: minimal
Data interpretation
Are there concerns that survival-related effects could affect attributing the study findings to exposure? | Concerns: minimal | Concerns: minimal Survival of both control and exposed males was shortened, but not until after 22 mo. | Concerns: some Survival can’t be adequately assessed.
Are there concerns that the route of exposure is not adequate for evaluating the potential for human carcinogenicity | Concerns: minimal | Concerns: minimal | Concerns: minimal
Are there concerns about the animal model (source, species, strain, or sex) that could affect study interpretation? | Concerns: minimal | Concerns: minimal | Concerns: minimal
Are historical control data reported? If not, this would be a concern for rare tumors, or tumors with high background. | Yes | No | No
Are there concerns that reporting of the data and statistical analysis are inadequate for evaluating the results? | Concerns: minimal | Concerns: some Tumor incidences were high, but only total tumors were reported, tumor types not specified. | Concerns: some Statistical analysis not reported and tumor incidences based on the number of rats surviving 11 weeks; the original number of animals in each group were not reported.
Overall assessment of study quality and utility for cancer assessment
Does this study have utility for cancer assessment? What is the overall level of concern for the quality of the study, and how would any concerns affect its interpretation? | Yes, some concerns about the dose levels being low as only the highest dose level out of four exposed groups had significant tumors. | Yes, some concerns of not reporting specific tumor incidences. | Yes, some concerns about the low numbers of rats; the inability to assess survival; only one dose level was tested, and most toxicity measures were negative; and that the substance was the only one that reported containing TCDD.

Table D-3 Assessment of the Quality of Cancer Studies in Mice

| NTP (1989) (Diet) | Innes et al. (1969) (Diet) | Boberg et al. (1983) (Diet) | Delclos et al. (1986) (Diet) | Spalding et al. (2000) (Diet) [p53 (+/−) knock-out] | Spalding et al. (2000) (Dermal) [Transgenic]
Substance characterization
Are there concerns that the purity solubility and stability of the chemical are not adequate for attributing any neoplastic effects to the substance? | Concerns: minimal | Concerns: some No stability testing | Concerns: some No stability testing, but bulk chemical re-purified every 6 months. | Concerns: some No stability testing, but bulk chemical re-purified every 6 months. | Concerns: minimal | Concerns: minimal
Animal husbandry
Are there concerns that the quality of the animal husbandry (e.g., care, diet, maintenance, and disease surveillance) is not adequate for attributing any neoplastic effects to the substance? | Concerns: minimal | Concerns: minimal | No information reported | No information reported | Concerns: minimal | Concerns: minimal
Study design
Are there concerns that the study design did not include randomization of animals to dose groups and blinding of dose groups? | Concerns: minimal Mice randomized but blinding not reported. | No information reported | No information reported | No information reported | Concerns: minimal Mice were randomized, but blinding was not reported | Concerns: minimal Mice were randomized, but blinding was not reported
Are there concerns that the dosing regimen (dose selection and dose groups, or other factors) is either not adequate for detecting a neoplastic effect (if present) or for attributing any tumor effects to the substance? | Technical Grade: Concerns: minimal Only two dose levels with acceptable weight loss in females. Dose levels were based on liver lesions (karyomegaly, cytomegaly, hepatocellular degeneration, and necrosis) in 6-month dietary studies. Dowicide EC-7: Concerns: minimal Three dose levels with acceptable toxicity except low survival in low-dose females. Dose levels were based on liver lesions (karyomegaly, cytomegaly, hepatocellular degeneration, and necrosis) in 6-month dietary studies. | Concerns: some Only one exposure level that is a relatively low dose (130 ppm in food). | Concerns: some Only one dose level used which did not significantly decrease body weight gain or survival, but the concentration in the feed (500 ppm) was comparable to that of the NTP (1989) studies. | Concerns: some Only one dose level used which did not significantly decrease body weight gain or survival, but the concentration in the feed (500 ppm) was comparable to that of the NTP (1989) studies. | Concerns: minimal Three dose levels used were comparable to the NTP (1989) study, but no overt toxicities were reported. | Concerns: minimal Three dose levels used and initially caused toxicity, so were reduced.
Are there concerns that the study duration (exposure and observation) is not adequate to detect a neoplastic effect, if present? | Concerns: minimal | Concerns: minimal Exposed and observed for less than lifespan (18 months) | Concerns: some Mice exposed for less than lifespan, 12 months and observed for a total of 16 months. | Concerns: some Mice exposed for less than lifespan, 10 months and observed for a total of 18 months. | Concerns: some Exposure was only for 26 wk, none of the 6 chemicals tested induced tumors, and no positive control was used. | Concerns: minimal Exposure was only 20 weeks, but the mice are transgenic and tumors were induced by PCP and a positive control.
Are there concerns that the current control group was not adequate for evaluating the study? | Concerns: minimal | Concerns: minimal | Concerns: minimal | Concerns: minimal | Concerns: minimal | Concerns: minimal
Are there concerns that the study does not have adequate statistical power (number of animals per exposure and control group) to detect a neoplastic effect, if present? | Concerns: minimal | Concerns: minimal | Concerns: minimal Each dose level had 36 females. | Concerns: minimal Each dose level had 35 females. | Concerns: some The number of mice in each group was low (10 males and 10 females). | Concerns: some The number of mice in each group was relatively low (13 to 15/dose level) and only females were tested.
Endpoint assessment
Are there concerns that the assessment of study outcome (gross and microscopic tissue analysis) was not done blind? | Concerns: minimal Histological examination not blinded. | No information reported | No information reported | No information reported | No information reported | No information reported
Are there concerns that the methods to access tumor outcome and the pathology procedures (necropsy, histology, or diagnosis) are not adequate for attributing the effects? | Concerns: minimal | Concerns: minimal Full necropsy, except for brain and thyroid gland. | Concerns: minimal Necropsies focused on the liver, but also included the pleural and peritoneal cavities and subcutaneous tissue. | Concerns: minimal Necropsies focused on the liver, but also included the pleural and peritoneal cavities and subcutaneous tissue. | Concerns: minimal | Concerns: minimal
Data interpretation
Are there concerns that survival-related effects could affect attributing the study findings to exposure? | Concerns: minimal | No information reported | Concerns: minimal | Concerns: minimal | Concerns: minimal | Concerns: minimal
Are there concerns that the route of exposure is not adequate for evaluating the potential for human carcinogenicity? | Concerns: minimal | Concerns: minimal | Concerns: minimal | Concerns: minimal | Concerns: minimal | Concerns: minimal
Are there concerns about the animal model (source, species, strain, or sex) that could affect study interpretation? | Concerns: minimal | Concerns: minimal | Concerns: some Only females used. | Concerns: some Only females used. | Concerns: some Knock-out mice (p53 (+/−)) were used without a positive control and none of the 6 chemicals tested induced tumors. | Concerns: some Only females were tested. The mice were transgenic, but positive and negative controls were used with expected outcomes. The mechanism of carcinogenesis in the model may not be relevant to mechanisms in humans.
Are historical control data reported? If not, this would be a concern for rare tumors or tumors with high background. | Yes | No | No | No | No | No
Are there concerns that reporting of the data and statistical analysis are inadequate for evaluating the results? | Concerns: minimal | Concerns: some Incidences were not reported. | Concerns: minimal | Concerns: minimal | Concerns: some Incidences were not reported, only a statement of negative findings. | Concerns: minimal
Overall assessment of study quality and utility for cancer assessment
Does this study have utility for cancer assessment? What is the overall level of concern for the quality of the study, and how would any concerns affect its interpretation? | Yes, minimal concerns in most key elements. | Yes, some concerns of a single, relatively low, exposure level. | Yes, some concerns of no stability testing; only tested in females; only tested one dose level without significant decreases in body weight or survival; and less than life-time exposure. | Yes, some concerns of no stability testing; only tested in females; only tested one dose level without significant decreases in body weight or survival; and less than life-time exposure. | Yes, some concerns with a low number of mice used in each group, a short-term p53 (+/−) knock-out model without the use of a positive control with none of the 6 chemicals inducing tumors and no toxicities reported. This model is positive primarily with mutagenic chemicals. | Yes, some concerns with a low number of mice used in each group. Carcinogenesis in the model can be activated by dermal irritation and wounding.