# Appendix C Human Cancer Studies

This appendix contains background information related to the cancer assessment on pentachlorophenol in humans including (1) detailed data information on study design, methods, and findings for human cancer studies (Table C-1, Table C-2, Table C-3) and (2) detailed information on the quality assessment of the individual studies (Table C-4). Table C-1, Table C-2, Table C-3 summarize studies specific for pentachlorophenol, including nested case-control and cohort studies of pentachlorophenol users and producers (Table C-1), a pentachlorophenol ecological study (Table C-2) and population based case-control studies (Table C-3).

## C.1 Methodologies and Study Characteristics of the Selected Epidemiological Studies and Identification of Cancer Endpoints

The data from the three cohort studies, one nested case-control study and one ecological study, and six case-control studies (see Table 3-1) were systematically extracted from relevant publications and are summarized in the tables below.

Table C-1 Cohort and Nested Case-control Studies of Pentachlorophenol Producers and Users

| Study Characteristics and Overall Findings
Kogevinas et al. (1995)
Related References | [underlined: Cohort]: Kogevinas et al. (1992), Saracci et al. (1991), Vena et al. (1998)
Geographic Location | 8 Western European countries, Australia, New Zealand, and Canada (IARC registry)
Population Characteristics
Cases: selection and ascertainment | [underlined: Cases]: 32 NHL (20 deaths, 12 incident cases) 11 STS (4 deaths, 7 incident cases) [underlined: Case eligibility criteria]: Male or female with NHL or STS as underlying or contributory cause of death identified in IARC Dioxin international registry or identified from cancer registry records [underlined: Cohort eligibility criteria]: All (21,183) workers in 24 cohorts from 11 countries ever exposed to phenoxy herbicides, chlorophenols or dioxins; 145 workers in the PCP production worker cohort [underlined: Participation rate]: 2 controls excluded in NHL analysis due to missing work histories
Controls: selection and ascertainment | [underlined: Referents]: 158 NHL; 55 STS [underlined: Referent eligibility criteria]: Members of participating cohort in IARC registry with complete job histories [underlined: Matching criteria]: 5 controls per case by incidence density sampling and matched for age, sex, and country of residence
Follow-up | Average of all cohorts: 17 yr; 25 yr for PCP cohort
Loss to follow-up | Average for all cohorts: 5% (maximum for individual cohort 10%)
Study Design and Analytical Methods | Nested occupational case-control study Conditional logistic regression analysis lagged by 5 yr. Risks calculated for four levels (including unexposed) of cumulative exposure
Exposure Data and Information Assessment
Exposure: levels and co-exposures | Levels of PCP and other exposures NR Potential co-exposures: Although the cohort consisted of members exposed to 21 chemicals, exposure to PCP only occurred in one British cohort, and no other co-exposures were reported.
Exposure assessment | Exposure assigned to individual workers by experts using company exposure questionnaires and records, department and jobs, likelihood of contact, and personal protection. Level of exposure was assigned using a relative scale. Ever-worked workers were classified into three categories of cumulative exposure: low = <1 yr, medium = 1 to 10 yr, high = 10 yr or more.
Assessment of potential confounders | No information on smoking or other lifestyle factors Risk estimates not adjusted for these co-exposures
Disease assessment | NHL (coded ICD-8 or 9 as 200, 202); STS (coded ICD-8 and 9 as 171) Death certificates or cancer registrations, depending on country, used to identify cases
Collins et al. (2009b)/Ramlow et al. (1996)
Related References | Bond et al. (1989); Ott et al. (1987) (earlier updates)
Geographic Location | Michigan, U.S.
Population Characteristics
Exposed cohort and ascertainment | [underlined: Eligibility criteria]: Subcohort of white male workers from total cohort ever employed in departments where PCP exposure could have occurred 1940–1980 [underlined: Exposed cohort]: 773 workers ever exposed to PCP between 1940 and 1980 (770 workers, Ramlow) [underlined: Total cohort]: Workers in production or finishing of higher chlorinated phenols (TCP or PCP) and 2,4,5, trichlorophenoxyacetic acid who were potentially exposed to PCDD (N = 2,192) from 1937–1980 [underlined: Follow-up]: Ramlow1940–1989 (average 26 yr); Collins 1940–2004 (average 35 yr) [underlined: Loss to follow-up]: 0%
Reference population | [underlined: External analysis]: U.S. white male population or State of Michigan or NIOSH for STS [underlined: Internal analysis]: Michigan Division workers employed 1940 to 1980, employed in plants without potential exposure to PCP or PCDD
All-cause and all-cancer mortality | All-cause mortality: SMR 0.94 (0.83–1.1) 229 All-cancer morality: SMR 0.95 (0.71–1.25) 50
Study Design, Analytical Methods/Control for Confounding | Historical cohort mortality study Ramlow: (a) SMR analyses: Life table analysis by age and calendar period for white males; unlagged and lagged by 15 yr (b) Cumulative exposure to PCP, 2,3,7,8-TCDD, and H/OCDD using two reference groups: external (U.S expected rates) or internal analysis of Michigan division workers (nonexposed and categories of cumulative exposure) and lagged for 15 yr Collins: (a) PCP only and PCP and TCP exposed workers: external (SMR) analysis, (b) dioxin congeners (PCP by-products): external for exposure categories (ppt-yr), (c) total TCDD TEQ: external for exposure categories and internal (proportional hazard regression model) using exposure categories (ppt-yr) and linear models (1 part per billion increases in cumulative exposure) and adjusted for age, hire yr and birth.
Exposure Data and Information Assessment
Exposure: levels and co-exposures | Job exposure matrix for TCP (similar to that of PCP). Assessment of exposure to 2,3,7,8-TCDD, both background levels and from exposure to TCP. No individual quantitative exposure assessment for other agents but industrial hygiene data from company data and NIOSH investigators
Exposure assessment | Ramlow: Individual work histories by job title and department, expert knowledge (veteran employees), plant information, and industrial hygiene data used to calculate cumulative exposure to PCP and higher chlorinated dioxins Collins: 2,3,7,8-TCDD TEQ for 5 dioxin by-products in PCP or TCP and the levels of individual congers estimated using a model that incorporated serum dioxin analyses from a subsample of past workers, work history, and industrial hygiene monitoring data
Assessment: other exposures | Not reported
Disease assessment | Death certificates (underlying cause of death); coding converted to ICD-8
Ruder and Yiin (2011)
Related References | Fingerhut et al. (1991) Marlow (1986) (exposure data)
Geographic Location | U.S.A., 4 manufacturing plants
Population Characteristics
Exposed cohort and ascertainment | [underlined: Eligibility criteria]: All members of the NIOSH Dioxin Registry* with complete demographic data ever employed in PCP production departments at four plants that produced PCP from 1936 to 2006. 0.8% excluded due to missing data [underlined: Exposed cohort]: 1,402 workers ever exposed to PCP but not TCP [underlined: Total cohort]: 2,122 PCP production workers exposed to PCP, TCP and/or other chemicals, 720 of which were exposed to PCP + TCP [underlined: Follow-up]: 1940 or first date of PCP production (whichever was later) to 2005 [underlined: Loss to follow-up]: 0.4% (PCP, no TCP); 0.1% (PCP + TCP)
Reference population | [underlined: External analysis]: U.S. national mortality rates [underlined: Internal analysis]: Lowest employment duration category (<58 days)
All-cause and all-cancer mortality | All-cause mortality: SMR 1.04 (0.97–1.11); 818 All-cancer mortality: SMR 1.25 (1.09–1.42); 238
Study Design and Analytical Methods/Control for Confounding | Historical cohort mortality study NIOSH life table analysis system used to calculate person-yr at risk External analysis: race-, sex- and calendar period-adjusted SMR (Poisson distribution); underlying and multiple cause of death analyses conducted. SMR also calculated by sex, gender, plant, and duration of employment in PCP departments. Internal analysis: SRR for employment duration; trend slope also calculated.
Exposure Data and Information Assessment
Exposure: levels and co-exposures | PCP: Exposure data limited to most recent dates of PCP production at each plant. Exposure across plants ranged from 0.006 to 45 mg/m^3^ (see Appendix B, Table B-1). Duration of exposure 1 day–30.7 yr (2.5 ± 4.71 yr) 90% workers exposed to multiple chemicals reported in 1 or more plant, including IARC Group 1, 2A, 2B carcinogens; however, few are risk factors for cancer sites of interest; 172 workers exposed only to PCP and no TCP or other chemicals TCP (contaminated with 2,3,7,8-TCDD) made in 2 (Michigan and Illinois) of the 4 plants
Exposure assessment | Exposure coded via company personnel records and work histories from start of PCP production through 1983, updated to 1992 for workers employed after 1983 and new workers employed after 1983; insufficient data to create a job exposure matrix Missing data: No coding of work history and exposures for workers in Plant 4 after 1992, although PCP production continued to 2006
Assessment: other exposures | Smoking data available for a subset of one of the plants
Disease assessment | Death certificates: ICD-9 used for analysis Missing Data: Vital status unknown for 0.3% workers
Demers et al. (2006)
Related References | Hertzman et al. (1997) (earlier follow-up); Friesen et al. (2007) (additional analysis). Exposure: Hertzman et al. (1997); Teschke et al. (1989); Teschke et al. (1996); Teschke et al. (1998)
Geographic Location | British Columbia, Canada
Population Characteristics
Exposed cohort and ascertainment | [underlined: Eligibility criteria]: Male workers employed ≥1 yr (or 260 days total) from 1950–1995 at 1 of 14 sawmills in British Columbia, Canada [underlined: Exposed cohort]: 26,464 male workers in mortality study; 25,685 in incidence study [underlined: Follow-up]: 1950–1995 (mortality); 1969–1995 (incidence) [underlined: Loss to follow-up]: 4% (mortality); <0.1% (incidence)
Reference population | External: Provincial standardized referent mortality and incidence rates [underlined: Internal]: Lowest category for exposure
All-cause and all-cancer mortality/incidence | All-cause mortality: SMR: 0.95 (0.93–0.98); 5,872 All-cancer mortality/incidence: SMR: 1.00 (0.95–1.05); 1,495 SIR: 0.99 (0.95–1.04); 2,571
Study Design and Analytical Methods/Control for Confounding | Historical cohort mortality and incidence study External analysis: SMR and SIR adjusted for age and yr (Poisson distribution) Internal analysis: Exposure-response analysis (RR and trend) for specific cancer sites (mortality, unlagged, 10-20-lagged incidence) and 4 dermal exposure categories, (using lowest exposure category as the reference group). Separate analysis for (1) all chlorophenols, (2) PCP or (3) TeCP. Continuous exposure was also modeled (Friesen et al. 2007). RR estimated using maximum likelihood methods; age-, race- and calendar period-adjusted using Poisson regression but not adjusted for co-exposure or other potential confounders.
Exposure Data and Information Assessment
Exposure: levels and co-exposures | Most formulations contained both PCP and TeCP (mainly PCP from 1941–1965; mainly TeCP 1965–on). Correlation between TeCP and PCP = 0.45 Urinary levels on chlorophenols measured on subset of current workers for two seasons. Dermal exposure: PCP: 0.062–0.41 mg/cm^2^/day; TeCP 0.15–0.82 mg/cm^2^/day 2,3,7,8-TCDD not detected in PCP or TeCP formulations Exposure to cooper chrome arsenate or creosote unlikely. Little information on other exposure but exposure to wood dust or formaldehyde possible.
Exposure assessment | Detailed work history for each cohort member, mill-specific assessments using historical records, fungicide formulations (PCP/TeCP) and expert informants (senior workers) Almost all of exposure was dermal. Expert assessment correlated (0.72 and 0.76) with urinary levels measured in subset of current workers Exposure years, hour per yr and fungicide formulation used to calculate full-time equivalent exposure-years (1 FTE yr = ~2,000 hr dermal contact) for PCP and TeCP. Exposure levels categorized as <1, 1–2, 2–5, and 5+ FTE exposure-year.
Assessment: other exposures | Age-adjusted smoking rates (based on interviews with 2,000 workers) similar to general population and not correlated with exposure
Disease assessment | Cancer registry and death certificates (underlying cause) using ICD-9; Soft tissue sarcoma diagnosed using tissue site and histology data

IARC = International Agency for Research on Cancer; NHL = non-Hodgkin lymphoma; STS = soft tissue sarcoma; PCP = pentachlorophenol and by-products of its synthesis; yr = year or years; NR = not reported; ICD = (WHO) International Classification of Diseases (and revision versions); TCP = 2,4,5-trichlorophenol; PCDD = polychlorinated dibenzodioxins; NIOSH = National Institute for Occupational Safety and Health (U.S.); SMR = standardized mortality ratio; 2,3,7,8-TCDD = 2,3,7,8-tetrachlorodibenzo-p-dioxin; HpCDD = 1,2,3,4,6,7,8-hepta-chlorodibenzo-p-dioxin; HxCDD = 1,2,3,4,7,8-hexachlorodibenzo-p-dioxin (1,4-HxCDD) or 1,2,3,6,7,8-hexachlorodibenzo-p-dioxin (1,6-HxCDD) or 1,2,3,7,8,9-hexachlorodibenzo-p-dioxin (1,9-HxCDD); OCDD = octachlorodibenzo-p-dioxin; ppt = parts per trillion; TEQ = toxic equivalent calculated using WHO recommended weights for 2,3,7,8-TCDD, HxCDDs, HpCDD and OCDD combined; SRR = standardized relative risk; SIR = standardized incidence ratio; RR = relative risk; TeCP = tetrachlorophenol; FTE = full-time equivalent.

Table C-2 Pentachlorophenol Ecological Study

| Study Characteristics and Overall Findings
Zheng et al. (2015)
Related References | Zheng et al. (2012)
Geographic Location | Tongling district, China
Population Characteristics
Population | Eligibility criteria: All cancer cases reported to local cancer registry from hospitals, community health centers, and death registries 2009–2011 for all residents in district
Reference population | World population, age-standardized incidence rates Low – high exposure residency areas
Study Design and Analytical Methods/Control for Confounding | Cross-sectional ecological study Age-standardized incidence rate per 100,000 population reported for males and females separately SRR analysis using low exposure category as reference and by duration of exposure (residence) No analyses for potential confounding
Exposure Data and Information Assessment
Exposure: levels and co-exposures | Low exposure area: 0–<2.117 mg/m^2^/yr Medium exposure area: 2.117–34.002 mg/m^2^/yr High exposure area: >34.002–80.142 mg/m^2^/yr Cumulative exposure 1–40 yr
Exposure assessment | Ecological assessment of residence in area sprayed with Na-PCP from 1960–2002 Pollution Index: PCP average application mg/m^2^/yr calculated using schistosomiasis control records. Average exposure: pollution index/yr for each of 10 districts Exposure grade across districts: low, medium, and high corresponding to pollution index (PCP usage/square meter)
Assessment: other exposure | Not reported
Disease assessment | Cancer registry

SRR = standardized relative risk; yr = year or years; Na-PCP = sodium pentachlorophenate; PCP = pentachlorophenol and by-products of its synthesis.

Table C-3 Population-based Case-control Studies of Pentachlorophenol Users

| Study Characteristics and Overall Findings
Hardell et al. (1994)
Related References | Hardell (1981); Hardell (1979) (questionnaire validation study)
Geographic Location | Umea, Sweden
Population Characteristics
Cases: selection and ascertainment | [underlined: Cases]: 105 cases of NHL [underlined: Case eligibility criteria]: All cases of histologically verified NHL among males 25–85 yr old admitted to Dept. Oncology, Umea, Sweden 1974–1978 with a completed lifetime work history/exposure questionnaire (self or proxy) [underlined: Participation rate]: 100% cases, 99.2% controls
Controls: selection and ascertainment | [underlined: Referents]: 338 [underlined: Referent eligibility criteria]: Subjects, identified via the National Population Registry or National Registry for Causes of Death, from the same or adjacent municipality as cases and who initially answering the questionnaire. Exclusions: Suicides and cancer deaths, and deceased controls who had recently died or not worked 5 yr before death [underlined: Matching criteria]: Age, sex, municipality, and vital status; 8 living controls per living case and 10 deceased controls per deceased case
Study Design and Analytical Methods | Population-based case-control study Mantel-Haenszel OR, stratification by age and vital status; multivariate analysis that included chlorophenols, phenoxyacetic acids, organic solvents, and DDT
Exposure Data and Information Assessment
Exposure: levels and co-exposures | Low exposure: <1 week (continuous) or <1 month (total) High grade exposure: ≥1 week (continuous) or ≥1 month (total) Prevalence of PCP exposure (high grade): 14.3% cases 2.7% controls Co-exposures: NR
Exposure assessment | Structured questionnaire (self or proxy) for information on lifetime working history and exposure to chlorophenols including PCP, phenoxyacetic acid herbicides, and other exposures. Workers with potential exposure to chlorophenols via cutting oils and leatherwork considered unexposed due to insufficient exposure information. Validation study of a similar questionnaire in the same area found a 97% agreement between information from self-reported exposure and employers (sawmill and pulp industry) but few details or data from the study were provided.
Assessment of potential confounders | Questionnaire (self or proxy) report of exposure to chlorophenols including PCP), phenoxyacetic acid herbicides, and smoking and other exposures
Disease assessment | Histological data from NHL cases re-examined and classified by authors according to subtype stage, and anatomical site. Rappaport classification
Hardell and Eriksson (1999)
Related References | Hardell et al. (2002) (pooled analysis)
Geographic Location | Mid and northern Sweden
Population Characteristics
Cases: selection and ascertainment | [underlined: Cases]: 402 male cases of NHL [underlined: Case eligibility criteria]: All male NHL cases, 25 yr or older, reported to regional cancer registry between 1987 and 1990, confirmed by pathological report (N = 442, including 192 deceased cases) and who completed a self-reported lifetime questionnaire [underlined: Participation rate]: 91% of cases and 84% controls; participation rate for proxies similar to living respondents
Controls: selection and ascertainment | [underlined: Referents]: 741 [underlined: Referent eligibility criteria]: Living controls identified from National Population registry and deceased controls identified from National Registry for Causes of Death (884) and who completed a self-reported questionnaire. Suicides excluded [underlined: Matching criteria]: Age, sex, county of residence (living cases); age, sex, yr of death (deceased cases) and vital status; 2 male controls per case.
Study Design and Analytical Methods | Cancer registry-based population case-control study Logistic conditional regression analysis; analysis by time since first exposure and last exposure to diagnosis NHL only (Hardell and Eriksson 1999): No adjustment for co-exposures or assessment of potential confounding. NHL and HCL (Hardell et al. 2002): multivariate analyses that includes impregnating agents (PCP 60% of cases), herbicides, insecticides and fungicides
Exposure Data and Information Assessment
Exposure: levels and co-exposures | PCP levels and cumulative duration of exposure NR Duration of exposure reported for all herbicides and phenoxyacetic acids only Prevalence of PCP exposure: 13.7% cases; 11.7% controls Chlorophenols banned in 1977. No co-exposures reported for PCP-exposed subjects
Exposure assessment | Self or proxy-reported, structured questionnaire, including complete employment history, questions on specific pesticides (both occupational and non-occupational), brands, methods of use, years of exposure and cumulative exposure in days. Follow-up interviews, blinded to case-control status, conducted when exposure information unclear Interviews conducted from 1993 to 1995 Exposures within 1 yr of diagnosis excluded from analysis
Assessment of potential confounders | Information on smoking, medical history and diet requested on questionnaire but data not reported or included in analyses.
Disease assessment | All cases identified in regional cancer registry subject to pathological report confirmation; 29 of initial 442 cases excluded due to wrong diagnosis or wrong date of diagnosis
Nordström et al. (1998)
Related References | Hardell and Eriksson (1999) (NHL); Hardell et al. (2002) (pooled analysis of NHL and HCL)
Geographic Location | Sweden
Population Characteristics
Cases: selection and ascertainment | [underlined: Cases]: 111 male cases of HCL [underlined: Case eligibility criteria]: All living males with hairy-cell leukemia (subtype of NHL) reported to Swedish Cancer Registry 1987–1992 (including 1 case from 1993) (N = 121) [underlined: Participation rate]: 91% cases and 83% controls
Controls: selection and ascertainment | [underlined: Referents]: 400 males [underlined: Referent eligibility criteria]: 4 living males per case identified from National Population Registry (N = 484) [underlined: Matching criteria]: Age and county of residence
Study Design and Analytical Methods | Cancer registry-based case-control study Logistic regression controlling for age (matching was dissolved to increase statistical power); multivariate analysis (including pesticides, solvents, animals, and exhausts) conducted only for combined “impregnating” agents (including creosote and other unspecified agents) by 2 categories of exposure duration. Conditional logistic regression performed on subset of the data.
Exposure Data and Information Assessment
Exposure: levels and co-exposures | Levels of PCP NR Prevalence of PCP exposure: 8.1% cases; 3.5% controls No co-exposures reported for PCP-exposed subjects
Exposure assessment | Self-reported by respondent on (mail + interview) questionnaire on lifetime working history, information on specific exposures (occupational and non-occupational) and lifetime activities. Interviews and coding blinded to case-control status Proxy used for 4 cases and 5 controls due to medical reasons or death Minimum exposure of 1 working day and induction period of 1 yr.
Assessment of potential confounders | No assessment of co-exposures for PCP-exposed cases Smoking data for total cohort indicated OR 0.6 (0.4–1.1) for active smokers; not examined for PCP-exposed cases and controls
Disease assessment | Compulsory reporting of cancers to National Cancer Registry
Hardell et al. (1995)
Related References | Individual studies in pooled analysis: Hardell (1979); Eriksson et al. (1990); Eriksson et al. (1981); Hardell and Eriksson (1988)
Geographic Location | Sweden
Population Characteristics
Cases: selection and ascertainment | [underlined: Cases]: 434 cases of STS [underlined: Case eligibility criteria]: Male or female cases (alive or deceased) of STS >25 or 26 yr old; admitted to Umea hospital 1970–77, or reported to Swedish cancer registry from southern counties 1974–1977, Umea regional cancer registry 1978–1983; Uppsala regional cancer registry 1978–1986 [underlined: Participation rate]: Not reported for all studies, appears to range from <1% to 6% for cases, <1% to 10% for controls
Controls: selection and ascertainment | [underlined: Referents]: 948 [underlined: Referent eligibility criteria]: Controls selected from national population registries or National Register on Causes of Death; Exclusions: cancer controls and controls who had not worked 5 yr before retirement or death. [underlined: Matching criteria]: 1–2 controls per case matched on age, gender, and county of residence.
Study Design and Analytical Methods | Cancer registry-based case control studies; pooled analysis of 4 independent studies in Sweden with similar methods and population base Mantel-Haenszel odds ratios stratified for age, viral status, and study; no adjustment for lifestyle factors or occupational co-exposures. Cases and controls with exposure to phenoxyacetic acids were excluded in analyses in two of the individual case control studies (Eriksson et al. 1990; Hardell 1979)
Exposure Data and Information Assessment
Exposure: levels and co-exposures | Levels of PCP exposure: Not Reported Length of potential exposure to chlorophenols: 64% >77 days, and 36% ≤77 days PCP exposure prevalence: 6.2% cases; 3.2% controls Exposure (high-grade) was defined as ≥1 week (continuous) or ≥1 month (total) No co-exposures reported for PCP-exposed subjects
Exposure assessment | Self-reported (mailed) questionnaire completed by subject or proxy (deceased cases or controls) on complete work history and information on specific job categories, smoking habits, and leisure time information on exposure to chemicals. Follow-up interviews were conducted if information was unclear or incomplete. Validation study of a similar questionnaire in the same area found a 97% agreement between information from self-reported exposure and employers (sawmill and pulp industry) but few details or data from the study were provided.
Assessment of potential confounders | Smoking information obtained via questionnaire, no effect of smoking or use of oral snuff
Disease assessment | Cases of STS identified in cancer registry or hospital and histologically verified by site and type by independent pathologists (blinded to status of cases and controls) for two studies; only certain histopathological diagnosis included in other 2 studies. Questionable diagnosis of STS usually requires second opinion in Sweden
Ruder et al. (2009)
Related References | Ruder et al. (2004);Ruder et al. (2006); Carreón et al. (2005)
Geographic Location | U.S. (Iowa, Michigan, Minnesota, Wisconsin)
Population Characteristics
Cases: selection and ascertainment | [underlined: Cases]: 798 cases of brain glioma [underlined: Case eligibility criteria]: Histologically confirmed brain gliomas, ≥18 yr old diagnosed in 4 states 1995–1997 identified via participating medical facilities and neurosurgeons’ offices in 4 states and border city practices Cases with previous cancer other than glioma not excluded [underlined: Participation rate]: 91.5% eligible cases (or proxies) and 70.4% eligible controls (or proxies) completed questionnaires
Controls: selection and ascertainment | [underlined: Referents]: 1,175 [underlined: Referent eligibility criteria]: Residents as of Jan 1995 in a nonmetropolitan county in one of 4 states; eligible controls with previous cancer other than glioma not excluded; controls identified from DMV (18–64 yr olds) or HCFA records (65–80 yr olds) [underlined: Matching criteria]: 2 potential controls randomly matched per case on sex and within 10 yr of age at diagnosis of case
Study Design and Analytical Methods | Population-based case-control study Maximum likelihood unconditional logistic regression analysis No analysis for potential confounding
Exposure Data and Information Assessment
Exposure: levels and co-exposures | Levels of PCP NR No co-exposures reported for PCP-exposed subjects
Exposure assessment | Extensive self-reported questionnaire on farming practices, jobs on farm, crops, livestock, use of pesticides, fertilizers, solvents, wood preservatives
Assessment of potential confounders | No assessment of co-exposures or other potential confounders among PCP-exposed subjects (exposures and other risk factors compared for all cases and controls)
Disease assessment | Cases of brain glioma (ICD-O 2nd edition 938–948) identified via physicians, medical practices and neurosurgeons and histologically confirmed Missing data: comparison with state cancer registry data indicated 78% case ascertainment
Ward et al. (2009)
Related References | Ma et al. (2004)
Geographic Location | U.S. (35 counties in northern and central California) (Northern California Childhood Leukemia Study)
Population Characteristics
Cases: selection and ascertainment | [underlined: Cases]: 184 Acute lymphocytic leukemia (ALL) (2nd tier) included in the analysis [underlined: Case eligibility criteria]: ≤7 yr of age, diagnosed in December 1999. Cases were identified from 9 major pediatric clinical centers and who completed two tiered interviews and assessment. [underlined: Participation rate]: 86% <8 yr old for cases, and 88.5% for controls after 1st tier, and 92% cases and 80% controls after second tier.
Controls: selection and ascertainment | [underlined: Referents]: 212 (2nd tier) [underlined: Referent eligibility criteria]: selected from California birth certificate files. Survey found no evidence that the participating controls were different from the sampled population in terms of parental age, parental education, and mother's reproductive history (Ma et al. 2004) [underlined: Matching criteria]: individually matched on age, sex, race, Hispanic ethnicity, and material residence
Study Design and Analytical Methods | Case-control study of childhood leukemia (acute lymphoblastic leukemia, ALL). Evaluated quartiles of exposure (based on distribution in controls) of chemical concentration and chemical loading. Analysis adjusted for age, and race/ethnicity (non-Hispanic with, Hispanic, non-Hispanic other race), and confounding factors that changed ORs of ≥10% (income, yr, and season of the dust sample). Evaluated potential effect modification by breast-feeding status and maternal age.
Exposure Data and Information Assessment
Exposure: levels and co-exposures | Carpet concentrations (ng/g) ranged from <32 to 22,676
Exposure assessment | Residential exposure to PCP assessed via concentration in carpet dust. 1st tier – Interviews with primary provider on residential and parental occupational history; 2nd tier interviews, information on home and garden pesticide use, inventory pesticides in home storage, and obtained carpet dust samples PCP carpet dust concentrations converted to natural log; Chemical loading– amount of chemical/m^2^ of carpet – concentration × dust loading
Assessment of potential confounders | Interview Other chemicals (PCB and organochloride pesticides highly correlated)
Disease assessment | Newly diagnosed – prospectively ascertained; Although cases were identified from hospitals, a comparison with population-based cases obtained via registry found that 88% of the cases were identified from the hospital in a 3 yr period.

NHL = non-Hodgkin lymphoma; OR = odds ratio; DDT = dichlorodiphenyltrichloroethane; PCP = pentachlorophenol and by-products of its synthesis; NR = not reported; yr = year or years; N = number; HCL = hairy cell leukemia; STS = soft tissue sarcoma; DMV = Division of Motor Vehicles (U.S.); HCFA = Health Care Financing Administration (U.S.); ICD-O = International Classification of Diseases for Oncology; ALL = acute lymphocytic leukemia.

### C.1.1 Assessment of Potential Bias, Analytical Methods, and Other Study Quality Characteristics

Biases in observational studies are often classified into three major categories: (1) selection bias, (2) information bias, and (3) confounding (discussed in section 3.3.2). Studies with lower potential for bias are generally considered to be the most informative for cancer evaluation. However, the presence of a potential bias in a study does not necessarily mean that the findings of the study should be disregarded. Therefore, an important step in the process of evaluating biases is to determine the probable impact of the described biases on study results—that is, the magnitude of distortion and the direction in which each bias is likely to affect the outcome of interest (if known). The impact of the potential bias or confounding on the study findings is discussed in the cancer assessment (See Section 3.4).

For this review, overall conclusions on the concern for the potential (unlikely/minimal, possible or probable) of selection and information bias and the adequacy of other quality factors (good, adequate, or limited) for each study were made using the questions and guidelines outlined in the protocol (see https://ntp.niehs.nih.gov/NTP/roc/thirteenth/Protocols/PCPHumanStudies20130815_508.pdf. In some cases, there is insufficient information to evaluate the level of concern. The guidelines describe the ideal methods and design for each study element. The terms used for defining the potential for bias are as follows:

- Unlikely/minimal: Information from study designs and methodologies indicate that the potential for bias is unlikely or minimal and are close to the ideal study characteristics.
- Possible: Study designs or methodologies are close to but less than ideal, recognizing that in observational studies, there is almost always some methodological or informational limitation and thus some potential for certain types of bias.
- Probable: Study designs or methodologies suggest that the potential for a specific type of bias is likely.
- Unknown: Insufficient information is provided to enable an evaluation to be made.

If adequate information is available, each type of bias is also characterized as to whether it is differential or non-differential. Differential (systematic) biases in the selection of study participants or information assessment are related to both exposure and disease status and have the potential to bias findings in one direction or another, whereas non-differential (random) biases, which are not related to both exposure and disease, tend to reduce the precision of the risk estimates and often bias the findings toward the null. For example, occupational cohort studies may have limited exposure data across exposure groups, increasing the potential for non-differential exposure misclassification, and may also have the potential for a healthy worker (hire or survival) effect, a type of selection bias that tends to bias findings away from finding an effect (if present) in studies where the comparison group comes from the general population.

An overview of the approach and conclusions is discussed in Section 3.3 and details of the quality assessment are provided below in Table C-4.

Table C-4 Summary of Study Quality

Study | Selection/Participation Bias Attrition Bias (Loss to Follow-up) | PCP Exposure Assessment: Adequacy | Cancer Assessment: Adequacy | Ability to Detect an Effect and Analytical Methods: Adequacy
Cohort and nested case-control studies of PCP producers and users
Kogevinas et al. (1995) NHL, STS IARC registry-based nested-case control study | Selection/participation bias [underlined: Unlikely/minimal]: cohort members selected based on registry of workers and all cases of NHL and STS (and matched controls) identified from within cohort | Exposure characterization [underlined: Adequate]: exposure based on questionnaires, factory or spraying records; PCP exposure confined to member of one UK production cohort (N = 149) Exposure misclassification [underlined: Possible (non-differential)]: exposure assigned based on individual work history and characterization of plant exposure (defined above); ever exposed >1 day | Misclassification of deaths [underlined: Possible (non-differential]): death certificates use to determine underlying and contributing causes of deaths for 20 of the 32 NHL cases and 4 of the STS cases Misclassification of cases Unlikely/minimal ([underlined: non-differential)]: Additional cases (12 NHL and 7 STS) identified by cancer registry data. Histologic diagnosis available for most of the cancer cases. | Ability to detect an effect [underlined: Overall limited due to small number of cases] [underlined: Statistical power] ~26% (NHL) and <10% (STS) to detect 2-fold; few workers (145) exposed to chlorophenols or PCP in total cohort; information on exposure duration and levels not known Analysis [underlined: Adequate]: lagged external and internal analysis by categories of exposure; no analysis for potential confounding but no other herbicides were produced at the factory making PCP
Collins et al. (2009b); Ramlow et al. (1996) Michigan pentachlorophenol producers cohort mortality study | Selection bias [underlined: Possible]: All-cause and all-cancer mortality rates close to expected rates for population, but high % short-term workers may increase risk of HWE or HWSE Loss to follow-up [underlined: Unlikely/minimal]: no loss to follow-up reported | Exposure characterization [underlined: Good]: quantitative exposure assessment based on area samples, individual work histories, and serum profiles of chlorinated dioxins of past workers Exposure misclassification [underlined: Minimal]: for highest category of cumulative exposure to dioxins [underlined: Possible (non-differential)]: for lower cumulative categories to dioxins Individual workers assigned to cumulative exposure categories (ppt-yr) for chlorinated dioxins based on biomonitoring data (for subset of workers), occupational history, and pharmacokinetic modeling. Pharmacokinetic modeling of past dioxin exposure is less accurate for lower exposure categories. | Misclassification of deaths [underlined: Possible (non-differential)]: death certificates used to determine underlying cause of death Misclassification of cases [underlined: Possible (non-differential)]: mortality data may miss cases that do not result in death for cancers such as NHL, STS, MM, with longer survival | Ability to detect an effect: [underlined: Overall limited] [underlined: Statistical power]: approx. 37% NHL), 14%, (STS) and 29% (kidney) to detect 2-fold increase; [underlined: adequate] length of follow-up and level and range of estimated exposure to PCP, [underlined: limited exposure duration]: approx. 50% workers had <1 year cumulative exposure to PCP (Ramlow et al. 1996) Analysis [underlined: Good for some sites] external analysis only for most tumor sites; internal analyses by cumulative exposure for all cancers combined and 4 specific cancer sites only and for workers potentially exposed to combined PCP + TCP group only; no analysis of other potential confounders
Ruder and Yiin (2011) NIOSH pentachlorophenol producers cohort mortality study | Selection bias [underlined: Possible]: all-cause and all-cancer mortality rates close to expected rates for population, but high % short-term workers may increase risk of HWE Loss to follow-up [underlined: Unlikely/minimal]: 0.3% overall loss to follow-up | Exposure characterization: [underlined: Adequate]: some area, personal and wipe sampling conducted by investigators in each plant but insufficient data to compare PCP levels across departments/plants or create a JEM Exposure misclassification: [underlined: Possible (non-differential)]: individual work/job histories used to assign exposure category but no JEM or levels of exposure used | Misclassification of deaths [underlined: Possible (non-differential]): multiple sources used to ascertain vital status; death certificates from multiple sources used to determine causes of death Misclassification of cases [underlined: Possible (non-differential)]: mortality data may miss cases that do not result in death (see above) | Ability to detect an effect [underlined: Overall limited] Statistical power approx. 67% (NHL), 19% (STS) and 54% (kidney) statistical power to detect 2-fold increase in risk; [underlined: adequate] length of follow-up; [underlined: limited] employment duration of exposure in PCP dept.; mean ranged from 1.3 to 3.2 yr across plants Analysis Adequate for some sites (NHL, lung and all cancers combined); separate external mortality analyses for all tumor sites for PCP only and PCP + TCP groups; internal analyses by employment duration for combined cohort only and for lung cancer and NHL only; no analyses of other potential confounders
Demers et al. (2006) Canadian sawmill workers cohort incidence and mortality study | Selection bias: [underlined: unlikely/minimal;] all-cause and all-cancer incidence rates same as expected rates for population Loss to follow-up bias [underlined: unlikely/minimal;] loss to follow-up 4% deaths and <0.1 for incidence | Exposure characterization [underlined: Good]: dermal exposure predominant; historical exposure estimated using formulations of fungicide (PCP/TeCP) used at different time periods, mill records and experts; urine PCP levels available on subset of workers Exposure misclassification [underlined: Unlikely/minimal (non-differential)]: Exposure categories (dermal, 1 FTE year = 2,000 hr. exposure) assigned using detailed work history for each cohort member and industrial hygiene information described above; expert assessment validated by urine PCP levels in sample of workers | Misclassification of deaths: [underlined: Possible (non-differential]); multiple sources used to ascertain vital status and provincial and national mortality databases used to ascertain cause of death Misclassification of cases [underlined: Unlikely/minimal (non-differential)]: British Columbia cancer registry or Canadian cancer registry used to identify cases; incidence data more reliable and informative for some cancers e.g., NHL, STS, MM; STS cases histologically confirmed | Ability to detect an effect [underlined: Overall good] Statistical power: approx. power 99% (NHL), 67% (STS) and 99% (kidney) to detect 2-fold increase in risk cancer incidence; [underlined: adequate] length of follow-up, employment duration (mean 9.8 yr) and range of estimated exposure to PCP Analysis [underlined: Good] external and internal analyses including exposure-response analyses lagged for 10 and 20 years. Separate analysis of major co-exposure (TeCP). Some information on smoking
Ecological study of pentachlorophenol exposure
Zheng et al. (2015) Chinese ecological exposure assessment incidence study | Selection bias Insufficient information to evaluate quality and completeness of cancer registry data in the different areas of the study district | Exposure characterization [underlined: Inadequate]: aggregate residential exposure assessed indirectly using data on cumulative amount of PCP spraying across study area Exposure misclassification [underlined: Probable (not clear if differential or non-differential);] no data on length of residence, occupations, or likelihood of exposure | Misclassification of cases [underlined: Possible (non-differential)]: completeness and accuracy of cancer registry data unknown | Ability to detect an effect Cannot be determined based on limited data reported Analysis [underlined: Inadequate]: reporting of 2-year cancer rates for district qualitatively compared with world population rates (not vs. Chinese population); in internal comparison of medium and high exposure vs. low exposure areas and length of exposure, no data on the relative size and demographics of population at risk in each exposure category (level or duration of exposure) was provided
Population-based case-control studies of pentachlorophenol users
Hardell et al. (1994) NHL Swedish 1994 NHL study | Selection bias [underlined: Unlikely/minimal]: cases and control selected from the same population base independent of exposure status; 0.5% (all controls) did not complete exposure questionnaire | Exposure characterization [underlined: Limited]: expert review of self-reported (work histories and other exposures), minimum exposure duration (“high grade”) ≥1 week (continuous) or ≥1 month (total) Exposure misclassification [underlined: Probable (non-differential)]: reliance on self-report or proxies (for deceased cases and controls), supplemented by interviews; interviewer blind to case status; questionnaire reported to be verified by employers but no details on validation study | Misclassification of cases [underlined: Unlikely/minimal (non-differential)]: use of local hospital registry for cases and national registry for death certificates; cases histologically confirmed | Ability to detect an effect: [underlined: Overall limited] Statistical power: approx. 26% power to detect 2-fold increase in risk for NHL incidence in association with PCP; exposure prevalence; 14.3% (cases), 2.7% (controls); no data on exposure levels, duration, or range of exposure Analysis [underlined: Limited/Adequate (confounding)]: OR for PCP by one (high exposure) category lagged by 1 year; multivariate analysis of chlorophenols (mostly PCP) controlling for exposure to phenoxyacetic acids and solvents.
Hardell and Eriksson (1999) NHL;Hardell et al. (2002) (Combined HCL and NHL) Swedish 1994 NHL case-control study | Selection/participation bias [underlined: Unlikely/minimal]: cases and control selected from the same population base independent of exposure status; all cases reported to regional cancer registries eligible; 91% of cases and 84% controls (or proxies) completed exposure questionnaire; interviewers blinded to case status | Exposure characterization [underlined: Limited]: expert review of self-reported (work histories and other exposures), minimum exposure duration Exposure misclassification [underlined: Probable (non-differential)]: reliance on self-report or proxies (for deceased cases and controls), supplemented by interviews; interviewer blind to case status | Misclassification of cases [underlined: Unlikely/minimal (non-differential)]: use of regional cancer registry for cases and national registry for deaths; cases histologically confirmed and re-reviewed by authors | Ability to detect an effect [underlined: Overall limited]: Statistical power (pooled analysis): approx. 99% power to detect 2-fold increase in risk for NHL incidence in association with PCP; exposure prevalence 13.7% cases; 11.7% controls; no data on exposure levels, duration, or range of exposure Analysis [underlined: Limited (1999)]: OR for ever exposed (presumably 1 day minimum based on previous study methods) and time since first and last exposure but not by level or duration, no adjustment for potential confounding in 1999, multivariate analysis adjusted for impregnating agents (60% of which are PCP) for 2002
Nordström et al. (1998) HCL; Hardell et al. (2002) (Combined HCL and NHL) Swedish HCL case-control study | Selection/participation bias: [underlined: Unlikely/minimal]: cases (cancer registries) and controls (population registries) selected from the same population independent of exposure status; appears all cases reported to cancer registry eligible; 91% cases and 83% population controls completed questionnaires | Exposure characterization [underlined: Limited]: expert review of self-reported (work histories and other exposures); minimum exposure of 1 day and 1 year induction Exposure misclassification [underlined: Probable (non-differential)]: reliance on self-report, supplemented by interviews; interviewer blind to case status | Misclassification of cases [underlined: Possible (non-differential)]: histological or pathological verification of diagnosis not specified | Ability to detect an effect [underlined: Overall limited] Statistical power: approx. 39% power to detect 2-fold increase in risk for HCL incidence in association with PCP; exposure prevalence: 8.1% (cases), 3.5% (controls); no data on exposure levels, duration, or range of exposure Analysis [underlined: Limited]: OR for PCP subset of “impregnating agents”-exposed group only; multivariate analysis and analysis by 2 categories of exposure duration conducted for “impregnating agents” group only; no analysis of potential confounders
Hardell et al. (1995)^a^ STS Swedish pooled analysis of STS case-control studies | Selection/participation bias [underlined: Unlikely/minimal;] cases (cancer registries) and controls (population registries) selected from the same population base independent of exposure status; refusal to participate (complete questionnaire) varied between <1.0% to 10% in the individual studies | Exposure characterization [underlined: Limited]: expert review of self-reported (work histories and other exposures), minimum exposure duration (“high grade”) ≥1 week (continuous) or ≥1 month (total) Exposure misclassification [underlined: Probable (non-differential)]: reliance on self-report or proxies (for deceased cases and controls), supplemented by interviews; interviewer blind to case status; questionnaire reported to be verified by employers but no details on validation study | Misclassification of cases [underlined: Unlikely/minimal (non-differential)]: cases identified via regional cancer registries and national mortality data, histologically confirmed by pathologist and medical records | Ability to detect an effect: Overall low [underlined: Statistical power]: approx. 96% power to detect <2-fold increase in risk for STS; low exposure prevalence and limited exposure information: no data on exposure levels, duration, or range of exposure Analysis [underlined: Limited]: OR for PCP exposure for any duration of exposure only and no analysis for potential confounding

PCP = pentachlorophenol and by-products of its synthesis; NHL = non-Hodgkin lymphoma; STS = soft tissue sarcoma; IARC = International Agency for Research on Cancer; HWE = healthy worker (hire or survival) effect; ppt = parts per trillion; yr = year or years; MM = multiple myeloma; TCP = 2,4,5-trichlorophenol; NIOSH = National Institute for Occupational Safety and Health (U.S.); JEM = job exposure matrix; TeCP = tetrachlorophenol; FTE = full-time equivalent; HCL = hairy cell leukemia; OR = odds ratio.