# Appendix B Human Exposure and Regulations and Guidelines

Table B-1 U.S. Pentachlorophenol Manufacturing Plants: Air and Wipe Samples^a^

Location (Reference) | Job Type/Area (Years) | Sample Type (N) | Conc. Range [TWA range] (mg/m^3^)
Wichita, KS Marlow and Fingerhut (1985a)^b^ | Production, flaking (1980–1983) | Air, area (74) Air, personal breathing zone^c^ (118) First class penta operator (45) Third class penta operator (73) | <0.01–0.85^d^ [<0.01–0.85] 0.005–0.84 [0.005–0.84] <0.006–4.65 [<0.006–3.17]
Tacoma, WA Marlow and Fingerhut (1985b) | Production, prilling, blocking (1983) | Air, area (18) Air, personal breathing zone (28) (Highest value reported for maintenance man) | <0.01–0.07 [0.01–0.058] <0.01–71.21 [0.02–36.06]
U.S. PCP manuf. plant, location not specified Marlow (1986) | Production, distillation, finishing (–) | Air, personal breathing zone (54) (Range of means; highest value reported for handyman) | 0.059–2.66 [–]
Midland, MI Marlow et al. (1991) | Production, distillation, finishing, flaking (1965–1980) | Air, area (238) (Highest value reported for chlorination, torch burning) Air, personal (150) (Highest value reported for handyman) | 0.003–68.69 [–] 0.006–33 [–]
Sauget, IL Marlow et al. (1997) | Production, flaking, prilling, blocking (1977) | Air, area (2) Air, personal (6) | <0.001–0.026 [–] <0.001–0.14 [–]
Sauget, IL Marlow et al. (1997) | Production, flaking, prilling, blocking (1977) | Wipes - set 1 (7)^e^ Wipes - set 2 (7) | 12.5–216 µg/100 cm^2^ 1.4–15.1 µg/100 cm^2^

^a^ A subset of these data were also reported by Ruder and Yiin (2011).

^b^ Data shown does not include samplings prior to 1980, which used a different sampling method and results were deemed unreliable; results from all methods used after 1980 are included here. Time-weighted averages (TWA) are shown if included in report.

^c^ First class operators take samples from the primary and secondary chlorinators; third class operators clean the flaker, load flaked pentachlorophenol into the kiln, bag box and load glazed pentachlorophenol into trailers and hopper cars, and other general housekeeping duties.

^d^ Only representative areas and job types are included from the report. Highest level in area air was in ‘Penta bagging house’ where glazed pentachlorophenol flakes are packaged, i.e., taken from bulk storage to a hopper and gravity fed into a specially designed bag on a pneumatic-operated machine.

^e^ Wipes: first set of samples was in April and second set in August, after institution of more stringent industrial hygiene practices.

Table B-2 Blood and Urine Pentachlorophenol Levels for Wood Treatment Workers

Reference | Type of Job | | Number of Workers | Concentration in Blood (ppm), Mean (Range) | | Concentration in Urine (ppm), Mean (Range)
Cline et al. (1989) | Wood preservation | | 6 | Serum | 0.490 (0.250–0.740) | –
Cline et al. (1989) | Chemical packaging | | 4 | Serum^a^ | 57.6 (21.7–84.9) | –
Cline et al. (1989) | Chemical packaging | | 4 | Whole blood | 25.1 (8.6–45.2) | –
Cline et al. (1989) | Chemical packaging | | 6 | Whole blood | 15.9 (6–23) | –
McLean et al. (2009b) | Sawmill workers | Mixers | 8 | – | – | 2.8 mg/L^b,c^ (0.14–13)
McLean et al. (2009b) | Sawmill workers | Table hands | 48 | – | – | 0.21 mg/L^b,c^ (0.005–2.2)
McLean et al. (2009b) | Sawmill workers | Diffusion plant, ordermen, graders, yardhands | 49 | – | – | 0.05 mg/L^b,c^ (0.004–0.73)
McLean et al. (2009b) | Sawmill workers | Green and dry milling, drivers of mobile plant | 59 | – | – | 0.01 mg/L^b,c^ (<0.002–0.44)
Gunter and Thoburn (1980) | Manufacturing: wood fence posts and poles | | 9 | – | – | –
Markel et al. (1977) | Wood treatment: railroad ties, telephone poles | | 11 | – | – | – (<0.010–5.2)
Markel and Lucas (1975) | Wood treatment: lumber, fence posts | | 17 | – | – | 0.49^c^ (0.11–1.85)
Markel and Lucas (1975) | Wood treatment: timber | | 6 | Serum | 1.372 (0.348–3.963) | 0.164 (0.041–0.760)

^a^ These chemical workers are described in Cline et al. (1989) as formulating and packaging pentachlorophenol under very unsafe conditions. A worker in a different packaging plant with 23 ppm pentachlorophenol in whole blood died after breaking up blocks of pentachlorophenol using a jack hammer and other tools without adequate protective clothing.

^b^ Geometric mean. All other means are arithmetic means unless stated otherwise.

^c^ Values in McLean et al. (2009b) reported in mg/L.

Table B-3 Levels of Pentachlorophenol in Blood and Urine of Various Handlers and Users of Pentachlorophenol-treated Wood

Reference | Type of Job | Number of Workers | Concentration in Blood (ppm) Mean (Range) | | Concentration in Urine Mean ± SD (Range); Median
Cline et al. (1989) | Log home construction | 2 | Serum | 0.083 (0.072–0.094) | –
Cline et al. (1989) | Telephone line maintenance | 13 | Serum | 0.110 (0.026–0.260) | –
Cline et al. (1989) | Log museum | 4 | Serum | 0.450 (0.350–0.630) | –
Bader et al. (2007) | Painters | 189 | – | – | 5.6 ± 8.1 (<0.2–52); 2.4 (µg/g creatinine)
Bader et al. (2007) | Bricklayers | 148 | – | – | 3.2 ± 3.9 (<0.2–25); 1.8 (µg/g creatinine)
Thind et al. (1991) | Electrical utility linemen^a^ | Exposed 23 Control 5 | – | – | Exposed: 29.6 ± 1.74 Control: 10.2 ± 1.74 (6–26) (µg/g creatinine)

SD = standard deviation.

^a^ Two groups of linemen were based on required glove use (Group A) and ‘as needed’ glove use (Group B); groups were combined for comparison of all workers with controls (administrative staff not occupationally exposed).

^b^ Geometric means and standard deviations were provided in study.

Table B-4 Pentachlorophenol Concentration in Serum and Urine Samples in People Living in the United States between 1967 and 2003 (Tables SI-7 and SI-8 from Zheng et al. (2011))

Country/Location (Year of Data Collection) | Exposure | Sample Type | N | PCP Concentration, Mean, µg/L (Range) | Reference
USA (1980) | PCP-treated log homes | Serum | 5 32 | 1,126 (580–1,750) 330 (116–1,084) | Hernandez and Strassman (1980)
USA (1980) | Control group | Serum | 32 | 320 (2–7,200) | Klemmer et al. (1980)
USA (1980) | Control group Untreated log homes Conventional homes | Serum | 42 2 11 | – (4–68) 51 (34–75) 48 (15–55) | WHO (1987)
USA (1980) | Conventional homes PCP-treated log homes | Serum | 34 123 | 37 (15–75) 300 (69–1,340) | Cline et al. (1989)
USA (1967) | Households & pesticide users Honolulu heart program cohort | Urine | 117 173 | 40 (ND–1,840) 44 (3–570) | Bevenue et al. (1967)
USA (1970) | Non-specific exposure | | 6 | 5 (2–11) | Cranmer and Freal (1970)
USA (1978) | Human monitoring program | | 418 | 6.3 (ND–193) | WHO (1987)
USA (1980) | PCP-treated log homes PCP-treated log homes Control group Untreated log homes Conventional homes | | 5 32 42 2 11 | 84 (47–216) 13 (2–87) – (0.7–11) 1.4 (1–2) 2.5 (1–7) | Hernandez and Strassman (1980)
USA (1980) | Non-occupational exposure^a^ | | 32 | 30 (<10–1,000) | Klemmer et al. (1980)
USA (1981) | Non-occupational exposure | | 10 | 9 (3–16) | WHO (1987)
USA (1981) | Non-occupational exposure (controls) Non-occupational exposure (controls) | | 38 31 | 24.2 (3–106) 19 (3–105) | Kalman (1984)
USA (1981) | Non-specific exposure (control subjects) | | 10 | 8.2 (3–16) | Lores et al. (1981)
USA (1982) | Non-occupational exposure Non-occupational exposure | | 23 22 | 25.3 (10–108) 32.2 (15–137) | Kalman (1984)
USA (1980–6) | Conventional homes PCP-treated homes | | 143 118 | 2.7 (–) 37 (1–340) | Cline et al. (1989)
USA (1989) | Community around herbicide plant (children) | | 197 | 14^b^ (>1–240) | Hill et al. (1989)
USA (1994) | Non-specific exposure | | 87 | 1.6 (0.5–9.1) | Thompson and Treble (1994)
USA (1995) | NHANES III^c^ | | 951 | 2.5 (ND–55) | Hill et al. (1995)
USA (1997) | Non-specific exposure (children) | | 9 | 0.329 (0.175–0.666) | Wilson et al. (2003)
USA (1998–2001) | Local fatty fish consumption | | 361 | 7^b^ (1–52)^d^ | Berkowitz et al. (2003)
USA (2001) | Non-specific exposure (children) Non-specific exposure (children) | | 128 126 | 0.433 (<0.262–3.45) 0.876 (<0.536–23.8) | Wilson et al. (2007)
USA (2003) | Environmental exposure (fetus-amniotic fluid) | | 20 | 0.23 (0.15–0.54) | Bradman et al. (2003)

^a^ Control group for Klemmer et al. (1980) described as workers without occupational exposure; no other exposure information was presented for control group.

^b^ Median.

^c^ National Health and Nutrition Examination Survey.

^d^ Percentile range: 10%–90%.

Table B-5 Pentachlorophenol Ambient Air Levels

Country | Location/Sample | Mean Concentration, ng/m^3^ | Concentration Range, ng/m^3^ | Reference
Industrial Settings
United States | Wood treatment facility fence line | – | 29,000 (max) | ATSDR (2007)
United States | Residence within 1 mile of wood treatment facility | – | 8,100 (max) | ATSDR (2007)
Urban settings
United States | Raleigh-Durham-Chapel Hill, NC | – | ND–52.1 | Wilson et al. (2007)
Belgium | Urban area | – | 5.7–7.8 | Cautreels et al. (1977) ^a^
Canada | White City | 217.0 | 0.7–1,233 | Waite et al. (1998)
Canada | Prince Albert | 2.4 | 6.8 (max) | Waite et al. (1998)
Canada | Yellowknife | 1.7 | 4.2 (max) | Waite et al. (1998)
Rural settings
Bolivia | Mountain rural area | – | 0.25–0.93 | Cautreels et al. (1977) ^a^
Canada | Agriculture and Agri-Food Canada Research Station | 0.4 | 0.6 (max) | Waite et al. (1998)
Canada | Waskesiu | 0.7 | 1.5 (max) | Waite et al. (1998)
Urban/rural/industrial setting not specified
Canada | – | 0.64^b^ | 0.30–0.87^c^ | Environment Canada (1990) ^d^
Switzerland | – | – | 0.9–5.1 | Bundesamt für Umweltschutz (1983) ^a^

All means are arithmetic means unless noted otherwise.

ND = not detected.

^a^ As cited in WHO (1987).

^b^ Grand mean of data sets for ambient air levels from a review of pentachlorophenol concentration data in published and unpublished reports for the period 1981–1990, weighted by sample size.

^c^ Range of means from data sets for ambient air levels from a review of pentachlorophenol concentration data in published and unpublished reports for the period 1981–1990.

^d^ As cited in Coad and Newhook (1992).

Table B-6 Pentachlorophenol Indoor Air Levels

Country | Location/Sample | | Mean Concentration, ng/m^3^ | Concentration Range, ng/m^3^ | Reference
United States | Pentachlorophenol-treated log home in Kentucky, 1980 | | – | 200–380 | Hernandez and Strassman (1980)
United States | Twenty-one pentachlorophenol-treated log homes in Kentucky, 1984 | | 80^a^ | 3–810 | Hosenfeld (1986)
United States | Fifteen pentachlorophenol-treated log homes in Montana | | – | <7,000^b^ | Lee and Gunter (1986)
United States | Indoor air in two child day care centers (1997, Raleigh-Durham, NC)^c^ | | 0.918 | 0.740–1.18 | Wilson et al. (2003)
United States | Indoor air in day care centers (2001–2002, coastal plain, Piedmont, and mountain regions, NC) | | 1.16^d^ | 0.500–63.3 | Wilson et al. (2007)
United States | Indoor air in day care centers (2001–2002, northern, central, and southern regions, OH) | | 1.32^d^ | BDL–16.8 | Wilson et al. (2007)
United States | Indoor air at homes of nine children (1997, Raleigh-Durham, NC) | | 9.11^e^ | 0.660–53.2 | Wilson et al. (2003)
United States | Indoor air in children’s homes (2001–2002, coastal plain, Piedmont, and mountain regions, NC) | | 1.5^d^ | BDL–27.5 | Wilson et al. (2007)
United States | Indoor air in children’s homes (2001–2002, northern, central, and southern regions, OH) | | 2.14^d^ | BDL–73.3 | Wilson et al. (2007)
United States | Basement of a building with highest ratio of treated wood surface area to room volume (no ventilation) among a group of treated wooden structures | | – | 38,000 (max)^f^ | Saur et al. (1982) ^h^
United States | Nine homes in Raleigh-Durham, NC | | 50^g^ | 290 (max) | Lewis et al. (1994)
Germany | Indoor air samples in 104 homes | | – | ND–25,000 | Krause and Englert (1980)^h^, Aurand et al. (1981)^h^, and Krause (1982)^h^
Germany | Living room of house containing pentachlorophenol-treated wood | | – | 50,000–100,000 | Gebefügi et al. (1979) ^h^
Germany | Building with an enclosed swimming pool with pentachlorophenol-treated walls and ceilings | | – | 1,000–160,000 | Gebefügi (1981); Gebefügi et al. (1983)^h^
Germany | Indoor air samples | | – | <0.3–576.4 | Schnelle-Kreis et al. (2000)
Netherlands | Family A, home with pentachlorophenol-treated timber and furniture, before house was heated and ventilated | | – | 140–1,200 | Sangster et al. (1982)
Netherlands | Family A, home with pentachlorophenol-treated timber and furniture, after house was heated and ventilated | | – | ND–240 | Sangster et al. (1982)
Netherlands | Family B, home with pentachlorophenol-treated timber in basement | | – | ND–400^h^ | Sangster et al. (1982)
Netherlands | Family C, restored home with pentachlorophenol-treated timber | | – | 440–950 | Sangster et al. (1982)
Switzerland | Home living rooms and bedrooms | | – | 1,000–10,000 | Zimmerli et al. (1979) ^i^
United Kingdom | House with pentachlorophenol-treated roof void, first week after treatment | In roof void | – | 16,000–67,000 | Dobbs and Williams (1983) ^i^
United Kingdom | House with pentachlorophenol-treated roof void, first week after treatment | In landing | – | 3,900–15,000 | Dobbs and Williams (1983) ^i^
United Kingdom | House with pentachlorophenol-treated roof void, first week after treatment | In bedroom | – | 1,600–2,800 | Dobbs and Williams (1983) ^i^
United Kingdom | House with pentachlorophenol-treated roof void, 5–10 weeks after treatment | In roof void | – | 1,700–6,700 | Dobbs and Williams (1983) ^i^
United Kingdom | House with pentachlorophenol-treated roof void, 5–10 weeks after treatment | In landing | – | 600–5,000 | Dobbs and Williams (1983) ^i^
United Kingdom | House with pentachlorophenol-treated roof void, 5–10 weeks after treatment | In bedroom^j^ | – | 1,600–2,800 | Dobbs and Williams (1983) ^i^

ND = not detected; BDL = below detection limit.

^a^ Geometric mean. Unless noted otherwise, all other mean values are arithmetic means.

^b^ Reported as <7 µg/m^3^.

^c^ Two air samples averaged over 48 hours at each of the two day care centers.

^d^ 50th percentile.

^e^ One air sample averaged over 48 hours at each of the nine homes.

^f^ The pentachlorophenol level in the main floor of this house was 8.8 µg/m^3^, and the pentachlorophenol level in a warehouse was 3.52 µg/m^3^; these levels were higher than levels in 11 other rooms in different buildings evaluated in Saur et al. (1982) (as cited in WHO (1987)).

^g^ Two air samples were taken simultaneously at 12 and 75 cm above the floor. Result reported is the arithmetic mean of the two individual samples; individual sample values, though described as generally similar, were not reported.

^h^ Reported with “±” in Sangster et al. (1982) but all other measurements were reported in µg/m^3^.

^i^ As cited in WHO (1987).

^j^ Concentrations in or near the treated room rapidly decreased, but levels in the untreated bedroom remained stable, possibly due to adsorption and desorption processes.

Table B-7 Pentachlorophenol in Air and Urine – Other Occupational Exposures (Exposed Workers in a NIOSH HETA Report)

Location (Source) | Type of Job | Number of Workers | TWA Range of Concentrations in Air (mg/m^3^) | Concentrations in Urine^a^ (ppm) # Samples - Mean (Range) | # Wipe Samples Mean (Range) ng/cm^2^
Fort Stanwix National Monument – Rome, NY Rosensteel (1978) | Park office staff (exposure to treated walls of office) | 5 | Area - two methods^b^: #1: 0.014–0.033 #2: 0.022–0.187 | 5 - Workers (1.4–4.2) 2 - Controls (<0.8, 0.9) | NT
Follow-up Study Fort Stanwix National Monument – Rome, NY Lee and Lucas (1983) | Park office staff (exposure to treated walls of office) | 6 | Area - all sampled locations were below LOD (<0.008) | 6 - Workers (<0.004–0.0163) 4 - Controls (all <0.004) LOD = 0.004 | 6 - Personal (hand) <10–70 3 - Work surface <10–70 LOD = 10

HETA = Hazard Evaluation and Technical Assistance; LOD = limit of detection; NT = not tested.

^a^ Corrected to specific gravity of 1.024.

^b^ Used two different methods of air sampling.

Table B-8 Measurements of Pentachlorophenol in Soil

Country | Location/Sample | | Mean Concentration, µg/kg | Concentration Range, µg/kg | Reference
United States | LA, wood treatment facility (NPL site) | Soil depth of 0–3 in | – | 320–2,300 | ATSDR (1995) ^a^
United States | LA, wood treatment facility (NPL site) | Subsurface soil | – | 820–200,000 | ATSDR (1995) ^a^
United States | FL, inactive landfill (NPL site) | | – | 21,000 (max) | ATSDR (1993b) ^a^
United States | GA, wood preserving company | On-site samples | – | 13,000 (max) | Anonymous (1999) ^a^
United States | GA, wood preserving company | Off-site samples | – | 1,300 (max) | Anonymous (1999) ^a^
Canada | Former site of a pesticide plant | | – | <50 | Garrett (1980) ^b^
Finland | Sawmills, location unspecified | Soil depth of 0–5 cm, near trtmnt. basin | – | 45,600^c^ | Valo et al. (1984) ^b^
Finland | Sawmills, location unspecified | Soil depth of 80–100 cm, near trtmnt. basin | – | 1,000^c^ | Valo et al. (1984) ^b^
Finland | Sawmills, location unspecified | In storage area for preserved wood | – | 140 (max)^c^ | Valo et al. (1984) ^b^
Finland | Sawmills, location unspecified | Outside of storage area for preserved wood | – | 12^c^ | Valo et al. (1984) ^b^
Germany | Agriculturally used soils in Bavaria | | – | 100 | Gebefügi (1981) ^b^
Switzerland | Four sites near a penta-chlorophenol production facility | Soil depth of 0–10 cm | – | 25–140 | Bundesamt für Umweltschutz (1983) ^b^
Switzerland | Four sites near a penta-chlorophenol production facility | Soil depth of 20–30 cm | – | 33–184 | Bundesamt für Umweltschutz (1983) ^b^

NPL = National Priorities List.

^a^ As cited in ATSDR (2001).

^b^ As cited in WHO (1987).

^c^ Reported as a fresh weight sample.

Table B-9 Measurements of Pentachlorophenol in Food

Country | Type of Sample/Frequency of Detection | Mean Concentration, µg/kg | Concentration Range, µg/kg | Reference
United States | 10 out of 60 composite food samples (1973–4) | – | 10–30 | Manske and Johnson (1977) ^a^
United States | 5.4% of 240 samples | – | 10–40 | Johnson and Manske (1977) ^a^
Canada | Fish | 5.9^b^ [N = 36]^c^ | 0.2–24.0^d^ | Coad and Newhook (1992) ^e^
Canada | Shellfish | 2.6 [N = 14]^f^ | 0.1–20.2 | Coad and Newhook (1992) ^e^
Canada | Milk | 0.6^g^ [N = 1] | <0.38–2.53^h^ | Coad and Newhook (1992) ^e^
Canada | Beef | 0.6 [N = 6] | 0.47–3.2 | Coad and Newhook (1992) ^e^
Canada | Pork | 0.8 [N = 3]^f^ | 0.54–2.70 | Coad and Newhook (1992) ^e^
Canada | Lamb | 0.4 [N = 2] | 0.3–1.1 | Coad and Newhook (1992) ^e^
Canada | Poultry | 0.9 [N = 4]^f^ | 0.1–4.9 | Coad and Newhook (1992) ^e^
Canada | Offal | 32.0 [N = 27]^f^ | <1.0–79.0 | Coad and Newhook (1992) ^e^
Canada | Eggs | 2.7 [N = 4] | 0.03–2.82 | Coad and Newhook (1992) ^e^
Canada | Grains and cereals | 2.5 [N = 2] | 0.22–4.80 | Coad and Newhook (1992) ^e^
Canada | Root vegetables | 0.8 [N = 3] | 0.36–1.4 | Coad and Newhook (1992) ^e^
Canada | Garden vegetables | 0.5 [N = 2] | 0.44–0.55 | Coad and Newhook (1992) ^e^
Canada | Fruit | 0.4 [N = 7] | 0.20–4.8 | Coad and Newhook (1992) ^e^
Canada | Sugars and adjuncts | 2.3 [N = 8] | 0.8–5.6 | Coad and Newhook (1992) ^e^
Canada | Oils and fats | 4.2 [N = 7] | 2.2–5.7 | Coad and Newhook (1992) ^e^
Canada | Soups, juices, and beverages | 0.2 [N = 24] | 0.1–0.8 | Coad and Newhook (1992) ^e^
Canada | Produce samples consisting mainly of potatoes and raw milk | – | <10 | Jones (1981)
Canada | Isolated produce samples stored in containers made of treated wood | – | 2,700 | Jones (1981)
Canada | Chicken meat | 10 | – | Ryan et al. (1985) ^i^
Canada | Pork liver | 50 | – | Ryan et al. (1985) ^i^ Crosby et al. (1981)
Canada | Marine fish | 5 | 3–8.3 | Ryan et al. (1985) ^i^ Crosby et al. (1981)
Canada | Potatoes | – | ND–0.043 | Crosby et al. (1981) Ministry of Agriculture Fisheries and Food (1989) ^i^
Canada | Grain cereal | 0.001 | – | Crosby et al. (1981) Ministry of Agriculture Fisheries and Food (1989) ^i^
Canada | Poultry | 9 | ND–40 | Crosby et al. (1981) Ministry of Agriculture Fisheries and Food (1989) ^i^
United Kingdom | Eggs | 60 | ND–300 | Ministry of Agriculture Fisheries and Food (1989) ^i^ Gebefügi (1981) ^a^
United Kingdom | Milk | 4 | ND–20 | Ministry of Agriculture Fisheries and Food (1989) ^i^ Gebefügi (1981) ^a^
United Kingdom | Daily diet samples | 16.3^j^ | 2.6–27.5 | Ministry of Agriculture Fisheries and Food (1989) ^i^ Gebefügi (1981) ^a^
Germany | Two-thirds of food basket samples of persons applying wood preservatives in private homes | 6^k^ | 2–13^l^ | Krause (1982) ^a^
Germany | 11 out of 17 fresh mushroom samples | – | >10 | Meemken et al. (1982) ^a^

^a^ As cited in WHO (1987).

^b^ Grand mean weighted by sample size unless noted otherwise for Coad and Newhook 1992.

^c^ N = number of data sets.

^d^ Range of calculated means unless noted otherwise for Coad and Newhook (1992).

^e^ Coad and Newhook (1992) cites original study authors for data for pentachlorophenol levels in food. All food commodities are expressed on a wet weight basis.

^f^ Some data sets include means where non-detected values equal to zero are included because detection limits were not specified or number of samples with non-detected values was not specified.

^g^ Reported as sample mean.

^h^ Reported as sample range.

^i^ As cited in Wild and Jones (1992).

^j^ Arithmetic average.

^k^ Median.

^l^ Control samples were between <0.1 and 5 µg/kg.

Table B-10 Measurements of Pentachlorophenol in Drinking Water, Ground and Surface Water

Country | Location/Sample | Mean Concentration, µg/L | Concentration Range, µg/L | Reference
Drinking water
United States | Domestic well water, Oroville, CA | – | <1–50 | Wong and Crosby (1981) ^a^
United States | Willamette River | – | 0.06^b^ | Buhler et al. (1973) ^a^
United States | Florida drinking water | – | 0.003–0.34 | Morgade et al. (1980) ^a^
Germany | Ruhr area | – | 0.01–0.02 | Dietz and Traud (1978) ^a^
Unspecified | Unspecified | – | 0.1^b^ | Dougherty and Piotrowska (1976) ^a^
Groundwater
United States | SC wood preserving site | – | 19,000 (max) | ATSDR (1993a) ^c^
United States | Inactive FL landfill | – | 0.6^b^ | ATSDR (1993b) ^c^
United States | GA wood preserving company | – | 4,300 (max) | Anonymous (1999)
United States | Wood preservation plant near Lake Superior | – | 2,050–3,350 | Thompson et al. (1978) ^a^
Surface water
United States | Willamette River | – | 0.1–0.7 | Buhler et al. (1973) ^c^
United States | Great Lakes | – | 0.1–1 | USEPA (1980) ^c^
United States | Sewage discharge site in Sacramento, CA | – | <1 | Wong and Crosby (1978) ^c^
United States | Stream running through industrial district in PA | – | 38–10,500 | Fountaine et al. (1976) ^c^
United States | Streams in HI | – | 0.01–0.48 | Young et al. (1976) ^c^
United States | Estuary in Galveston Bay, TX | – | ND–0.01 | Murray et al. (1981) ^a^
United States | Pond in MS contaminated by waste from pole treatment plant | – | <1–82 | Pierce et al. (1977) ^a^
Canada | British Columbia freshwater sites | – | Trace–0.3 | Environment Canada (1979) ^a^
Canada | British Columbia marine sites | – | ND–7.3 | Environment Canada (1979) ^a^
Germany | Weser River and estuary | – | 0.05–0.5 | Ernst and Weber (1978) ^a^
Germany | German Bight | – | <0.002–0.026 | Ernst and Weber (1978) ^a^
Germany | Ruhr river | 0.1^d^ | <0.1–0.2 | Dietz and Traud (1978) ^a^
Germany | Rhine River, Cologne | – | 0.1^b^ | Fischer and Slemrova (1978) ^a^
Japan | Tama River, Tokyo | – | 0.01–0.9 | Matsumoto et al. (1977) ^a^
Japan | Sumida River, Tokyo | – | 1–9 | Matsumoto et al. (1977) ^a^
Japan | River water, Tokyo area | – | 0.18 ± 0.14 | Matsumoto (1982) ^a^
Netherlands | Rhine River, 1976 | 0.7^d^ | 2.4 (max) | Wegman and Hofstee (1979) ^a^
Netherlands | Rhine River, 1977 | 1.1^d^ | 11 (max) | Wegman and Hofstee (1979) ^a^
Netherlands | River Meuse, 1976 | 0.3^d^ | 1.4 (max) | Wegman and Hofstee (1979) ^a^
Netherlands | River Meuse, 1977 | 0.8^d^ | 10 (max) | Wegman and Hofstee (1979) ^a^
South Africa | 124 sampling points, location unspecified | – | ND–0.85 | van Rensburg (1981) ^a^
Sweden | River water downstream from pulp mill | – | 9^b^ | Rudling (1970) ^a^
Sweden | Lake receiving discharges | – | 3^b^ | Rudling (1970) ^a^

^a^ As cited in WHO (1987).

^b^ Only 1 value was reported.

^c^ As cited in ATSDR (2001).

^d^ Arithmetic mean unless reported otherwise.

## B.1 Regulations and Guidelines

### B.1.1 Regulations

#### B.1.1.1 Consumer Product Safety Commission (CPSC)

Pentachlorophenol should not be used as a preservative for playground equipment wood.

#### B.1.1.2 Department of Transportation (DOT)

Pentachlorophenol is considered a hazardous material and a marine pollutant, and special requirements have been set for marking, labeling, and transporting this material, including transporting it in tank cars.

#### B.1.1.3 U.S. Environmental Protection Agency (EPA)

##### B.1.1.3.1 Clean Air Act

National Emission Standards for Hazardous Air Pollutants: Listed as a hazardous air pollutant.

##### B.1.1.3.2 Clean Water Act

Designated a hazardous substance.

Effluent Guidelines: Listed as a toxic pollutant.

Water Quality Criteria: Based on fish or shellfish and water consumption = 0.27 µg/L; based on fish or shellfish consumption only = 3.0 µg/L.

Comprehensive Environmental Response, Compensation, and Liability Act

Reportable quantity (RQ) = 10 lb.

Regional Screening Levels (formerly Preliminary Remediation Goals): Residential soil = 0.89 mg/kg; industrial soil = 2.7 mg/kg; residential air = 0.48 µg/m^3^; industrial air = 2.4 µg/m^3^; tap water = 0.035 µg/L; maximum contaminant level (MCL) = 1 µg/L.

##### B.1.1.3.3 Emergency Planning and Community Right-To-Know Act

Toxics Release Inventory: Listed substance subject to reporting requirements.

##### B.1.1.3.4 Federal Insecticide, Fungicide, and Rodenticide Act

Pentachlorophenol is registered for use only as a heavy-duty wood preservative.

##### B.1.1.3.5 Resource Conservation and Recovery Act

Characteristic Hazardous Waste: Toxicity characteristic leaching procedure (TCLP) threshold = 100 mg/L.

Listed Hazardous Waste: Waste codes for which the listing is based wholly or partly on the presence of pentachlorophenol = D037, F021, F027, F028, F032, K001.

Listed as a hazardous constituent of waste.

##### B.1.1.3.6 Safe Drinking Water Act

Maximum contaminant level (MCL) = 1 µg/L

#### B.1.1.4 U.S. Food and Drug Administration (FDA)

Maximum permissible level in bottled water = 0.001 mg/L.

Maximum level of pentachlorophenol in wood preservatives prepared from pentachlorophenol and its sodium salt used on wooden articles used in packaging, transporting, or holding raw agricultural products = 50 ppm in the treated wood (calculated as pentachlorophenol).

Pentachlorophenol may be used as a component of adhesives and coatings in packaging, transporting, or holding food provided that conditions prescribed in 21 CFR 175 are met.

#### B.1.1.5 Occupational Safety and Health Administration (OSHA)

This legally enforceable PEL was adopted from the 1968 ACGIH TLV-TWA shortly after OSHA was established. The PEL may not reflect the most recent scientific evidence and may not adequately protect worker health.

Permissible exposure limit (PEL) = 0.5 mg/m^3^ [0.05 ppm].

Potential for dermal absorption.

### B.1.2 Guidelines

#### B.1.2.1 American Conference of Governmental Industrial Hygienists (ACGIH)

Threshold limit value – time-weighted average (TLV-TWA) = 0.5 mg/m^3^ [0.05 ppm].

Threshold limit value – short-term exposure limit (TLV-STEL) = 1 mg/m^3^ [0.09 ppm].

Potential for dermal absorption.

#### B.1.2.2 National Institute for Occupational Safety and Health (NIOSH)

Recommended exposure limit (REL) = 0.5 mg/m^3^ [0.05 ppm].

Immediately dangerous to life and health (IDLH) limit = 2.5 mg/m^3^ [0.23 ppm].

Potential for dermal absorption.