# Appendix A Literature Search Strategy

This document identifies the data sources, search terms, and search strategies that were used to identify literature for the draft monograph on pentachlorophenol (CASRN 87-86-5). The literature search strategy used for pentachlorophenol involved several approaches designed to identify potentially useful information for the broad range of topics covered by a Report on Carcinogens (RoC) monograph, as listed below.

- Properties and Human Exposure (focusing on the U.S. population)
- Disposition (ADME) and Toxicokinetics
- Human Cancer Studies
- Studies of Cancer in Experimental Animals
- Mechanistic Data and Other Relevant Effects
  - Genetic and Related Effects
  - Mechanistic Considerations

The methods for identifying the relevant literature for the draft pentachlorophenol monograph including (1) the search strategy, (2) updating the literature search, and (3) review of citations using web-based systematic review software are illustrated in Figure A-1 and discussed below. The detailed literature search strategy, including all database sources, and exclusion/inclusion criteria, are available at https://ntp.niehs.nih.gov/go/37898.

Figure A-1

Literature Search Strategy and Review

## A.1 Search Strategies

Relevant literature is identified using search terms, data sources, and strategies as discussed below.

1. General data search: This search covers a broad range of general data sources (see Pentachlorophenol Literature Search Strategy, available at https://ntp.niehs.nih.gov/go/37897 for information relevant to many or all of the wide range of monograph topics pertaining to pentachlorophenol.
2. Exposure-related data search: This search covers a broad range of potential sources (see Pentachlorophenol Literature Search Strategy, available at https://ntp.niehs.nih.gov/go/37897 for exposure-related information and physical-chemical properties.
3. Database searches in PubMed, Scopus, and Web of Science: The majority of the primary literature used to draft the pentachlorophenol monograph was identified from searches of these three extensive databases available through the NIEHS Library. Synonyms, metabolites, and the chemical class for pentachlorophenol were identified from the sources listed in Table A-1 and the search terms are listed in Table A-2. The substance search terms were combined with the search terms for each of the monograph topics listed above to create the specific literature searches. See Table A-2 for details on this approach and Table A-3 for topic-specific search terms.
4. Searches for human cancer studies are somewhat unique because they involve the identification of search terms for exposure scenarios that might result in exposure of people to pentachlorophenol. For pentachlorophenol, these exposure-related search terms were based on the manufacture of pentachlorophenol and its use in wood preservation and the use of the handling of the treated wood by workers in sawmills and in fence building; the search terms for those uses were combined with search terms specific for human cancer (see Table A-2 and Table A-3).
5. QUOSA library of occupational case-control studies search of the QUOSA-based library of approximately 6,000 occupational case-control studies, approximately 60% of which are currently available as searchable full-text pdfs, was conducted using the synonyms “pentachlorophenol,” “87-86-5 (CASRN),” “hydroxypentachlorobenzene,” “pentachlorobenzene,” “pentachlorophenate,” “Dowicide EC-7,” and “Dowicide 7.”
6. Special topic-focused searches: A topic-specific follow-up search was conducted for pentachlorophenol and immunosuppression using the terms (pentachlorophenol OR hydroxypentachlorobenzene OR pentachlorobenzene OR pentachlorophenate OR Dowicide) AND (immune AND (system OR suppress* OR surveillance)) OR (immunosuppress*).
7. Secondary sources: Citations identified from authoritative reviews or from primary references located by literature search, together with publications citing key papers identified using the Web of Science “Cited Reference Search,” were also added.

## A.2 Updating the Literature Search

The literature searches will be updated prior to submitting the draft monograph for peer review and prior to finalizing the monograph. Monthly search alerts for pentachlorophenol synonyms, metabolites, chemical class, exposure scenarios (human cancer), and topic-focused searches were created in PubMed, Scopus, and Web of Science, and the results of these searches from the closing date of the initial search will be downloaded for review.

## A.3 Review of Citations Using Web-based Systematic Review Software

Citations retrieved from literature searches were uploaded to web-based systematic review software and screened using inclusion and exclusion criteria. Multi-level reviews of the literature were conducted, with initial reviews (Level 1) based on titles and abstracts only to identify citations that could be excluded and to assign the included literature to one or more monograph topics; subsequent reviews (Level 2) for literature assigned to the various monograph topics (Exposure, ADME & TK, Human cancer studies, etc.) were based on full-text (i.e., PDFs) of the papers and were carried out by the writer and scientific reviewer for each monograph section. Two reviewers, at least one of whom is a member of the ORoC at NIEHS, participated at each level of review. The inclusion/exclusion criteria are available in the pentachlorophenol Literature Search Strategy document, available at https://ntp.niehs.nih.gov/go/37897.

Table A-1 Data Sources for Pentachlorophenol Searches

Information Type | Data Sources
Synonyms | National Library of Medicine databases (e.g., ChemIDplus, Hazardous Substances Data Base)
Metabolites | USEPA (2010), NTP (1999), IARC (1999), Dahlhaus et al. (1996)

Table A-2 Literature Search Approach for Pentachlorophenol

Substance | Search Terms | Topics (Combined with)^a^
Pentachlorophenol synonyms | Pentachlorophenol, 87-86-5 (CASRN), hydroxypentachlorobenzene, pentachlorobenzene, pentachlorophenate, Dowicide EC-7, Dowicide 7 | Human exposure Toxicokinetics Human cancer studies Cancer studies in experimental animals Genotoxicity Toxicity Mechanism
Pentachlorophenol metabolites and their synonyms | tetrachlorophydroquinone (TCHQ), tetrachloro-1,2-hydroquinone (TCoHQ), tetrachlorocatechol (TCpCAT), tetrachloro-p-benzoquinone (TCpBQ), tetrachloro-1,4-benzosemiquinone (TCpSQ), tetrachloro-1,2-benzosemiquinone (TCoSQ), tetrachlorophenol, and trichlorophenol | Human cancer studies Cancer studies in experimental animals (for the mechanistic section) Genotoxicity Toxicity Mechanism
Chemical class synonyms | chlorophenols/chlorinated phenols/polychlorinated phenols | Cancer studies in experimental animals (for the mechanistic section) Genotoxicity Toxicity Mechanism
Exposure scenarios (Dye industry, rubber chemical manufacturing, and herbicide manufacturing) | (wood and preserv*) OR lumber OR sawmill OR fenc* | Human cancer studies

^a^ Search terms for each of these topics were developed in consultation with an informational specialist.

Table A-3 Search Terms for Monograph Topics for Pentachlorophenol

Monograph Topic | Search Terms Used in PubMed, Scopus, and Web of Science | MeSH Terms Used in PubMed
Exposure | exposure OR occurrence OR oral OR dermal OR air OR water OR food OR soil OR environmental pollut* OR environmental exposure* OR occupational exposure* | (“Environmental Pollutants” [MeSH] OR “Environmental Pollution” [MeSH])
ADME/ Toxicokinetics | Toxicokinetic search terms- administration OR absorption OR distribution OR tissue distribution OR bioavailab* OR biological availability OR metaboli* OR biotransform* OR activat* OR bioactivat* OR detoxif* OR excret* OR clearance OR eliminat* OR kinetic* OR pharmacokinetic* OR toxicokinetic* OR cytochrome P450 Combine with AND Animal study search terms- in vivo OR animal* OR mouse OR mice OR rat OR hamster OR guinea pig OR rabbit OR monkey OR dog | Toxicokinetic search terms- “Pharmacokinetics”[Mesh]) OR “Metabolism”[Mesh]) OR “Cytochrome P450 Enzyme System”[Mesh]
Human Cancer | Cancer search terms- cancer OR mortality OR follow-up OR incidence) Combine with AND Epidemiology search terms - epidemiogic* OR workers OR case-control OR cohort OR case-report OR case-series | None
Animal Tumors | Cancer search terms- cancer OR neoplasm* OR carcinogen* OR malignan* OR oncogene* OR tumor* OR tumour* Combine with AND Animal study search terms- animal* OR mouse OR mice OR rat OR hamster OR “guinea pig” OR rabbit OR monkey OR dog | Cancer search terms- “Neoplasms”[Mesh]) OR “Carcinogens”[Mesh]
Genotoxicity | genetic toxicology” OR clastogen* OR “DNA strand break*” OR “unscheduled DNA synthesis” OR “UDS” OR aneuploid OR aneuploid* OR polyploid OR polyploid* OR “neoplastic cell transformation” OR “chromosom* aberration*” OR cytogenetic OR cytogenetic* OR “DNA adduct*” OR “DNA damage” OR “DNA repair” OR crosslink* OR “germ-line mutation” OR micronucle* OR mutagen OR mutagen* OR mutation OR mutation* OR oncogen* OR “sister chromatid exchange” OR “SCE” OR “SOS response*” OR “Ames test” OR “gene expression” OR “cell proliferation” OR cytotoxic OR cytotoxic* OR “comet assay” | “DNA Damage”[Mesh] OR “DNA Repair”[Mesh] OR “Mutagens”[Mesh] OR “Mutation”[Mesh] OR “Cytogenetic Analysis”[Mesh] OR “Oncogenes”[Mesh] OR “Mutagenicity Tests”[Mesh]
Toxicity | toxic* OR toxin*OR cytotoxic* OR (nephrotoxic* OR hepatotoxic* OR pneumotoxic* OR thyrotoxic* | “Toxic Actions”[Mesh]) OR “Toxicity Tests”[Mesh]) OR “adverse effects” [Subheading]
Mechanisms of Carcinogenicity | ((mode OR mechanism*) AND action) OR (carcinogen OR genetic OR epigenetic OR inhibit* OR promot* OR interact* OR activate* OR detoxific* OR “oxidative damage” OR alkylat* OR adduct)) AND ((animal OR animals OR mouse OR mice OR rat OR hamster OR “guinea pig” OR rabbit OR monkey OR dog OR pig) OR (person* OR people OR individual* OR subject* OR participant*))