# 6 Overall Cancer Hazard Evaluation – Synthesis of Animal, Human, and Mechanistic Data

This section synthesizes the information from the animal and mechanistic studies and applies the RoC listing criteria to that body of knowledge to reach a listing recommendation. No epidemiological studies were identified that evaluated the relationship between human cancer and exposure specifically to cumene. As stated in Section 4, cancer studies in experimental animals identified cumene-induced tumors in the lung, liver, and kidney that met the RoC criteria for sufficient evidence of carcinogenicity in experimental animals. That assessment did not consider data on mechanisms of carcinogenesis, and cancer at some tissue sites may be due to species-specific mechanisms. This section discusses the metabolism and genotoxicity of cumene and synthesizes the data on cancer in experimental animals and mechanisms of carcinogenesis for lung, liver, and kidney tumors and tumors at other sites. The RoC listing recommendation for cumene follows the discussion.

## 6.1 Metabolism to Reactive Metabolites and Genotoxicity

Metabolism of cumene is complex and not fully elucidated; however, there are clear similarities across species, and reactive intermediates of cumene can be generated by several metabolic pathways. The primary urinary metabolite in both humans and rodents is 2-phenyl-2-propanol (as a conjugate), suggesting that its metabolism is similar in these species. Most of the metabolites of cumene have not been tested for genotoxicity or carcinogenicity.

Although cumene was not mutagenic or genotoxic in most of the standard in vitro and in vivo assays, single-cell gel electrophoresis (the comet assay) provided evidence that cumene caused DNA damage in the liver of male rats and lungs of female mice. Cumene metabolism proceeds primarily through side-chain oxidation, but ring oxidation also occurs in vivo. One of the cumene metabolites detected in expired air from mice and in rat or mouse lung or liver microsomal incubations was α-methylstyrene. Metabolism of cumene to proposed reactive intermediates by side-chain oxidation of α-methylstyrene to α-methylstyrene oxide or by ring oxidation to arene oxides could potentially result in DNA damage. Although α-methylstyrene is not mutagenic in bacteria, there is evidence that it causes chromosomal damage in rodents and in cultured rodent and human cells, and α-methylstyrene oxide is mutagenic in bacteria. Therefore, some evidence exists for a genotoxic mechanism of carcinogenicity for cumene (presumably via its metabolism to α-methylstyrene or to other metabolites). The data on reactive metabolites and genotoxicity are consistent with the findings that cumene caused tumors at several different tissue sites.

## 6.2 Mouse Lung Tumors

The incidences of benign and malignant lung tumors (alveolar/bronchiolar adenoma, alveolar/bronchiolar carcinoma, and alveolar/bronchiolar adenoma and carcinoma combined) were increased in mice of both sexes. Studies or hypotheses relevant to evaluating potential mechanisms for induction of lung tumors by cumene include (1) a series of studies evaluating changes in gene expression and K-ras and p53 mutations and (2) a hypothesis that species-specific metabolism to reactive metabolites results in cytotoxicity and cell proliferation.

Cumene-induced mouse lung tumors have more K-ras and/or p53 mutations than do spontaneous lung tumors. Furthermore, the mutational spectra of K-ras and p53 in lung tumors from mice exposed to cumene differ from those observed in spontaneous lung tumors. These findings suggest the involvement of DNA damage (either direct damage from adduct formation or indirect damage through reactive oxygen species) and genomic instability. The K-ras and p53 mutations observed in cumene-induced lung tumors were accompanied by increased expression of genes involved in the alteration of the mitogen-activated kinase signaling pathway, invasion and metastasis, inhibition of apoptosis, increased angiogenesis, and increased metastatic potential. These molecular alterations resemble those found in human lung and other cancers.

The occurrence of alveolar/bronchiolar tumors in mice but not in rats may be partly explained by differences in disposition and metabolism. Following administration of ^14^C-labelled cumene, ^14^C concentrations in lung tissue were highest in female mice after seven consecutive daily doses but did not increase with repeated dosing in rats. In vitro studies with mouse and rat lung and liver microsomes demonstrated that mouse lung microsomes were the most efficient at metabolizing cumene, which is consistent with accumulation of cumene metabolites in mouse lung.

Based on a comparison with ethylbenzene, styrene, and other compounds that also induced lung tumors in mice but not in rats, some investigators proposed that species-specific metabolism by the cytochrome P450 isoform CYP2F2 in the Clara cells of mouse lung resulted in the production of cytotoxic metabolites that produced tumors. However, very few data are available to indicate which P450 isoforms are responsible for metabolizing cumene. CYP2E1 and CYP2F2 are likely candidates based on similarities between cumene and other alkylbenzenes, but metabolism of cumene by CYP2F2 in mouse lung has not been demonstrated to date. The orthologous isozyme CYP2F1 is found in human lung. In the NTP two-year carcinogenicity study of cumene, bronchiolar hyperplasia and alveolar epithelial bronchiolar metaplasia were significantly increased in mice of both sexes, but there was no evidence of cytotoxicity (e.g., necrosis or inflammation) in the lung in this study or in a three-month study. Therefore, these data are insufficient to support the conclusion that mouse lung tumors are not relevant to humans based on species-specific metabolism to cytotoxic metabolites.

As discussed above, the gene-expression data provide some evidence that cumene has similar molecular targets in mouse and human lung. Therefore, these data support a conclusion that cumene’s induction of lung tumors in mice is relevant to human carcinogenicity.

## 6.3 Mouse Liver Tumors

The incidences of malignant and benign liver tumors (hepatocellular adenoma and hepatocellular adenoma and carcinoma combined) in female mice were increased, with a significant dose-response relationship.

No data were identified on the mechanism of liver tumor formation in mice exposed to cumene. However, α-methylstyrene, which is produced when cumene is incubated with mammalian microsomes, has been shown to cause liver tumors in mice and rats. In vivo metabolism of α-methylstyrene is known to form a dihydrodiol product, presumably through the reactive intermediate α-methylstyrene oxide. These data provide support for a role of α-methylstyrene in cumene-induced liver cancer. No experimental evidence is available to suggest that the mouse liver tumors are not relevant to humans; therefore, these data support the conclusion that cumene’s induction of liver tumors in mice is relevant to human carcinogenicity.

## 6.4 Rat Kidney Tumors

The combined incidence of benign and malignant kidney tumors (renal-tubule adenoma and carcinoma) was increased in male rats exposed to the cumene metabolite α-methylstyrene.

α_2u_-Globulin nephropathy is a recognized mechanism of carcinogenicity associated with kidney tumors in male rats, but not females, that is not considered relevant to carcinogenicity in humans. Other data reported from NTP two-week, three-month, and two-year studies were used to assess the potential involvement of α_2u_-globulin nephropathy as a possible mechanism of carcinogenicity. Both IARC and the U.S. EPA have identified specific criteria and a sequence of events for evaluating whether this is the sole mechanism responsible for carcinogenicity. Although the available data are consistent with an α_2u_-globulin nephropathy mechanism of action in kidney-tumor formation, not all of the criteria for its being the sole mechanism were met. IARC criteria for which the evidence is questionable include nongenotoxicity, male-rat specificity of nephropathy, and evidence of sustained cell proliferation in the renal cortex (see Section 5.2.3).

There is evidence that cumene is genotoxic in some tissues (liver and lung) and that a metabolite, α-methylstyrene, can cause chromosome damage (see Section 6.1). In the NTP study, there was weak evidence of nephropathy in female rats; however, this may have been due in part to lower survival of the control group of female rats. Although there was no evidence of sustained cell proliferation in the renal cortex with PCNA staining, there was histological evidence of cell regeneration, and the data are unclear.

Overall, these data provide evidence that cumene causes kidney tumors largely via α_2u_-globulin nephropathy; however, the contribution of other mechanisms, such as genotoxicity, cannot be ruled out. Although it is likely that genotoxicity plays a role in cumene-induced carcinogenicity at some tissue sites, the strongest evidence for genotoxicity was found for lung and liver tumors, and the extent to which genotoxicity contributes to the formation of kidney tumors is unknown. Therefore, the relevance of the kidney tumors in rats to human cancer is uncertain, and the kidney-tumor findings are considered to be supportive of, rather than contributing directly, to sufficient evidence of carcinogenicity of cumene from studies in experimental animals.

## 6.5 Other Tumor Sites

The incidence of benign nasal tumors (adenoma of the respiratory epithelium) was significantly increased in rats of both sexes, and a significant dose-related trend was observed in males, but no malignant tumors were identified. Because this type of tumor typically does not progress to malignancy, these findings do not meet the RoC criteria for carcinogenicity (increased incidence of malignant tumors or benign and malignant tumors combined). However, these data were considered supportive of other findings of cancer in experimental animals.

Additional tumors that may have been related to cumene exposure include malignant blood-vessel tumors (hemangiosarcoma, primarily of the spleen) and benign thyroid-gland tumors (follicular-cell adenoma) in male mice and benign tumors of the testes (interstitial-cell adenoma) in male rats.

## 6.6 NTP Listing Recommendation

Cumene is reasonably anticipated to be a human carcinogen based on sufficient evidence of carcinogenicity from studies in experimental animals. The relevance to humans of the cancer findings in experimental animals is supported by data on mechanisms of carcinogenicity. Specifically, there is evidence that the metabolism of cumene is similar in humans and experimental animals. There is also evidence that cumene is genotoxic, based on findings of DNA damage in rodent lung and liver and production of a genotoxic metabolite (α-methylstyrene). Furthermore, mutations of the K-ras oncogene and p53 tumor-suppressor gene observed in cumene-induced lung tumors in mice, along with altered expression of many other genes, resemble molecular alterations found in human lung and other cancers. Therefore, there is no compelling evidence to indicate that the mechanism(s) by which cumene causes cancer at certain tissue sites in experimental animals would not also occur in humans.