# 5 Mechanistic Data and Other Relevant Effects

This section reviews data related to identifying and evaluating putative mechanisms for the potential carcinogenicity of cumene including (1) genetic and related effects, (2) mechanistic considerations, and (3) mutagenic and/or carcinogenic effects of metabolites and analogues. The primary purpose is to identify potential mechanisms of action of carcinogenicity, review the strength of evidence for potential mechanisms, and discuss any key issues that address the relevance of carcinogenic effects observed in experimental animals to effects in humans.

## 5.1 Genetic and Related Effects

Cumene has been evaluated in mutagenicity and genotoxicity assays in several laboratories. Much of the available information is based on a series of unpublished genotoxicity studies submitted to the EPA in partial fulfillment of the Toxic Substances and Recovery Act (TSCA), which were reviewed in several authoritative, peer-reviewed reports (EC 2001; NTP 2009; US EPA 1997; WHO 1999). The descriptions of the primary studies in these reviews are limited and do not allow for comprehensive evaluation. The database of genotoxicity studies of cumene consists of in vitro studies in bacteria and yeast (Section 5.1.1), and mammalian cells (Section 5.1.2), in vivo studies in rodents (Section 5.1.3) and mutation studies in mice (Section 5.1.4). Genotoxicity studies are also available on cumene metabolites (Section 5.1.5).

### 5.1.1 In Vitro Studies in Bacteria and Yeast

Cumene was tested in six studies using Salmonella typhimurium tester strains to measure mutagenic potential in a histidine reversion assay, in one study with Escherichia coli in a tryptophan reversion assay, and in one study in the yeast Saccharomyces cerevisiae D3 to measure mitotic recombination; the findings are reported in Appendix D, Table D-1. The S. typhimurium (Ames) assay can detect two types of DNA damage: base-pair substitution, producing a missense mutation (tester strains TA100 and TA1535), or frameshift mutation (tester strains TA97, TA98, TA1537, and TA1538).

Cumene was not mutagenic in any of the S. typhimurium strains tested using the spot test or standard plate incorporation Ames assay, with or without the addition of metabolic activation (EC 2001; Florin et al. 1980; NTP 2009; Simmon et al. 1977). One study (Tardiff et al. 1976) reported a positive mutagenic response in TA100; however, a subsequent study by the same researchers was negative (Simmon et al. 1977). Cumene was also negative in all tested strains using modifications of the standard Ames assay, including preincubation of the culture with cumene, treating cultures in a closed chamber or sealed tubes, and using hamster liver S9 instead of rat liver S9 for metabolic activation (EC 2001; NTP 2009; Simmon et al. 1977). An additional study reported that addition of cumene (10% by volume) to diesel fuel did not increase mutagenicity in S. typhimurium (strains not specified) (Jensen et al. 1988).

Although all of the S. typhimurium quantitative studies reported negative results for mutation induction by cumene, only three studies utilized the preincubation method, which is generally more sensitive than plate incorporation. One study (Simmon et al. 1977) performed the assay (plate incorporation) in a closed chamber—preferable for a volatile, water-insoluble substance such as cumene—and results were negative when tested to treatment levels that were toxic to the cells. In the NTP (2012) study, special efforts were made to prevent a reduced exposure due to the volatility of cumene, by preparing dosing samples in capped (with septa) vials flushed with N_2_ and carrying out the preincubation treatment in capped tubes. Using this modified technique, cumene was tested in E. coli, as well as S. typhimurium strains TA98 and TA100, and showed no mutagenic activity in these bacteria. Since all the NTP (2012) testing was performed to toxic levels, exposure of the cells to cumene was demonstrated to be adequate under these conditions. Limitations are noted for some of these studies, including presenting averaged rather than raw data, not testing in a closed chamber, and not testing to toxic doses; however, based on a review of all the available data, cumene is not mutagenic in the S. typhimurium or E. coli reversion assays.

Cumene was not mutagenic in the yeast S. cerevisiae D3 assay measuring mitotic recombination (ade^-^ homozygosity), tested both with and without rat S9 (Simmon et al. 1977).

### 5.1.2 In Vitro Studies in Mammalian Cells

Cumene was tested in several mammalian in vitro studies to measure genotoxic effects including mutation, chromosomal aberrations, cell transformation, and unscheduled DNA synthesis. Findings from these studies are reported in Appendix D, Table D-2.

Cumene was not mutagenic in mammalian cells, tested with and without rat liver S9, in the Chinese hamster ovary (CHO)/HGPRT assay (GLSC 1985a; Yang 1987) as described in (EC 2001; NTP 2009). In addition, cumene did not induce chromosomal aberrations in CHO cells when tested to toxic doses without S9 added (EC 2001). A small but statistically significant increase in structural chromosomal aberrations per cell was observed for 156 µg/mL cumene treatment in the presence of S9 compared with the vehicle control; however, this increase was not significant relative to the untreated control. There was no statistically significant increase in the percentage of cells with aberrations due to cumene treatment.

Cell transformation in BALB/3T3 mouse embryo cells was initially reported as positive at 60 µg/mL but, when a data review called the result equivocal, the assay was repeated and gave negative results when tested to toxicity (EC 2001; NTP 2009). An initial study of unscheduled DNA synthesis (UDS) in F344 rat hepatocytes was positive at 16 µg/mL; however, a review of this study considered it invalid because of inconsistent responses in replicate cultures and the high incidence of repair-positive cells in negative controls. A subsequent study failed to find evidence of unscheduled DNA synthesis in rat hepatocytes at doses up to 24 µg/mL (higher doses were toxic) (EC 2001).

The available database of in vitro studies on cumene includes some peer-reviewed publications, but most of the available information is from reviews (EC 2001; NTP 2009; US EPA 1997; WHO 1999) of several unpublished studies, which often did not have adequate information on study methodology and results. Overall, an evaluation of the in vitro test results indicates that cumene is not mutagenic in bacteria or mammalian cells. However, in vitro testing with small molecular weight volatile compounds such as cumene poses a number of challenges. For one, the chemical tends to volatilize from the medium and therefore may not be sufficiently available to the test cell or organism. This issue has been addressed in some studies by using a closed chamber or sealed tubes. Findings for chromosomal aberrations were inconclusive. Although positive results were initially reported for both cell transformation and UDS, repeat studies by different laboratories reported negative results. The repeat testing used somewhat varied methods (e.g., a different Pluronic surfactant was used, but the reason for and significance of this are not known) and the reported toxicity levels varied between original and retest for both assays. Toxicity levels should be similar in repeat testing; differences in toxic dose levels suggest that test parameters were changed that affected toxicity and potentially could also affect mutagenicity. A limitation of this cell transformation study in BALB/3T3 cells was that no exogenous source of metabolic activation was used. There are other problems with in vitro testing that are often overlooked (Eastmond 2012). These chemicals are often preferentially metabolized by CYP2E1, which is generally found at low levels in Aroclor 1254-induced rat liver S9. Common diluents used in in vitro studies such as DMSO, ethanol, and methanol are also metabolized by CYP2E1 so the diluents can act as competitive inhibitors of the enzyme in the test system. Whether the same would occur with the CYP2F isoforms is unknown. As a result, some caution should be exercised in interpreting the negative results for these types of chemicals in in vitro studies.

### 5.1.3 In Vivo Studies of Chromosomal and DNA Damage by Cumene in Rodents

Cumene was tested in rodents in vivo for micronucleus induction in erythrocytes, from bone marrow or peripheral blood, by various treatment routes including gavage, inhalation, and intraperitoneal injection. DNA damage was assessed using the comet assay in several tissues from rats and mice treated with cumene by gavage. In an additional study, rats were treated with cumene by inhalation to assess oxidative damage using the fragment length analysis with repair enzyme (FLARE) assay in conjunction with the comet assay. Findings from these studies are reported in Appendix D, Table D-3.

Cumene was tested in vivo for micronucleus induction in erythrocytes of both bone marrow and peripheral blood in studies in male rats, and in both males and females of two strains of mice. These studies reported results for mature erythrocytes (normochromatic erythrocytes or NCEs), immature erythrocytes (polychromatic erythrocytes or PCEs), or both NCEs and PCEs.

In the mouse, cumene did not induce micronuclei in peripheral blood erythrocytes, in either males or females, when treatment was by inhalation (NTP 2009) or by gavage (NTP 2012); results were also negative for micronucleus induction in bone marrow erythrocytes when the mice (both sexes) were exposed to cumene by gavage (EC 2001).

Findings in rats were mixed. Exposure to cumene in male F344/N rats by intraperitoneal (i.p.) injection, in two independent trials, resulted in statistically significant increases in the induction of micronuclei in polychromatic erythrocytes in bone marrow as well as a statistically significant trend test (NTP 2009). The results for the two trials in this study were consistent, which argues against it being a false positive. However, in a second NTP study, male F344/DuCrl rats were treated by gavage and no increased micronucleus formation in peripheral blood erythrocytes was observed at any treatment dose (NTP 2012). Both of these studies were short term (3 to 4 days), but there were several differences between the protocols. Micronuclei in PCEs were measured in different tissues; bone marrow PCEs were assessed using microscope slide scoring, whereas peripheral blood PCEs were scored by flow cytometry. In addition, the studies were done using different substrains of rats exposed by different routes of administration. It is unlikely that the results are explained by differences in the sensitivity of the micronucleus protocol assays because the study measuring micronuclei in peripheral blood restricted its analysis to the youngest reticulocytes (subpopulation of erythrocytes with the highest CD71 expression) that were least altered by the efficient action of the rat spleen in sequestering and destroying micronucleated red blood cells. In addition, the study evaluated 20,000 PCE, and the methodology is considered to have similar sensitivity as the bone marrow assay. One plausible explanation for the inconsistent results may be the treatment doses and differences in the routes of administration used in these studies. The micronucleus-inducing dose in the i.p. study was 1,250 mg/kg while the highest dose administered in the gavage study was 800 mg/kg. There were also differences in toxicity between the studies; no bone marrow toxicity was observed in the i.p. study but there was toxicity (as shown by decreased % PCE) when rats were treated by gavage. How the animal absorbs and metabolizes the chemical from these routes (i.p. and gavage) may differ, resulting in a higher or lower effective dose.

A study by Kim et al. (2008) used the formamidopyrimidine (Fpg)/endonuclease III (Endo III) FLARE assay to investigate cumene-induced oxidative DNA damage in hepatocytes and lymphocytes. The study was limited by high background values and inadequate reporting of methods and results and was determined to be inadequate for evaluation (see Appendix D, Table D-3).

The comet assay was used to detect DNA damage in the blood (leukocytes), liver, lung, and kidney of male rats and female and male mice administered cumene by gavage for 4 days (NTP 2012). Male F344 rats were treated with 200, 400, or 800 mg/kg cumene, female mice with 250, 500, or 1,000 mg/kg, and male mice with 312, 625, or 1,250 mg/kg. Results of the assay in the male rat showed a statistically significant increase in DNA damage in the liver at the high dose (p = 0.004; p < 0.025 is significant for pairwise comparisons) and a positive trend across doses of cumene (p_trend_ = 0.002; p < 0.025 is significant for trend test). No significant treatment effects were observed in the blood, lung, or kidney of the rat. In the female mouse, there was a statistically significant increase in DNA damage in the lung at the high dose (p = 0.016) and a positive trend (p_trend_ = 0.008). No significant treatment effects were observed in the blood, liver, or kidney of male or female mice and in the lung of male mice (see Appendix D, Table D-3). Recent evaluations have found that the comet assay detected nearly 90% of carcinogens that were negative or equivocal in the micronucleus assay and thus several investigators have recommended a combined micronucleus/comet assay to broadly assess in vivo genotoxic potential (Kirkland and Speit 2008; Pfuhler et al. 2007).

### 5.1.4 Mutations in Cumene-induced Lung Tumors in Mice

Hong et al. (2008) evaluated spontaneous and cumene-induced lung tumors (alveolar/bronchiolar adenoma and carcinoma) in male and female B6C3F_1_ mice for K-ras mutations in exons 1 and 2 (codons 12, 13, and 61) and p53 mutations in exons 5 to 8. This study included data from 52 cumene-induced lung tumors (6 adenomas and 46 carcinomas), 7 spontaneously occurring carcinomas from concurrent controls, and 6 samples of normal lung tissue. Findings were also compared with ras mutation data in spontaneous lung tumors from 117 historical controls. Lung tumors also were examined for p53 protein expression and loss of heterozygosity (LOH) at the p16 locus on chromosome 4 and near the K-ras gene on chromosome 6. The data showed differences in the incidence of K-ras mutations between cumene-induced (87%) and spontaneous lung tumors (14%) and historical controls (28%) (Appendix D, Table D-4). K-ras mutations (all dose groups combined) were more prevalent in males (41/45, 91%) than in females (4/7, 57%). The predominant K-ras mutations in lung tumors from cumene-exposed mice were codon 12 G to T transversion (36% vs. 18% in historical controls) and codon 61 A to G transition (29% vs. 6% in historical controls). Codon 12 G to A transition (42%) was the most common mutation in spontaneous lung tumors. There were no significant differences in ras mutations at codon 13 between spontaneous and cumene-induced lung tumors. Mutation spectra at codons 12 and 61 for cumene-induced and spontaneous lung tumors (historical controls) are compared in Figure 5-1.

Figure 5-1

K-ras Mutation Spectra for Spontaneous and Cumene-induced Lung Tumors in B6C3F_1_ Mice

Source: Hong et al. (2008).

Mutations in the p53 tumor suppressor gene were not observed in seven spontaneous lung tumors in concurrent controls but occurred in 52% of cumene-induced lung tumors (Appendix D, Table D-5) (Hong et al. 2008). Data from historical controls were not provided. These p53 mutations were identified in exon 5 (24/27, 89%) and exon 7 (3/27, 11%). As with K-ras mutations, p53 mutations were more prevalent in males (26/45, 58%) than in females (1/7, 14%); however, relatively few tumors were available from female mice. Increased p53 protein expression occurred in 56% of cumene-induced tumors but in only 1 of 7 spontaneous tumors. Although Hong et al. did not identify the specific p53 mutations, Wakamatsu et al. (2008) conducted a microarray analysis of DNA isolated from eight of the cumene-induced lung carcinomas. Four of the tumors had p53 mutations, including three tumors with G to A transitions in codon 155 of exon 5 and one with a C to T transition in codon 133 of exon 5. G to A transitions have been reported as frequent mutations in human lung cancer of both small-cell and non-small-cell types (Soussi 2012). Both K-ras and p53 genetic mutations showed a dose-dependent increase (total of all exposed groups), and similar mutation rates were reported for adenomas and carcinomas.

LOH also occurred in cumene-induced mouse-lung tumors (mainly carcinomas) but not in spontaneous tumors in control mice (Hong et al. 2008). The prevalence of LOH on chromosome 4 near the p16 tumor suppressor gene was 13% and that on chromosome 6 near the K-ras gene was 12%. Allele loss of p16 has been detected in human non-small-cell lung tumors. These data are similar to those reported for other chemically induced lung tumors from B6C3F_1_ mice (Devereux et al. 2002; Sills et al. 1999b; Zhang et al. 2001). These studies showed a high correlation between LOH near K-ras and K-ras mutations in lung tumors induced by vanadium pentoxide or chloroprene. These studies further demonstrated that wild-type K-ras can be a mouse lung tumor suppressor gene and that loss of the wild-type allele may be necessary for mutant K-ras to drive mitogen-activated protein kinase (MAPK) activation and mouse lung tumorigenesis.

### 5.1.5 Genotoxic Effects of Cumene Metabolites

Results from several genetic toxicology studies of α-methylstyrene, a metabolite of cumene, were reported by NTP (2007); the available information is summarized in Appendix D, Table D-6 and Table D-7.

When tested in vitro in the S. typhimurium preincubation assay, α-methylstyrene was not mutagenic in any strains (TA97, TA98, TA100, and TA1535) tested with and without rat or hamster S9 metabolic activation (NTP 2007; Zeiger et al. 1992). α-Methylstyrene (50 to 150 µg/mL) significantly increased the frequency of SCEs in CHO cells in the presence of S9. Another study reported weakly positive results for SCE in human whole blood lymphocytes exposed to α-methylstyrene (Norppa and Vainio 1983). However, it did not induce mutations or chromosomal aberrations in CHO cells with and without S9. In an NTP (2007) study, exposure by inhalation to 0 to 1,000 ppm α-methylstyrene in male and female mice for three months caused dose-related increases in the females (but not males) for micronuclei in normochromatic erythrocytes, with statistical significance (p = 0.0006) at the highest dose as well as for the trend test (p ≤ 0.001). However, micronuclei were not induced in the polychromatic immature erythrocytes, indicating that the observed micronucleus induction results reflected long-term accumulation of damage. The gender difference in micronucleus induction in mice is consistent with the gender difference in tumorigenicity of α-methylstyrene; the NTP concluded there was clear evidence of carcinogenic activity of α-methylstyrene in female mice based on increased incidence of hepatocellular adenoma and carcinoma and equivocal evidence in male mice based on marginal increases of hepatocellular adenoma or carcinoma (combined).

α-Methylstyrene oxide, a putative metabolite of cumene via P450 oxidation of α-methylstyrene, was mutagenic when tested in vitro with S. typhimurium strain TA100 in the preincubation assay (Rosman et al. 1986).

There is some evidence that the cumene metabolite, α-methylstyrene, is genotoxic: it induced SCEs in vitro in CHO cells and human lymphocytes and micronuclei in mice in vivo. α-Methylstyrene was not mutagenic in the S. typhimurium assay and did not induce chromosomal aberrations in CHO cells. However, α-methylstyrene oxide, the oxidation product of α-methylstyrene, was mutagenic in the S. typhimurium assay.

### 5.1.6 Summary of Genetic and Related Effects

Chemical agents that cause cancer at several tissue sites in more than one species frequently are genotoxic carcinogens. Although cumene was not mutagenic or genotoxic in most of the standard in vitro and in vivo assays, single-cell gel electrophoresis (the comet assay) provided evidence that cumene caused DNA damage in the liver of male rats and the lungs of female mice (NTP 2012). Although α-methylstyrene, a cumene metabolite, was not mutagenic in bacteria (NTP 2007), there is evidence that it causes chromosomal damage in rodents and cultured cells, and its proposed metabolite, α-methylstyrene oxide, is mutagenic in bacteria. The findings of specific K-ras (G > T transversions and A > G transitions) and p53 mutations in cumene-induced lung tumors provide some evidence consistent with, but not sufficient to confirm, a genotoxic mechanism involving cumene or its metabolites. Therefore, some evidence exists for a genotoxic mechanism of action for cumene (presumably via its conversion to α-methylstyrene or to other metabolites). The extent to which genotoxicity plays a role in causing tumors at different tissue sites is unknown.

## 5.2 Mechanistic Considerations

The mechanism(s) by which cumene might cause carcinogenic effects are not understood. It is unlikely that for any chemical a single mechanism or mode of action will fully explain the multiple biological alterations and toxicity pathways that can cause normal cells to transform and ultimately form a tumor. However, potential modes of action or molecular alterations have been identified. Cumene was associated with neoplasms in several tissue types in rats and mice and the tumor profiles showed some distinct species and gender differences. Renal tumors were observed in male rats only, while lung tumors were observed in mice but not in rats. Several potential modes of action or molecular alterations associated with carcinogenesis have been identified, including genetic and epigenetic effects, metabolic activation to reactive metabolites and cell proliferation, and α_2u_-globulin nephropathy. Proposed mechanistic considerations are not mutually exclusive and more than one mechanism might operate in a particular tissue and are discussed below for lung (Section 5.2.1), kidney (Section 5.2.2), and liver (Section 5.2.3).

### 5.2.1 Lung Tumors

Molecular alterations and species-specificity of chemically induced lung tumors and relevance to potential mechanisms of carcinogenicity are discussed below

#### Genetic Alterations

Genetic alterations (see Section 5.1.4), gene expression, and histone modifications (see Section 5.2.2) have been reported in the lung tumors from cumene-exposed mice in the 2-year bioassay and are different from those observed in spontaneous tumors.

Mutational data for cancer-related genes in target organs can provide important information for determining whether or not an agent acts through a mutagenic mechanism (e.g., direct interaction of a carcinogen with DNA and DNA-repair processes); however, this evaluation must be done cautiously. Mutations may also reflect the selection of cumene-induced or spontaneous mutations that provide a growth advantage to preneoplastic and neoplastic cells (Sills et al. 1999a). Tumors that arise spontaneously or through non-genotoxic or indirect genotoxic mechanisms (indirect DNA damage) may also contain increased frequencies of proto-oncogene mutations (Eastmond 2012; Hong et al. 2008) and many of these molecular changes may be an effect rather than a cause of cell transformation (Stanley 1995).

The difference in the specific mutations (mutational spectra) in K-ras and p53 genes between cumene-exposed mice and spontaneous lung tumors suggest that the lung tumors developed through different pathways of carcinogenicity and that the lung tumors in cumene-exposed mice were related to chemical exposure (Hong et al. 2008). The high frequency of K-ras mutations in adenomas (4 of 6) suggest that K-ras activation was a relatively early event and occurred either prior to or during this benign stage of carcinogenesis; however, the sample size was small (only 6 of 191 adenomas were examined for ras mutations), and K-ras mutations were not examined in pre-neoplastic lesions, in tumors less than 1 mm in size, or in normal tissue adjacent to neoplastic or preneoplastic lesions. Thus, the observed differences in mutational spectra in K-ras between spontaneous and cumene-induced lung tumors coupled with the dose-related increase in the number of tumors with K-ras and/or p53 mutations suggests a genotoxic effect.

Ras oncogene activation is common in both spontaneous and chemically induced lung tumors in mice. Mutational hot spots include codon 12 G > A transitions and G > T transversions and codon 61 A > T transversions and A > G transitions (Jackson et al. 2006; Stanley 1995). The incidence of GC > TA transversions, AT > GC transitions, and other prominent mutations for agent-induced and spontaneous mouse lung tumors reported in the NIEHS Genetic Alterations in Cancer (GAC) database and from Hong et al. (2008) are shown in Appendix D, Table D-9. Most of the mutation-inducing chemicals are considered genotoxic or mutagenic and many caused a shift in the mutational spectrum (similar to cumene) compared with spontaneous tumors, consistent with adduct formation. Although cumene forms reactive metabolites (see Section 2.2); no data on DNA adducts for cumene or its metabolites were identified and cumene is not mutagenic in vitro.

It is also possible that indirect (e.g., oxidative damage to DNA or genomic instability) DNA damage contributed to the mutational profile and development of lung tumors in mice exposed to cumene. G to T transversions in K-ras reported by Hong et al. (2008) are often associated with reactive oxygen species and are known to be caused by 8-oxo-deoxyguanosine adducts (Kino and Sugiyama 2005). Xie et al. (2004) reported that oxidative DNA damage appeared to play a causal role in tumorigenesis and that codon 12 of K-ras was a likely downstream target of oxidative DNA damage in lung tumorigenesis. More than 65% of knockout mice deficient in the oxidative DNA damage repair genes (Myh and Ogg1) and the mismatch repair gene (Msh2) developed lung and ovarian tumors and lymphoma. K-ras G to T mutations in codon 12 occurred in 75% of the lung tumors. Further, malignant lung tumors were increased with combined heterozygosity of Msh2. Other studies have shown that ROS, particularly the hydroxyl radical and singlet oxygen, can cause G to A, G to C, and C to T mutations. These mutations also occurred in K-ras or p53 in cumene-induced lung tumors in mice (Hong et al. 2008; Wakamatsu et al. 2008). No studies were identified that specifically reported 8-oxo-deoxyguanosine adducts or oxidative DNA damage with cumene exposure. However, the findings of DNA damage in female mouse lung tissue (as measured by the comet assay) provides some support that the G to T K-ras mutations, and possibly other mutations, may have been caused by cumene via oxidative DNA damage.

#### Gene Expression and Epigenetic Effects

Global gene expression analysis was conducted to compare gene regulation patterns between normal lung tissue and cumene-induced tumor tissue from the NTP (2009) two-year bioassay with and without K-ras mutations (Wakamatsu et al. 2008). Cluster analysis identified significant expression changes between normal tissue from untreated animals and tumor tissue from exposed mice in genes associated with the extracellular signal-regulated kinase-mitogen activated pathway (Erk MAPK). Differences also were observed for some of these genes between tumors with and without K-ras mutations. Although some genes were altered regardless of K-ras mutation status, many were significantly altered only in tumors with K-ras mutations (Appendix D, Table D-8). These data suggest that mouse lung carcinomas with K-ras mutations form differently from tumors without these mutations. Specifically, cumene-induced lung tumors with K-ras mutations were associated with increased expression of genes involved in the Erk MAPK signaling pathway, invasion and metastasis, inhibition of apoptosis, increased angiogenesis, and increased metastatic potential. The difference in gene expression suggests that cumene-induced carcinomas with K-ras mutations have a higher degree of malignancy than tumors without K-ras mutations. However, some caution is warranted regarding these findings since they were based on a small sample size (6 tumors with K-ras mutations and 2 tumors without K-ras mutations) and some of the ras-positive and ras-negative tumors also had p53 mutations. Wakamatsu et al. noted that many of the genes with altered expression in the mouse tumor model represent major genes that may play a role in lung and other cancers in humans. This work was supported by findings that the cumene mouse model recapitulates molecular alterations (K-ras and p53 mutations) found in human lung cancer (Hoenerhoff et al. 2009). Activation of the K-ras proto-oncogene and inactivation of the p53 tumor suppressor gene are among the major genetic alterations detected in human pulmonary adenocarcinoma. Susceptibility to both spontaneous and chemically induced lung tumors is known to have a genetic basis in mice and humans (Malkinson 1989). Taken together, the results of the gene expression and mutational spectra studies suggest that several genetic mechanisms can occur in cumene-induced lung tumors in mice. For example, DNA damage and genomic instability can result in K-ras and p53 dysregulation and upregulation and selection for pathways associated with a greater degree of malignancy and the development of lung cancer. Many of the genes with altered expression in the mouse tumor model represent major genes that may play a role in lung and other cancers in humans.

The potential involvement of epigenetic mechanisms in cumene-induced lung cancer was investigated using significance analysis of function and expression (SAFE) (Wakamatsu et al. 2008). SAFE is used to test functional categories in gene expression experiments and has the ability to detect changes in a set of genes that might otherwise have been missed when considering expression patterns of individual genes in isolation. Genes associated with the histone deacetylase (HDAC) complex were significantly altered (p = 0.046) in mouse lung carcinomas. Posttranslational modification (acetylation or deacetylation) of histone tails is a common epigenetic mechanism for regulating gene transcription. There was a stronger association between altered genes putatively associated with HDACs and tumors with K-ras mutations than tumors without K-ras mutations; thus, K-ras activation may affect histone modification or vice versa. Taken together, the genetic and epigenetic data suggest that mechanisms involved in causing alveolar/bronchiolar carcinomas observed in cumene-exposed mice involve K-ras mutations resulting in increased Erk MAPK signaling and histone modification.

#### Species-specific Disposition and Metabolism and Tumor Formation

The occurrence of alveolar/bronchiolar neoplasms in mice but not in rats may be partly explained by differences in disposition and metabolism. Chen et al. (2011) compared the disposition and metabolism of cumene in male F344 rats and B6C3F_1_ mice of both sexes following oral or intravenous administration (see Section 2). Several differences were noted that might partially explain the carcinogenic effects observed in these species. In female mice, the lungs had the highest ^14^C concentration after seven consecutive daily doses, which is consistent with the higher incidence of alveolar/bronchiolar adenoma or carcinoma reported in mice in the NTP (2009) study. This increase in bioavailability may also explain the positive trend with dose of female mouse lung for DNA damage (as measured by the comet assay), but not in the male rat. In contrast, ^14^C-cumene did not accumulate in rat lung (see Section 2.1.2) and did not induce lung tumors in rats. B6C3F_1_ mice are more susceptible to lung tumors than F344 rats as evidenced by having a much higher spontaneous incidence (Haseman et al. 1998). The in vitro study with female mouse and female rat lung and liver microsomes demonstrated that mouse lung microsomes were the most efficient in metabolizing cumene to 2-phenyl-2-propanol, 2-phenyl-1-propanol, and α-methylstyrene (Chen et al. 2011). 2-Phenyl-2-propanol, which has also been detected in human urine, can dehydrate to form α-methylstyrene or undergo further oxidation to form other reactive metabolites, including ring-oxidized metabolites. These data are consistent with accumulation of [^14^C]cumene in mouse lung after multiple doses and may help explain the carcinogenic effect of cumene observed in the mouse, but not rat, lung.

Alveolar/bronchiolar adenoma and carcinoma were increased in male and female mice exposed to cumene, while lung neoplasms were not increased in rats but nasal tumors were (NTP 2009). This tissue-response pattern for tumors in mice and rats has been observed for other chemicals containing aromatic rings. Cruzan et al. (2009; 2012) have proposed a mechanism by which the CYP2F2 isoform of cytochrome P450 in mice generates ring-hydroxylated metabolites that are cytotoxic to the lung. Cytotoxicity and associated inflammation can lead to generation of ROS, subsequent indirect DNA damage, and result in lung tumors. Cruzan et al. based this proposed mode of action on collective data from studies with styrene, ethylbenzene, coumarin, naphthalene, divinylbenzene, benzofuran, cumene and its metabolite α-methylstyrene. Although α-methylstyrene is included in this list, the conclusion of the NTP for the 2-year bioassay of that molecule in rats and mice was that no exposure-related neoplasms of the lung were observed (NTP 2007) (see Section 5.3).

While a role for CYP2F2-mediated metabolism of cumene in the mouse lung to ring-oxidized cytotoxic metabolite(s) has been postulated by Cruzan and coworkers, no direct evidence of involvement of this isoform in cumene metabolism was reported by Cruzan et al. or found in a search of the published, peer-reviewed literature. Very little information on specific cytochrome P450 isoforms responsible for metabolizing cumene was identified. Similarities with other alkylbenzenes indicate that CYP2E1 and CYP2F2 are likely candidates for mammalian enzymes that metabolize cumene (NTP 2009). Henne et al. (2001) reported that bacterial CYP102, but not rabbit CYP4B1 or rat CYP2B1, metabolized cumene in vitro to isopropylphenol, a ring-oxidized metabolite. NTP (2009) proposed a metabolic activation pathway for cumene that included ring hydroxylation to isopropylphenol. Although isopropylphenol has not been confirmed as a cumene metabolite in mammals, conjugates formed from hydroxyl-isopropylphenol (M2 and M3 in Table 2-1) have been detected.

Chen et al. (2011) were the first to identify three ring-oxidized metabolites of cumene in vivo (Figure 2-2); however, it is unclear whether these explain the findings of lung tumors in mice and not in rats. One of the ring metabolites, 4-(2-hydroxy-2-propyl)phenylsulfate (designated as M3) was detected in rats but not mice (or only in trace amounts), and a second, 2-(2-hydroxy-2-propyl)phenylsulfate (designated as M2) was detected in female mice but only at trace levels in male mice or rats. The third metabolite (thought to be a dihydrodrodiol) was detected in mice but not rats, consistent with the tumor profile; however, the structure was not confirmed (see Section 2.2 for more details). As mentioned in Section 4.2, bronchiolar hyperplasia and alveolar epithelial bronchiolar metaplasia also were significantly increased in both sexes of mice in the 2-year study, but no evidence of lung cytotoxicity (e.g., necrosis or inflammation) was observed in the subchronic or chronic studies.

### 5.2.2 Liver Tumors

No data were identified for the mechanism by which cumene causes liver tumors (hepatocellular adenoma and carcinoma) in female mice. However, it is possible that α-methylstyrene, a metabolite of cumene, plays a role in tumorigenicity, as it can be metabolized to a dihydrodiol, presumably through the reactive intermediate, α-methylstyrene oxide. α-Methylstyrene was detected in the expired air of mice exposed to cumene (higher concentrations in female mice) and in incubations with female mouse liver microsomes (Chen et al. 2011). Female mice exposed to α-methylstyrene had increased incidences of liver tumors (hepatocellular adenoma and carcinoma), and male mice also had slightly increased rates of liver tumors (NTP 2007). α-Methylstyrene is listed by IARC (2012) as possibly carcinogenic to humans (Group 2B).

### 5.2.3 Kidney Tumors and α_2u_-Globulin Nephropathy

α-Methylstyrene also caused kidney tumors (renal-tubule adenoma and carcinoma combined) in male but not female rats (NTP 2007) and may play a role in cumene- induced renal tumors in male rats.

One of the few mechanisms of action currently recognized by the EPA and IARC as unlikely to be relevant to humans is α_2u_-globulin-associated nephropathy in male rats (IARC 1999; US EPA 1991a). α_2u_-Globulin is a low-molecular-weight protein that is synthesized in the liver of male rats and is regulated by complex hormonal interactions. Androgens stimulate synthesis, whereas estrogens suppress synthesis. Although humans and other species synthesize proteins that are similar to α_2u_-globulin, there is no evidence that these proteins are involved in a similar nephropathy.

α_2u_-Globulin nephropathy is characterized by the rapid accumulation of α_2u_-globulin (observed as hyaline droplets) in lysosomes in the P2 segment of the proximal tubule. With continued exposure, hyaline droplet accumulation is followed sequentially by tubule epithelial degeneration and necrosis, granular cast formation at the cortico-medullary junction, sustained compensatory cell proliferation in the renal cortex, linear papillary mineralization, accelerated onset of cortical changes typical of chronic progressive nephropathy commonly seen in older rats, formation of sporadic foci of atypical hyperplasia within the proximal tubules, and progression to renal-tubule tumors (IARC 1999; Swenberg and Lehman-McKeeman 1999; US EPA 1991a). There is a quantitative relationship between sustained renal-cell proliferation and the promotion of preneoplastic and neoplastic lesions in the male rat. These changes do not occur in similarly treated female rats. Furthermore, renal tumors associated with α_2u_-globulin nephropathy typically have a longer latency period (requiring at least 18 months of continuous exposure) and a lower tumor rate (25% or less) than those associated with classical renal carcinogens (Swenberg and Lehman-McKeeman 1999).

Hyaline droplet accumulation in the proximal convoluted tubules is one of the most common histological findings in toxicity studies in rats (Hard 2008). However, many chemicals that induce hyaline droplets do not necessarily meet all the criteria of an α_2u_-globulin-associated response. Therefore, IARC (1999) developed a specific list of criteria, all of which must be met, for identifying agents where this is the sole mechanism responsible for carcinogenicity (Table 5-1).

Table 5-1 Criteria for α_2u_-Globulin-associated Nephropathy

Criteria
1. Lack of genotoxic activity (agent and/or metabolites) based on an overall evaluation of in vitro and in vivo data,; 2. Male rat specificity for nephropathy and renal tumorigenicity,; 3. Induction of the characteristic sequence of histopathological changes in shorter-term studies, of which protein droplet accumulation is obligatory,; 4. Identification of the protein accumulating in the tubule cells as α_2u_-globulin,; 5. Reversible binding of the chemical or metabolite to α_2u_-globulin,; 6. Induction of sustained increased cell proliferation in the renal cortex,; 7. Similarities in dose-response relationship of the tumor outcome with the histopathological endpoints (protein droplets, α_2u_-globulin accumulation, cell proliferation).

Source: IARC (1999).

It is important to note that renal tumors induced by α_2u_-globulin accumulation in male rats must be assessed independently of evaluations regarding tumors at other sites or in other exposed animals and, as mentioned above, some chemicals that induce hyaline droplets will not necessarily meet all the criteria associated with an α_2u_-globulin response. The US EPA (1991a) identified three possible categories for chemicals inducing renal tumors in male rats. These are: (1) the α_2u_-globulin sequence of events accounts solely for the renal tumors, (2) other potential mechanisms account for the renal tumors, and (3) both α_2u_-globulin-associated events and other potential carcinogenic mechanisms account for the renal tumors. Thus, the first question is whether or not α_2u_-globulin is involved. If it is, then a substantial database for each specific chemical will be required to determine the extent to which the α_2u_-globulin process is involved. Evidence of genotoxicity in short-term tests, nephrotoxicity and/or kidney tumors in female rats or either sex of other species, or data from specialized tests or biochemical studies may indicate that other carcinogenic mechanisms are involved.

The data from subchronic and chronic cumene toxicity studies and disposition studies in rats are consistent with α_2u_-globulin nephropathy in male rats (Chen et al. 2011; Cushman et al. 1995; NTP 2009). Chen et al. (2011) reported that cumene-derived ^14^C concentrations in the kidneys of male rats were significantly higher (p < 0.0001) than concentrations in the kidneys of male or female mice 24 hours after exposure to similar oral doses (see Sections 2.1 and 2.2). These data are consistent with binding of cumene and/or its metabolite with α_2u_-globulin in the kidneys of male rats. Cushman et al. (1995) exposed male and female F344 rats to cumene vapor at 0, 100, 500, or 1,200 ppm for 6 hours/day, 5 days/week, for 13 weeks. Cumene exposure-related findings in this study were increased liver, kidney, and adrenal gland weights in both sexes for treatments at the higher doses. Interstitial nephritis, renal proximal tubular-cell hypertrophy and hyperplasia, and hyaline droplet formation were also observed in male rats exposed to 500 or 1,200 ppm. Although α_2u_-globulin was not specifically identified in this study, the kidney lesions are consistent with those reported for male rats exposed to other chemicals known to induce α_2u_-globulin nephropathy. In the 2-week toxicity study by NTP (2009), groups of 5 male and 5 female rats were exposed to cumene vapor concentrations of 250, 500, 1,000, 2,000, or 4,000 ppm for 6.2 hours/day, 5 days/week for 16 days. All animals in the high-dose group died on the first day. Kidney weights were increased in all exposed groups compared with controls. Male rats exposed to cumene vapor concentrations of 250 to 2,000 ppm had minimal to mild hyaline droplet accumulation in the renal tubular cortex. No evidence of other renal tubule epithelial damage was observed. In the 3-month study, groups of 10 male or 10 female rats were exposed to cumene vapors at 62.5, 125, 250, 500, or 1,000 ppm for 6.2 hours/day, 5 days/week for 14 weeks. All animals survived to the end of the study. Relative kidney weights, but not absolute kidney weights, were increased in female rats exposed to 250 ppm or greater. Male rats had significantly increased kidney weights, increased amounts of α_2u_-globulin in the kidneys, and increased incidences of medullary granular casts (Table 5-2). The severity of hyaline droplet accumulation and the incidence and severity of renal cortical tubule regeneration were slightly increased with increasing exposure concentrations. The presence of granular casts, combined with an exposure-related increase in the severity of renal cortical tubule hyaline droplet accumulation and regeneration, demonstrated that cumene exposure caused damage to the renal tubule epithelium. Cell proliferation indices were determined in male rats by staining a section of the left kidney with proliferating cell nuclear antigen (PCNA) complexed with avidin and biotin. PCNA analyses indicated that the mean numbers of proximal tubule cells in S-phase were significantly increased in the two highest dose groups; however, the number of cells labeled and the labeling index were not significantly different from the control group.

Table 5-2 Renal Toxicity Data for Male Rats Exposed to Cumene Vapor for Three Months

Conc. (ppm) | Kidney Weight (g) | | α_2u_-Globulin (nmol/g Kidney) | Cortical Renal Tubules | | Medullary Granular Casts
Conc. (ppm) | Absolute | Relative | α_2u_-Globulin (nmol/g Kidney) | Hyaline Droplet Accumulation | Regeneration | Medullary Granular Casts
0 | 0.92 | 2.96 | 172.2 ± 22.3 | 10^a^ (1.1)^b^ | 8 (1.0) | 0
62.5 | 0.98 | 3.13** | 328.1 ± 69.6 | 10 (1.4) | 6 (1.2) | 0
125 | 1.01* | 3.13** | 383.4 ± 46.3** | 10 (1.9) | 8 (1.5) | 2 (1.0)
250 | 1.06** | 3.19** | 420.7 ± 50.1** | 10 (2.4) | 10 (1.8) | 8** (1.5)
500 | 1.07** | 3.41** | 363.2 ± 41.4** | 10 (3.0) | 10 (2.1) | 10** (2.5)
1,000 | 1.15** | 3.56** | 575.2 ± 74.8** | 10 (2.9) | 10 (2.1) | 9** (2.2)

Source: NTP (2009).

* p ≤ 0.05 (compared with chamber controls).

** p ≤ 0.01.

^a^ Number of animals with lesion (10 animals examined per group).

^b^ Average severity grade: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

In NTP’s 2-year study, incidences of renal tubule hyperplasia, mineralization of the renal papilla, and hyperplasia of the transitional epithelium of the renal pelvis were significantly increased in male rats (Table 5-3). Renal tubule hyperplasia was distinguished from regenerative epithelial changes commonly seen as part of nephropathy and was considered a preneoplastic lesion. Renal tubule hyperplasia, adenoma, and carcinoma are recognized as parts of a morphologic continuum. Incidences of hyperplasia of the transitional epithelium of the renal pelvis were significantly increased in the two highest dose groups, and the hyperplasia also increased in severity. This lesion is common in rats and frequently increases with the severity of nephropathy. Incidences of nephropathy in exposed groups of rats were not significantly different from chamber controls; however, the incidence and severity of nephropathy in both males and females showed a slight increase with dose.

Table 5-3 Renal Toxicity Data for Rats Exposed to Cumene Vapor for Two Years

Sex | Conc. (ppm) | Renal Tubule Hyperplasia | Renal Papilla Mineralization | Renal Pelvis Transitional Epithelium Hyperplasia | Nephropathy
Male | 0 | 0 | 5 (1.0) | 3 (1.7) | 47 (2.3)
Male | 250 | 3^a^ (3.3)^b^ | 35** (1.7) | 5 (1.8) | 47 (2.6)
Male | 500 | 8** (2.6) | 44** (2.1) | 14** (2.4) | 47 (2.9)
Male | 1,000 | 6* (2.2) | 41** (2.1) | 15** (2.0) | 50 (2.7)
Female | 0 | NR | 6 (NR) | 1 (NR) | 38 (1.4)
Female | 250 | NR | 3 | 1 | 37 (1.5)
Female | 500 | NR | 4 | 6 | 41 (1.9)
Female | 1,000 | NR | 6 | 1 | 44 (1.9)

Source: NTP (2009).

* p ≤ 0.05 (compared with chamber controls).

** p ≤ 0.01.

Conc. = concentration; NR = not reported.

^a^ Number of animals with lesion (50 animals examined per group).

^b^ Average severity grade: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

The NTP (2009) concluded that the nonneoplastic lesions of the kidney observed in male rats were characteristic of α_2u_-globulin accumulation. Renal tubule tumors occurred only in male rats and at doses that also resulted in increased histopathological endpoints associated with α_2u_-globulin nephropathy. However, the available data do not clearly show that all of the IARC (1999) criteria (see Table 5-1) were met. Criteria that are questionable include the following: lack of genotoxicity, male rat specificity for nephropathy, and evidence of sustained cell proliferation. Reversible binding to α_2u_-globulin was not assessed.

Kidney tumors occurred only in male rats but there was some evidence of nephrotoxicity in female rats. The incidence and severity of nephropathy increased slightly with dose in both male and female rats in the 2-year study, but there was also decreased survival in the female rat control group, which may have contributed to an apparent increase in nephropathy in the cumene-exposed group. Kidney weights also were increased in exposed male and female rats in the 2-week and 3-month studies.

Although α_2u_-globulin accumulation was identified in the male rat kidney in the subchronic study, no binding data with cumene were available for either the subchronic or chronic studies. Data were inadequate to determine if there was a sustained increase in cell proliferation in the renal cortex. Cell-proliferation data were available only for the 3-month study. Although there was an increase in the number of cells in S-phase, the number of labeled cells and the labeling index were not increased. This is in contrast with data reported for d-limonene, a classic α_2u_-globulin nephropathy-inducing chemical. Dietrich and Swenberg (1991b) reported that male rats exposed to d-limonene had a 4- to 5-fold increase in the labeling index of proximal tubule cells after 5 and 30 weeks of exposure. In that study, cell proliferation was determined by incorporation of 5-bromo-2'-deoxyuridine delivered via osmotic mini pumps and by immunohistochemistry rather than by PCNA staining.

Taken together, the available data indicate that cumene exposure induces α_2u_-globulin-associated nephropathy in male rats; however, it is unclear whether other mechanisms may play a role in carcinogenicity, as not all of the specific criteria for its being the sole mechanism were met. The data provide some evidence of genotoxic activity for cumene and its metabolites and weak evidence of cumene nephropathy in female rats.

## 5.3 Carcinogenicity of Metabolites and Analogues

Carcinogenicity data are available for several metabolites and analogues of cumene as discussed below.

### 5.3.1 Metabolites

2-Hydroxy-2-phenylpropionic acid (M8) was the second or third most abundant cumene metabolite in mice depending on dose and gender and the third most abundant in rats as reported by Chen et al. (2011) (see Table 2-1). This molecule also is known as phenyllactic acid. Phenyllactic acid may be formed endogenously through degradation of phenylalanine. Rauschenbach et al. (1975) investigated the carcinogenic effects of phenyllactic acid and p-hydroxyphenyllactic acid in mice. p-Hydroxyphenyllactic acid is an endogenous metabolite of tyrosine that is excreted in high concentrations in the urine of leukemia patients but is rarely detected in healthy individuals. C57BL/6 and CC57BR mice were exposed to phenyllactic acid and p-hydroxyphenyllactic acid administered by subcutaneous injections twice a week for 16 to 20 weeks. The total dose per mouse was 42 mg for p-hydroxyphenyllactic acid and 50 mg for phenyllactic acid (CC57BR mice only). The study was terminated after 22 months. Mice treated with p-hydroxyphenyllactic acid had an increased incidence of several neoplasms (leukemia, lung adenoma, vascular tumors, hepatomas, and benign and malignant urinary bladder tumors). Tumors (primarily leukemia, lung adenoma, and hemangioma) also occurred in CC57BR mice treated with phenyllactic acid, but these results were not considered significant because the tumor profile was similar to the spontaneous tumors observed in the control group. Total tumor incidences were 4/29 (14%) in C57BL/6 controls, 10/26 (38%) in CC57BR controls, 19/42 (45%) in CC57BR mice exposed to phenyllactic acid, 54/84 (64%) in C57BL/6 mice exposed to p-hydroxyphenyllactic acid, and 61/74 (82%) in CC57BR mice exposed to p-hydroxyphenyllactic acid.

2-Phenylpropionic acid was one of the minor cumene metabolites identified in rat and mouse urine by Chen et al. (2011) (see Table 2-1). Ahmad and Caldwell (1994) demonstrated that 2-phenylpropionic acid is a peroxisome proliferator in rats. Peroxisome proliferation in rodents can lead to liver tumors and is characterized by hepatomegaly, proliferation of peroxisomes with associated enzyme changes, increased mitochondrial number and enzyme levels, proliferation of the smooth endoplasmic reticulum, enhanced synthesis of cytochrome P450 isoenzymes of the 4A family (Ahmad and Caldwell 1994). However, no histologic evidence of peroxisome proliferation was reported in the cumene NTP bioassay (NTP 2009).

Data on α-methylstyrene, which is both a metabolite and an analogue of cumene are reported above under “Liver tumors” (Section 5.2.3).

### 5.3.2 Analogues

In addition to α-methylstyrene, cumene is structurally similar to several other alkylbenzenes including ethylbenzene, styrene, and toluene (Table 5-4). These compounds have been tested for carcinogenicity by the NTP (1979; 1990; 1999; 2007). No other well-conducted carcinogenicity studies were identified for any of these compounds other than styrene.

Table 5-4 Cumene Analogues Tested for Carcinogenicity

Chemical | Molecular Weight | Structure | Tumor Site(s)^a^
Chemical | Molecular Weight | Structure | Mice | | Rats
Chemical | Molecular Weight | Structure | Male | Female | Male | Female
α-Methylstyrene | 118.2 | | ^b^ | Liver | Kidney | None
Ethylbenzene | 106.2 | | Liver, lung | Liver, lung | Kidney | Kidney
Styrene | 104.2 | | Lung | None | None | ^c^
Toluene | 92.1 | | None | None | None | None

Sources: Cruzan et al. (2001); NTP (1979; 1990; 1999; 2007; 2011).

^a^ Tumor sites listed only if NTP concluded there was some or clear evidence of carcinogenicity or other studies found treatment-related increases in tumor incidence.

^b^ Equivocal evidence of liver tumors.

^c^ Equivocal evidence of mammary tumors.

Clear evidence of carcinogenic activity of ethylbenzene was reported in male rats (renal- tubule neoplasms) and some evidence of carcinogenic activity in female rats (renal-tubule adenomas) and mice of both sexes (lung or liver neoplasms) (NTP 1999). Ethylbenzene has not been reviewed for possible listing in the RoC.

Styrene was recently reviewed and listed in the RoC as reasonably anticipated to be a human carcinogen based on limited evidence of carcinogenicity in humans and sufficient evidence in experimental animals based on lung tumors in three strains of mice by two routes of administration (NTP 2011). There was equivocal evidence that styrene caused mammary tumors in female rats.

No evidence of carcinogenic activity in rats or mice exposed to toluene was reported (NTP 1990).