# 4 Studies of Cancer in Experimental Animals

This section reviews and assesses carcinogenicity studies in experimental animals exposed to cumene. These studies were identified by searching databases, comprehensive reviews, and citations from studies retrieved from the literature searches as described in Appendix A. Identified citations were reviewed using exclusion and inclusion criteria that limited selection of the studies to those examining neoplastic lesions, non-neoplastic or preneoplastic lesions relevant to carcinogenicity, and subchronic studies that provide information on dose selection. Chronic inhalation studies (2-year) conducted by NTP and the associated subchronic studies (90-day) in mice and rats were the only studies identified that meet these criteria (NTP 2009). Independent acute and subchronic inhalation studies in rats, guinea pigs, rabbits, dogs, and monkeys and a gavage study in rats were identified (Cushman et al. 1995; Fabre et al. 1955a; Jenkins et al. 1970; Wolf et al. 1956), but these studies did not examine tissues for neoplastic or preneoplastic endpoints or report any neoplastic lesions. The duration of these subchronic studies was not long enough to ensure the detection of cumene-induced carcinogenesis in the experimental animal models used at the doses tested and are not reviewed.

The characteristics, methodology, and relevant non-neoplastic findings from the chronic studies by NTP and the associated subchronic studies are reported in Sections 4.1 and associated tables. (Preneoplastic lesions that occur in the same tissue site in which neoplasms were observed are reported in the tables together with the information on neoplasms. The information on preneoplastic and neoplastic lesions in tables later in this section is provided to facilitate interpretation of data as it relates to tumor progression.) An assessment of the evidence for carcinogenicity is discussed in Section 4.2. The recommendation for the level of evidence is provided in Section 4.3.

## 4.1 Studies in Experimental Animals: Characteristics, Methodology, and Relevant Non-neoplastic Findings

Both the subchronic and chronic studies in rats and mice were conducted under FDA Good Laboratory Practice regulations in the same facility and using the same supplier and lot for the test chemical and husbandry and testing procedures as in the chronic study (NTP 2009). The subchronic studies in rats and mice were used to determine the test exposure groups in the chronic study. B6C3F_1_ mice or F344/N rats were exposed to cumene (99.9% pure) in inhalation chambers for 6 hours and 10 minutes per day, 5 days a week, for either 14 weeks (subchronic studies, 10 males and 10 females per exposure group) or 105 weeks (chronic studies, 50 males and 50 females per exposure group), with controls exposed to filtered air only. (Note: The additional 10 minutes of exposure were based on experimental data for the time required to achieve 90% of the target concentration (T_90_) after the beginning of vapor generation.) Complete necropsies and histopathology were performed on all animals. At necropsy, all organs and tissues were examined for grossly visible lesions, and all major tissues were processed and stained for histopathologic examination.

### 4.1.1 Rats

#### Subchronic Study

The subchronic study did not identify any neoplastic lesions at the exposure levels tested (0, 62.5, 125, 250, 500, and 1,000 ppm). Kidney and liver weights of males at exposures of 250 ppm or greater and liver weights of females at 1,000 ppm were significantly increased. Clinical chemistry results indicated hepatocyte injury. Alanine aminotransferase, sorbitol dehydrogenase, and alkaline phosphatase activities decreased with increasing exposure. However, no exposure-related gross or microscopic lesions were observed in the liver. To assess nephropathy in rats, kidneys from male rats were evaluated for α_2u_-globulin, soluble protein, and proliferating cell nuclear antigen. Kidneys of male and female rats were evaluated for histopathology and hyaline droplets. These endpoints were assessed because α_2u_-globulin nephropathy may be a potential mechanism for renal tumors (see Section 5.2.3). Exposure selection for the chronic study was based on the lack of mortalities and body weight effects, minimal organ weight changes, and the lack of lesions in tissues other than renal tubule epithelial damage in males. Cumene exposure concentrations selected for the 2-year inhalation study in rats were 250, 500, and 1,000 ppm.

#### Chronic Study

Survival for all exposed groups of rats was similar to that of the control group. Preneoplastic lesions in the nose and in the kidney were observed in the rat chronic study. Several lesions in the nasal cavity were found at significantly increased incidences. Olfactory basal-cell hyperplasia was increased in all exposed male and female groups. In males, respiratory epithelial-cell hyperplasia in all chemical exposure groups and goblet-cell hyperplasia at 250 ppm were increased. In females, there were significantly increased incidences of olfactory basal-cell hyperplasia in all chemical exposure groups and respiratory epithelial-cell hyperplasia in the high-exposure group. Hyperplasia of the respiratory epithelium of the nose can progress to adenoma of the respiratory epithelium, which was also observed in the chronic study. Neoplastic findings are discussed in Section 4.2.

Renal tubule hyperplasia and hyperplasia of the transitional epithelium of the renal pelvis were found to be significantly increased in males at the 500- and 1,000-ppm exposures; no significant increases were seen in females. These lesions can progress to neoplasia, which was observed in renal tubules in the chronic study. Kidneys of males had mineralization of the renal papilla that significantly increased in incidence compared with the chamber control group, and severity values were higher in all exposed groups. Females had incidences of mineralization similar to or less than the chamber control group. See Section 5.2. for a discussion of α_2u_-globulin nephropathy as a potential mechanism for cancer induction.

### 4.1.2 Mice

#### Subchronic Study

The subchronic study did not identify any neoplastic lesions at the exposure levels tested (0, 62.5, 125, 250, 500, and 1,000 ppm). Eight out of 10 females died in the high-exposure group; all males and females in the other exposure groups survived to the end of the study. There were no changes in hematology or clinical chemistry variables for the surviving animals. Upon necropsy, liver inflammation was noted in both sexes of mice. Exposure concentrations for the chronic study were based on toxicity found in the subchronic study of a slight decrease in body weight gain in males along with minimal increases in organ weights and a significant increase in the incidence of liver necrosis. In females, selection of exposure groups was based on a decrease in survival at 1,000 ppm and significant increases in thymic necrosis as well as focal chronic inflammation of the liver and non-significant increases in forestomach lesions (squamous hyperplasia, acute inflammation, and chronic inflammation).

#### Chronic Study

Exposures for the chronic study were 0, 250, 500, and 1,000 ppm in males and 0, 125, 250, and 500 ppm in females. During the chronic study, survival was significantly decreased in males, but not females (Table 4-1), and body weight gains for the male high-exposure group were less than for the control group, but similar to the control group in females.

Table 4-1 Incidences of Hyperplastic Lesions of the Nose in B6C3F_1_ Mice Exposed to Cumene by Inhalation for Two Years

Sex | Conc (ppm) | Mice (#) at Termination^b^ | Olfactory Epithelial Hyperplasia (Severity)^a^
Sex | Conc (ppm) | Mice (#) at Termination^b^ | Basal-cell | Atypical Basal-cell | Bowman’s Glands
Male | 0 | 38 | 0/50 | 0/50 | 3/50 (1.0)
Male | 250 | 34 | 0/50 | 0/50 | 11/50* (1.0)
Male | 500 | 30 | 15/49** (1.0) | 5/49* (1.6) | 9/49* (1.1)
Male | 1,000 | 23** | 33/48** (1.1) | 11/48** (1.7) | 23/48** (1.0)
Male | trend^+^ | p = 0.001^c^ | NR | NR | NR
Female | 0 | 37 | 0/50 | 0/50 | 1/50 (1.0)
Female | 125 | 36 | 1/50 (1.0) | 0/50 | 4/50 (1.0)
Female | 250 | 39 | 11/50**(1.0) | 2/50 (1.0) | 4/50 (1.0)
Female | 500 | 35 | 25/50** (1.1) | 10/50** (1.2) | 11/50** (1.0)
Female | trend^+^ | p = 0.996^c^ | NR | NR | NR

Source: NTP (2009).

^+^ Determined by Poly-3 trend test.

* p ≤ 0.05, **p ≤ 0.01 (compared with chamber controls by Poly-3 test for tumor sites or life table pairwise comparisons for survival data).

Conc = concentration, # = number, NR = not reported.

^a^ Average severity grade: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

^b^ All 50 animals per exposure group were necropsied and included in tumor incidence calculations, except when examination was prevented by cannibalism or autolysis as noted by the denominator.

^c^ Survival analysis performed by life-table trend test.

Lesions of the nose in mice consisted of hyperplasia or atypia of the olfactory epithelium and hyperplasia of Bowman’s glands (olfactory epithelial glands) (Table 4-1). There was a significant increase in hyperplasia of the olfactory epithelium and Bowman’s glands in exposed groups of male mice and in the 500-ppm exposure group of female mice. In particular, olfactory atypical basal-cell hyperplasia in four male mice in the high-dose group had features of preneoplastic change.

## 4.2 Assessment of Neoplastic Findings

The chronic inhalation studies in B6C3F_1_ mice and Fischer 344/N rats conducted by NTP were of sufficient duration to adequately assess the carcinogenic potential of cumene. Factors considered in study design were the number of animals per exposure group, exposure period, dose selection, monitoring of animal health, complete necropsies of all animals, and histopathologic examination of all major tissues. This study is considered a high-quality study and provides strong evidence to support the cancer assessment. Details of study quality criteria and assessment are reported in Appendix C. Important factors taken into account in data assessment are the significance of the effect as compared with the concurrent control (pairwise comparison), whether there is a change in the effect with dose (trend analysis), and the rarity of the event (historical control range). In the NTP assessments of experimental animal data in this report, a Poly-3 trend analysis is employed which is similar to the Cochran-Armitage trend test but is adjusted for survival.

### 4.2.1 Rats

#### Nose

In the NTP 2-year bioassay, cumene exposure significantly increased the incidences of adenoma of the respiratory epithelium of the nose in all exposed groups of males with a positive trend and in the 250-ppm exposed female rats (Table 4-2). Incidences in all exposed groups of rats exceeded the historical control ranges for inhalation studies and studies by all routes. Multiple adenomas were detected in male rats, but not female rats, at significant levels in the high-exposure group. Hyperplasia of the respiratory epithelium (see Table 4-2) and adenoma form a morphologic continuum. Adenomas of the respiratory epithelium of the nose in males are considered to be treatment related due to significant pairwise and trend exposure data and significant pairwise incidences of respiratory epithelial hyperplasia. Although it is possible that nasal respiratory epithelial adenoma of the nose can progress to adenocarcinoma, the tumor typically does not progress (Brown et al. 1991), and no evidence was reported of tumor progression to malignancy in this study.

Table 4-2 Incidence of Preneoplastic and Neoplastic Nasal Lesions Observed in Fischer 344/N Rats Exposed to Cumene by Inhalation for Two Years

Sex | Conc. (ppm) | Rats (#) at Termination^#^ | Olfactory Basal-cell Hyperplasia | Respiratory Epithelial-cell Hyperplasia | Goblet-cell Hyperplasia | Respiratory Epithelium Adenoma (Nose) (% Incidence)^b,c^
Male | 0 | 26 | 0/50 | 0/50 | 3/50 (1.7) | 0/50 (0.0)^d,f^
Male | 250 | 23 | 19/50** (1.1)^a^ | 15/50** (2.0) | 11/50* (2.3) | 7/50**(17.6)
Male | 500 | 27 | 27/49** (1.0) | 16/49** (2.9) | 7/49 (2.3) | 18/49*** (43.2)
Male | 1,000 | 24 | 26/50** (1.0) | 23/50** (2.7) | 5/50 (2.0) | 10/50*** (23.3)
Male | trend^+^ | p = 0.994^g^ | NR | NR | NR | p = 0.004
Female | 0 | 21 | 0/50 | 0/50 | 4/50 | 0/50 (0.0)^e^
Female | 250 | 27 | 14/48** (1.0) | 0/48 | 6/48 | 5/48* (12.2)
Female | 500 | 31 | 25/50** (1.0) | 4/50 (3.0) | 1/50 | 4/50 (9.3)
Female | 1,000 | 32 | 31/50** (1.1) | 6/50* (2.3) | 5/50 | 3/50 (6.9)
Female | trend^+^ | p = 0.061N^g^ | NR | NR | NR | p = 0.320

Source: NTP (2009).

* p ≤ 0.05, **p ≤ 0.01, ***p ≤ 0.001 (compared with chamber controls by Poly-3 test).

^+^ Determined by Poly-3 trend test.

^#^ All 50 animals per exposure group were necropsied and included in tumor incidence calculations, except when examination was prevented by cannibalism or autolysis as noted by the denominator.

Conc. = concentration, NR = not reported, # = number.

^a^ Incidence (severity), average severity grade: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

^b^ Number of animals with tumors; (Poly-3 estimated tumor percent incidence after adjustment for intercurrent mortality).

^c^ Respiratory epithelium of the nose.

^d^ Historical control range: 0%–2% for inhalation studies and studies by all routes.

^e^ Historical control range: 0%–0% for inhalation studies and studies by all routes.

^f^ Incidence includes multiple adenomas detected in male rats at 0 (0 ppm), 1 (250 ppm), 2 (500 ppm), 6 (1,000 ppm, *p ≤ 0.05).

^g^ Survival analysis performed by life-table trend test. A negative trend is indicated by N.

#### Kidney

The combined incidences of renal-tubule adenoma and carcinoma were significantly increased in male rats exposed to 500 ppm (mid-exposure) (Table 4-3). The incidences of adenoma, carcinoma, and adenoma and carcinoma (combined) in males exceeded the historical control ranges from inhalation studies and studies by all routes at all exposure levels except for carcinoma in the 250-ppm (low-exposure) group. Hyperplasia of renal tubules and renal pelvis in male rats was observed in 500- and 1,000-ppm (high-exposure) groups, and increased mineralization of renal papilla was observed in all exposed groups (see table in Section 5.2.3). Renal-tubule hyperplasia, adenoma, and carcinoma are part of a morphologic continuum. These results are considered to be treatment related based on evidence of neoplastic progression from hyperplasia of the renal pelvis and tubules, and tumor incidences outside of historical control values for adenoma, carcinoma, and adenoma and carcinoma (combined). No renal tumors were reported in females for any of the dose groups.

Table 4-3 Incidences of Kidney Neoplasms Observed in Fischer 344/N Rats Exposed to Cumene by Inhalation for Two Years

Sex | Conc. (ppm) | Rats (#) at Termination | Renal Neoplasia (% Incidence)^a^ | | | Comments
Sex | Conc. (ppm) | Rats (#) at Termination | Tubule Adenoma | Tubule Carcinoma | Combined | Comments
Males | 0 | 26 | 1/50 (2.4)^b^ | 1/50 (2.4)^b^ | 2/50 (4.8)^c^ | Hyperplasia of renal tubules and renal pelvis in 500- and 1,000-ppm dose groups and increased mineralization of renal papilla in all exposed groups (see Table 5-3 in “Mechanisms and Other Related Effects”).
Males | 250 | 23 | 4/50 (10.0) | 1/50 (2.5) | 5/50 (12.5)
Males | 500 | 27 | 5/50 (12.1) | 3/50 (7.3) | 8/50 (19.2)*
Males | 1,000 | 24 | 4/50 (9.3) | 3/50 (7.0) | 7/50 (16.2)
Males | trend^+^ | p = 0.994^e^ | p = 0.219 | p = 0.180 | p = 0.087
Females | 0 | 21 | 0/50^d^ | 0/50^d^ | 0/50^d^ | –
Females | 250 | 27 | 0/50 | 0/50 | 0/50 | –
Females | 500 | 31 | 0/50 | 0/50 | 0/50 | –
Females | 1,000 | 32 | 0/50 | 0/50 | 0/50 | –
Females | trend^+^ | p = 0.061N^e^ | – | – | – | –

Source: NTP (2009).

* p ≤ 0.05, **p ≤ 0.01, ***p ≤ 0.001 (compared with chamber controls by Poly-3 test).

^+^ Determined by Poly-3 trend test.

Conc. = concentration, # = number.

^a^ Number of animals with tumors (Poly-3 estimated tumor percent incidence after adjustment for intercurrent mortality).

^b^ Historical control range: 0%–2% for inhalation studies and studies by all routes.

^c^ Historical control range: 0%–4% for inhalation studies and studies by all routes.

^d^ Historical control range: not reported for inhalation studies and studies by all routes.

^e^ Survival analysis performed by life-table trend test. A negative trend is indicated by N.

#### Testis

The incidence of interstitial-cell adenoma (including bilateral) of the testis was significantly increased at 1,000 ppm with a positive trend and exceeded the historical control range from inhalation studies (Table 4-4). Interstitial-cell adenomas do not progress to malignancy. The severity grade of interstitial-cell hyperplasia increased across all dose groups (data not shown). Therefore, the results for interstitial-cell adenoma at the high-exposure concentration may have been exposure related.

Table 4-4 Incidences of Testicular Tumors Observed in Male Fischer 344/N Rats Exposed to Cumene by Inhalation for Two Years

Sex | Conc. (ppm) | Rats (#) at Termination | Interstitial-cell Adenoma (% Incidence)^a^
Male | 0 | 26 | 36/50 (80.0)^b^
Male | 250 | 23 | 38/50 (84.6)
Male | 500 | 27 | 40/50 (85.7)
Male | 1,000 | 24 | 46/50** (96.1)
Male | trend^+^ | p = 0.994^c^ | p = 0.006

Source: NTP (2009).

* p ≤ 0.05, ** p ≤ 0.01 (compared with chamber controls by Poly-3 test).

^+^ Determined by Poly-3 trend test.

Conc = concentration, # = number.

^a^ Number of animals with tumors; (Poly-3 estimated tumor percent incidence after adjustment for intercurrent mortality).

^b^ Historical control range: 66%–84% for inhalation studies and 66%–98% for studies by all routes.

^c^ Survival analysis performed by life-table trend test.

### 4.2.2 Mice

#### Lung

Statistically significant incidences of malignant and benign lung tumors (alveolar/bronchiolar adenoma, alveolar/bronchiolar carcinoma, and combined) in both sexes of exposed mice were detected for all treatment groups with significant trends, and incidences exceeded the ranges for historical controls by inhalation and by all routes (Table 4-5). Further, significant increases in bronchiolar hyperplasia and alveolar metaplasia were found in both sexes of all exposed mice. Alveolar/bronchiolar epithelial hyperplasia is considered a preneoplastic change and may progress to adenoma and carcinoma and is supportive of the cancer assessment. Based on positive pairwise comparisons, highly significant trend data, and historical control values, these results are considered to be treatment related.

Table 4-5 Incidences of Preneoplastic and Neoplastic Lung Lesions in B6C3F_1_ Mice Exposed to Cumene by Inhalation for Two Years

Sex | Conc. (ppm) | Mice (#) Termination^c^ | Preneoplastic Lung Lesions Incidence (Severity)^a^ | | Alveolar/Bronchiolar Tumors (% Incidence)^b^
Sex | Conc. (ppm) | Mice (#) Termination^c^ | Alveolar Epithelium Bronchiolar Metaplasia | Bronchiolar Hyperplasia | Adenoma | Carcinoma | Combined
Male | 0 | 38 | 5/50 (1.4) | 0/50 | 13/50 (27.5)^d^ | 9/50 (19.1)^e^ | 19/50 (39.8)^f^
Male | 250 | 34 | 43/50** (2.9) | 11/50** (2.1) | 31/50 (66.7)*** | 19/50 (41.5)* | 38/50 (81.4)***
Male | 500 | 30 | 42/50** (3.1) | 17/50** (3.2) | 31/50 (66.9)*** | 32/50 (70.5)*** | 42/50 (89.5)***
Male | 1,000 | 23** | 39/50** (3.0) | 18/50** (2.8) | 29/50 (67.9)*** | 33/50 (71.3)*** | 43/50 (92.1)***
Male | trend^+^ | p = 0.001^h^ | NR | NR | p ≤ 0.001 | p ≤ 0.001 | p ≤ 0.001
Female | 0 | 37 | 0/50 | 0/50 | 1/50 (2.3)^g^ | 3/50 (6.7)^i^ | 4/50 (8.9)^j^
Female | 125 | 36 | 42/50** (2.6) | 17/50** (2.7) | 26/50 (56.3)*** | 16/50 (35.3)*** | 31/50 (66.8)***
Female | 250 | 39 | 49/50** (2.9) | 10/50** (2.8) | 36/50 (74.5)*** | 20/50 (41.9)*** | 42/50 (86.0)***
Female | 500 | 35 | 47/50** (3.3) | 14/50** (2.8) | 38/50 (77.9)*** | 34/50 (69.5)*** | 46/50 (92.4)***
Female | trend^+^ | p = 0.996^h^ | NR | NR | p ≤ 0.001 | p ≤ 0.001 | p ≤ 0.001

Source: NTP (2009).

* p ≤ 0.05, **p ≤ 0.01, ***p ≤ 0.001 (compared with chamber controls).

^+^ Determined by Poly-3 trend test.

Conc. = concentration, NR = not reported. # = number.

^a^ Average severity grade: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

^b^ Number of animals with tumors (Poly-3 estimated tumor percent incidence after adjustment for intercurrent mortality).

^c^ All 50 animals per exposure group were necropsied and included in tumor incidence calculations, except when examination was prevented by cannibalism or autolysis as noted by the denominator.

^d^ Historical control range: 12%–26% for inhalation studies and 6%–28% for studies by all routes.

^e^ Historical control range: 10%–24% for inhalation studies and 2%–24% for studies by all routes.

^f^ Historical control range: 26%–44% for inhalation studies and 12%–44% for studies by all routes.

^g^ Historical control range: 2%–8% for inhalation studies and 0%–12% for studies by all routes.

^h^ Survival analysis performed by life-table trend test.

^i^ Historical control range: 0%–12% for inhalation studies and 0%–12% for studies by all routes.

^j^ Historical control range: 2%–14% for inhalation studies and 0%–18% for studies by all routes.

Female mice had statistically significant increased incidences of hepatocellular adenoma and adenoma and carcinoma (combined) at the high exposure, with significant positive trends (Table 4-6). These significantly increased incidences exceeded the historical control ranges for inhalation studies for hepatocellular adenoma and adenoma and carcinoma (combined) and the historical control range for all routes for combined tumors. Based on positive pairwise comparisons, significant trend data, and historical control values, these results are considered to be treatment related. Male mice had significantly increased incidences of eosinophilic foci in the liver at 500 and 1,000 ppm, while females had apparent increased incidences at 125 and 500 ppm, but not to a significant extent. Eosinophilic foci, hepatocellular adenoma, and hepatocellular carcinoma are thought to represent a morphologic continuum. Male mice did not develop liver tumors at significantly increased incidences or with significant positive trends; however, the control values for hepatocellular tumors are high making it less likely to observe a significant increase with dose.

Table 4-6 Incidence of Preneoplastic and Neoplastic Liver Lesions in B6C3F_1_ Mice Exposed to Cumene by Inhalation for Two Years

Sex | Conc. (ppm) | Mice (#) at Termination^b^ | Eosinophilic Foci | Hepatocellular Tumors (% Incidence)^a^
Sex | Conc. (ppm) | Mice (#) at Termination^b^ | Eosinophilic Foci | Adenoma | Carcinoma | Combined
Males | 0 | 38 | 6/50 | 34/50 (70.6)^c^ | 13/50 (27.1)^d^ | 40/50 (81.0)^e^
Males | 250 | 34 | 5/50 | 33/50 (69.9) | 18/50 (38.1) | 42/50 (85.8)
Males | 500 | 30 | 16/50** | 37/50 (77.9) | 21/50 (43.3) | 43/50 (87.2)
Males | 1,000 | 23** | 14/50* | 35/50 (79.5) | 17/50 (37.8) | 41/50 (87.1)
Males | trend^+^ | p = 0.001^f^ | NR | p = 0.135 | p = 0.184 | p = 0.250
Females | 0 | 37 | 8/50 | 18/50 (40.5)^g^ | 10/50 (22.2)^h^ | 25/50 (55.6)^i^
Females | 125 | 36 | 11/50 | 23/50 (50.0) | 7/50 (15.5) | 26/50 (56.5)
Females | 250 | 39 | 7/50 | 27/50 (56.4) | 6/50 (12.7) | 29/50 (60.4)
Females | 500 | 35 | 14/50 | 29/50 (59.8)* | 12/50 (25.4) | 36/50 (74.1)*
Females | trend^+^ | p = 0.996^f^ | NR | p = 0.040 | p = 0.311 | p = 0.024

Source: NTP (2009).

* p ≤ 0.05, **p ≤ 0.01 (compared with chamber controls).

^+^ Determined by Poly-3 trend test.

Conc. = concentration, # = number, NR = not reported.

^a^ Number of animals with tumors (Poly-3 estimated tumor incidence percent after adjustment for intercurrent mortality).

^b^ All 50 animals per exposure group were necropsied and included in tumor incidence calculations, except when examination was prevented by cannibalism or autolysis as noted by the denominator.

^c^ Historical control range: 30%–60% for inhalation studies and 14%–70% for studies by all routes.

^d^ Historical control range: 18%–32% for inhalation studies and 8%–48% for studies by all routes.

^e^ Historical control range: 50%–80% for inhalation studies and 20%–85% for studies by all routes.

^f^ Survival analysis performed by life-table trend test.

^g^ Historical control range: 12%–36% for inhalation studies and 2%–62% for studies by all routes.

^h^ Historical control range: 6%–20% for inhalation studies and 0%–28% for studies by all routes.

^i^ Historical control range: 22%–50% for inhalation studies and 8%–64% for studies by all routes.

In male mice, tumors in the blood vessels of the spleen (hemangiosarcoma) and in the thyroid gland (follicular-cell adenoma) may have been treatment related based on marginal increases over historical control values (Table 4-7). Male mice had a significant increase in hemangiosarcoma at the high-exposure treatment for the spleen and all organs; the incidence in the spleen exceeded the historical control ranges for inhalation studies and for all routes. However, these blood vessel tumors occur in multiple tissue types and are not specific to or rare in the spleen. Also, the incidence in all organs was within the historical control ranges for inhalation studies and for all routes. Male mice also had a significant increase in the incidence of adenoma of the thyroid gland at the high exposure, but the unadjusted overall tumor rate (6%) at the high exposure was within the historical control range (0%–6%) for inhalation studies and for all routes.

Table 4-7 Incidence of Vascular and Thyroid Gland Tumors in B6C3F_1_ Mice Exposed to Cumene by Inhalation for Two Years

Sex | Conc. (ppm) | Mice (#) at Termination | Hemangiosarcoma (% Incidence)^a^ | | Thyroid Gland: Follicular-cell Adenoma (% Incidence)^a^
Sex | Conc. (ppm) | Mice (#) at Termination | All Organs | Spleen | Thyroid Gland: Follicular-cell Adenoma (% Incidence)^a^
Male | 0 | 38 | 0/50 (0.0)^b^ | 0/50 (0.0)^c^ | 0/50 (0.0)^f^
Male | 250 | 34 | 1/50 (2.2) | 0/50 (0.0) | 0/50 (0.0)
Male | 500 | 30 | 2/49 (4.5) | 0/49 (0.0) | 0/49 (0.0)
Male | 1,000 | 23** | 4/50* (9.9) | 4/50* (9.9) | 3/50** (7.5)^h^
Male | trend^+^ | p = 0.001^g^ | p = 0.015 | p = 0.002 | p = 0.010
Female | 0 | 37 | 1/49^d^ (2.3) | 0/49 (0.0)^e^ | 1/50 (2.3)
Female | 125 | 36 | 3/50 (6.6) | 0/50 (0.0) | 4/50 (8.9)
Female | 250 | 39 | 6/50 (12.8) | 3/50 (6.4) | 0/50 (0.0)
Female | 500 | 35 | 1/50 (2.1) | 1/50 (2.1) | 3/50 (6.4)
Female | trend^+^ | p = 0.996^g^ | p = 0.518N | p = 0.271 | p = 0.432

Source: NTP (2009).

* p ≤ 0.05, ** p ≤ 0.01 (compared with chamber controls).

^+^ Determined by Poly-3 trend test, a negative trend is indicated by N.

Conc. = concentration, # = number.

^a^ Number of animals with tumors; (Poly-3 estimated tumor incidence percent after adjustment for intercurrent mortality).

^b^ Historical control range: 0%–12% for inhalation studies and studies by all routes.

^c^ Historical control range: 0%–4% for inhalation studies and studies by all routes.

^d^ Historical control range: 2%–8% for inhalation studies and 2%–16% for studies by all routes.

^e^ Historical control range: 0%–4% for inhalation studies and 0%–8% for studies by all routes.

^f^ Historical control range: 0%–6% for inhalation studies and studies by all routes.

^g^ Survival analysis performed by life-table trend test.

^h^ The unadjusted incidence is 6%.

## 4.3 NTP Level of Evidence Conclusion

These data meet the RoC criteria for sufficient evidence of carcinogenicity in experimental animals with an increased incidence of malignant and/or a combination of malignant and benign tumors in rats and mice or at multiple tissue sites. This conclusion is based on treatment-related malignant and/or a combination of malignant and benign tumors in the kidneys of male rats, the lungs of male and female mice, and livers of female mice.

Benign tumors of the respiratory epithelium of the nose were identified in the nasal cavities of male and female rats. These tumors do not typically progress to malignancy and no malignant tumors were described; thus, the nasal epithelial tumors are considered to be supporting evidence of carcinogenicity.