# 3 Human Cancer Studies

No epidemiological studies or case reports were identified that evaluated the relationship between human cancer and exposure specifically to cumene.