# 2 Disposition and Toxicokinetics

Disposition and toxicokinetics refer to how a chemical can enter and leave the body, what happens to it once it is in the body, and the rates of these processes. Disposition includes absorption, distribution, metabolism, and excretion while toxicokinetics refers to the mathematical description (toxicokinetic models) of the time course of disposition of a chemical in the body. These data are important because they help identify the various factors that affect the toxicity of a chemical. These factors include routes and rates of absorption, tissue concentrations and their temporal changes, reactive metabolites, intoxication and detoxication reactions, routes of elimination, and species differences in these factors. Section 2.1 discusses the absorption, distribution, and excretion of cumene. Although no extensive toxicokinetic models for cumene have been identified, a two-compartment pharmacokinetic model is summarized briefly in Section 2.1.2, below. Metabolism is discussed in Section 2.2 and Section 2.3 provides a summary of Sections 2.1 and 2.2. The mechanistic implications of these data are discussed in Section 5.

## 2.1 Absorption, Distribution, and Excretion

Cumene is readily absorbed following inhalation exposure in humans and after inhalation, oral, or dermal exposure in laboratory animals (Chen et al. 2011; EC 2001; Seńczuk and Litewka 1976; WHO 1999). These studies also indicate that cumene is widely distributed, extensively metabolized, and rapidly excreted, primarily in the urine based on recovery of ^14^C-cumene-derived radioactivity. Only one absorption and excretion study in humans was identified. That study was conducted in 10 healthy volunteers while other data were available from non-occupational exposure studies (see Section 1). Several cumene disposition and metabolism studies have been conducted in rats, mice, or rabbits.

### 2.1.1 Studies in Humans

Absorption data in humans is limited to inhalation studies. Respiratory absorption of cumene vapor in humans ranged from about 45% to 80% and declined with exposure duration (Brugnone et al. 1989; Seńczuk and Litewka 1976). Cumene absorption was directly proportional to the concentration of the primary urinary metabolite measured as dimethylphenylcarbinol (2-phenyl-2-propanol) or its acid-cleaved conjugates. No distribution data were available; however, one study did measure cumene in blood of two groups that included hospital staff and chemical workers who were employed in different areas of the facility without any direct exposure to cumene or related chemicals (Brugnone et al. 1989). Cumene concentrations were not significantly different in the infirmaries of the hospital or chemical plant where the examinations were conducted; however, blood cumene concentrations were significantly higher in the chemical workers. Blood concentrations also were correlated with cumene concentrations in alveolar air for the chemical workers but not the hospital staff. Concentrations in blood were about 40 times higher than in alveolar air, which was consistent with a reported blood/air partition coefficient of 37. Urinary excretion of 2-phenyl-2-propanol was biphasic with an initial excretion half-life of 2 hours and a subsequent (post-exposure) half-life of 10 hours (Seńczuk and Litewka 1976). Maximum urinary excretion occurred after 6 to 8 hours of exposure, declined rapidly after exposure ceased, and approached zero after 48 hours. Other studies indicated that some cumene is eliminated in expired air (Conkle et al. 1975; Krotoszynski et al. 1977). Trace levels of cumene were detected in some of the expired air samples collected from 28 nonsmoking, healthy volunteers who were selected to represent an urban population (Krotoszynski et al. 1977) and from 8 healthy male volunteers from the U.S. Air Force School of Aerospace Medicine (Conkle et al. 1975).

### 2.1.2 Studies in Animals

Disposition studies in rats and mice exposed by inhalation, gavage, or intravenous (i.v.) injection show interspecies similarities and differences (Chen et al. 2011; EC 2001; WHO 1999). An unpublished metabolism, disposition, and pharmacokinetics study of cumene in male and female F344 rats was conducted by Research Triangle Institute in 1989 (cited in EC (2001), WHO (1999)). Cumene was absorbed rapidly from the stomach and the lungs and was detected in the blood of rats within 5 minutes after inhalation exposure (EC 2001; WHO 1999). In gavage studies in rats, maximum blood levels were reached within 4 hours after a dose of 33 mg/kg and 8 to 16 hours after a dose of 1,350 mg/kg. Dermal absorption was demonstrated in rats and rabbits but no details of these studies were provided (WHO 1999).

Tissue retention in rats and mice 24 hours after receiving single oral doses was less than 3% in rats and less than 1% in mice (Chen et al. 2011). Tissue concentrations were similar for male and female mice administered the low dose (10 mg/kg) but were higher in females exposed to the highest dose (1,000 mg/kg). At comparable single doses, tissue concentrations were significantly higher in rats than in mice, particularly in the kidneys. This suggests that mice are more efficient in metabolizing and excreting cumene than the rat. In rats, the tissue and blood concentrations were proportional to dose with the highest concentrations occurring in the kidneys after single or repeat doses. In mice, the tissue concentrations were more variable across the range of doses but were highest in the liver, kidney, and lung. After seven consecutive daily doses, the highest tissue concentrations occurred in the lungs. Higher tissue concentrations in rat kidneys and mouse lung correlate with the higher incidence of tumors in these tissues (see Section 4). Inhalation studies in rats have reported half-lives of cumene disappearance from blood as 3.9 to 6.6 hours (WHO 1999). Longer half-lives in blood (9 to 16 hours) were reported in gavage studies with rats. There was no evidence of cumene accumulation in tissues following high or repeated oral doses in rats or mice.

Excretion data show that the majority of the administered dose is excreted in the urine (70% to 90%) in rats and mice regardless of the route of administration (Chen et al. 2011; EC 2001; WHO 1999). Excretion in feces ranged from about 1% to 5.3%, and excretion as radiolabeled volatile organic compounds (VOCs) in expired air ranged from <1% to about 22%. Cumene accounted for more than 95% of the radiolabeled VOCs excreted in expired air with α-methylstyrene accounting for 3% to 4% in mice and only a trace amount in rats. Increased excretion in the expired air with dose indicates possible saturation of metabolic pathways at high doses, and higher excretion in expired air in female mice than male mice indicates more efficient metabolism in males. Enterohepatic circulation of cumene glucuronide metabolites was implied because about 37% of the total dose was detected in the bile in bile-duct cannulated rats, but very little was excreted in the feces in any treatment group. There was little difference in the excretion pattern following single or repeated daily oral doses. The distribution and elimination of cumene in rats following an i.v. bolus dose was described by a two-compartment pharmacokinetic model. The distribution half-lives were calculated to be 0.21 hours for males and 0.27 hours for females while elimination half-lives were 8.6 hours for males and 7.3 hours for females.

## 2.2 Metabolism

Cumene is extensively metabolized by cytochrome P450 enzymes within hepatic and extrahepatic tissues, including the lung (WHO 1999). From studies in rabbits, mice, and rats, and evidence in humans, the primary metabolites of cumene are from oxidation of the side chain. Metabolism studies in mice and rats have shown that several reactive metabolites may be produced through ring oxidation as well as side-chain oxidation of cumene. These oxidized metabolites are primarily excreted as sulfate or glucuronide conjugates.

### 2.2.1 Studies in Humans

2-Phenyl-2-propanol was identified in urine samples from human volunteers exposed to cumene vapor for 8 hours (Seńczuk and Litewka 1976). This metabolite was not detected in urine samples collected before exposure but accounted for about 35% of the absorbed dose 48 hours after exposure. No other metabolites were reported. 2-Phenyl-2-propanol also has been identified as a primary cumene metabolite in rabbits, mice, and rats (discussed below), which indicates some similarity in cumene metabolism between humans and experimental animals.

### 2.2.2 Studies in Animals

The same six urinary metabolites were detected in the Research Triangle Institute study in rats exposed by gavage, i.v. injection, or nose-only inhalation (cited in EC (2001), WHO (1999)). Some of the metabolites were not identified but more than half were accounted for by 2-phenyl-2-propanol and its glucuronide or sulfate conjugates. Four cumene metabolites were identified in rabbits following oral exposure: 2-phenyl-2-propanol, 2-phenyl-1-propanol, 2-phenylpropionic acid, and 2-hydroxy-2-phenylpropionic acid (Ishida and Matsumoto 1992; Robinson et al. 1955); however, no phenolic metabolites were reported in rabbits or in rats exposed to cumene (Bakke and Scheline 1970). Urinary metabolites detected in this study included 2-phenyl-1-propanol and 2-phenyl-2-propanol. Thus, side-chain oxidation rather than ring oxidation is the primary metabolic pathway in rats and rabbits.

In a study of the metabolism and disposition of cumene in male rats or male and female mice exposed by oral or i.v. routes, Chen et al. (2011) detected sixteen metabolites (designated M1 to M16). In addition, in vitro metabolism of cumene was investigated using female rat and mouse liver and lung microsomes. Cumene was the primary compound detected in expired air but, in mice, up to 4% was α-methylstyrene. The 16 metabolites and their relative proportions in urine are shown in Table 2-1. Five of these metabolites (M6, M7, M9, M13, and M16) also were detected in bile from male rats, and three metabolites (α-methylstyrene, M14, and M15) were detected in the microsomal incubations. 2-Phenyl-2-propanol glucuronide was the most abundant metabolite in rat and mouse urine and rat bile. Mouse lung microsomes metabolized more cumene than microsomes from mouse liver, rat lung, or rat liver. These data indicate that metabolism primarily proceeds through side-chain oxidation (Figure 2-1); however, this study was the first to demonstrate that ring oxidation also occurs in vivo Figure 2-2). Several reactive metabolites may be produced through ring oxidation of cumene and side-chain oxidation to 2-phenyl-2-propanol (M14). These include arene oxide intermediates, a quinone or semi-quinone radical derived from a catechol intermediate (not shown), and quinone methide. Thompson et al. (1995) demonstrated that reactive quinone methide intermediates were readily formed when the para isomers of methylphenol, ethylphenol, and isopropylphenol were incubated with rat liver microsomes. Another potential reactive metabolite is α-methylstyrene oxide. This metabolite can form by further oxidation of α-methylstyrene that results from dehydration of M14. Although α-methylstyrene oxide was not detected, all metabolites from the α-methylstyrene pathway (M5, M6, M7, M8, and M12) are derived from the oxide (Figure 2-1). However, M5, M6, M7, and M8 also can be formed from 2-phenyl-1,2-propanediol by further oxidation of either of the two side-chain alcohols of M14 (2-phenyl-2-propanol) or M15 (2-phenyl-1-propanol). M14 was the major metabolite in incubations of cumene with microsomes prepared from female mouse and rat lung and liver tissue (Chen et al. 2011). The levels of M15 varied in these incubations.

Table 2-1 Cumene Metabolites in Rat and Mouse Urine (Oral Exposure)

Metabolite | Structure | % of Radiolabeled Peaks
Metabolite | Structure | Male Rat | Mouse
Metabolite | Structure | Male Rat | Male | Female
M1: (dihydrodiol?) | Not determined | N.D. | N.D.–trace | 1.8–3.0
M2: 2-(2-hydroxy-2-propyl)phenylsulfate | | trace | N.D.–trace | N.D.–4.4
M3: 4-(2-hydroxy-2-propyl)phenylsulfate | | 7–11.4 | N.D. | N.D.–trace
M4: (unknown) | Not determined | 5.2–5.6 | N.D. | N.D.–trace
M5: 2-hydroxy-2-phenylpropylsulfate | | 2.2–2.6 | 3–8.4 | 5.8–19.1
M6: 2-phenyl-1,2-propandiol 2-glucuronide | | N.D.–1.6 | 2.9–4.4 | 2.5–4.2
M7: 2-phenyl-1,2-propandiol 1-glucuronide | | 17.8–20.1 | 8.6–16.9 | 6.1–16.5
M8: 2-hydroxy-2-phenylpropionic acid | | 12.1–16.4 | 12.8–15.7 | 11.4–20.4
M9: 2-phenyl-2-propanol glucuronide | | 38.1–48.4^a^ | 33.5–42.8 | 29.8–36.8
M10: 2-phenylpropionyl glucuronide | | ^b^ | N.D. | N.D.
M11: 2-phenylpropionyl glycine | | N.D. | 5.1–11 | 2.8–3.7
M12: S-(2-hydroxy-2-phenylpropyl)-N-acetylcysteine | | 4–4.9^c^ | trace | trace
M13: 2-phenyl-1-propanol glucuronide | | 4–4.9^c^ | 1.6–5.8^c^ | 1.5–2.3^c^
M14: 2-phenyl-2-propanol | | trace–1.8 | N.D.–1.5 | N.D.
M15: 2-phenyl-1-propanol | | N.D. | N.D.–1.6 | N.D.
M16: 2-phenylpropionic acid | | trace–2.1 | N.D.–trace | N.D.–trace

Source: Chen et al. (2011).

N.D. = not detected.

^a^ Total of M9 and M10.

^b^ M10 reported as a minor metabolite that coeluted with M9.

^c^ Total of M12 and M13.

Figure 2-1

Cumene Metabolism: Side-chain Oxidation

Source: Chen et al. (2011).

Figure 2-2

Cumene Metabolism: Ring Oxidation

Source: Chen et al. (2011).

Only one study of types of cytochromes P450 metabolizing cumene was identified, and it was limited to two mammalian cytochromes and one bacterial one. Henne et al. (2001) investigated the active site topography of rabbit CYP4B1 relative to rat CYP2B1 and bacterial CYP102 in vitro using cumene and several other aromatic substrates. CYP4B1 is primarily an extrahepatic monooxygenase and does not have a clearly defined endogenous substrate. Each of these cytochromes metabolized cumene to hydroxylated products. CYP2B1 and CYP102 preferentially formed 2-phenyl-2-propanol; however, reaction with CYP4B1 preferentially formed 2-phenyl-1-propanol along with a relatively small amount of 2-phenyl-2-propanol. CYP102 was the only enzyme that formed significant amounts of isopropylphenol, a ring-hydroxylated metabolite. α-Methylstyrene was not a significant metabolite for any of the enzyme preparations.

## 2.3 Synthesis and Summary

Few studies have investigated the absorption, distribution, metabolism, and excretion of cumene in humans. The available human data show that cumene or its metabolites are excreted in expired air and the urine. In a study of experimentally exposed volunteers, absorption of cumene via the pulmonary tract ranged from 64% down to 45% with decreased retention in the body with increasing exposure time. Urinary excretion of the primary cumene metabolite dimethylphenylcarbinol (2-phenyl-2-propanol) was monitored and the excretion half-life was biphasic with a half-life of 2 hours for phase I and 10 hours for phase II.

From studies in rodents and rabbits, it is known that cumene is readily absorbed following inhalation or oral exposure, and ^14^C-derived radioactivity is rapidly excreted in urine. It is also absorbed through the skin. Disposition and excretion studies in rodents report that at 24 hours post-exposure, tissues contained less than 3% of the total dose, with 70% to 90% of cumene excreted in the urine. Excretion of radioactivity in feces ranged from about 1% to 5.3%, and that in volatile organic compounds (VOCs) in expired air ranged from <1% to about 22%. Cumene accounted for more than 95% of the radioactivity recovered in VOCs excreted in expired air with the cumene metabolite, α-methylstyrene, accounting for 3% to 4% in mice and a trace amount in rats. Enterohepatic circulation of cumene metabolites was implied because about 37% of the total dose was detected in the bile in bile-duct cannulated rats, but very little was excreted in the feces in any treatment group.

Cumene is extensively metabolized by cytochrome P450 within hepatic and extrahepatic tissues, including the lung. Thirteen metabolites were detected in male rat urine, and five of these metabolites (2-phenylpropionic acid and four glucuronidated metabolites) also were detected in bile from male rats. Fifteen metabolites were detected in male and female mouse urine combined. These data indicate that metabolism primarily proceeds through side-chain oxidation, but ring oxidation also occurs in vivo. Proposed reactive metabolites that may be produced through ring oxidation of 2-phenyl-2-propanol include arene oxide intermediates, a catechol, and quinone methide. Three metabolites (α-methylstyrene, 2-phenyl-2-propanol, and 2-phenyl-1-propanol) were detected in microsomal incubations; female mouse lung microsomes metabolized more cumene than female mouse liver, female rat lung, or female rat liver microsomes. 2-Phenyl-2-propanol glucuronide was the most abundant metabolite in rat and mouse urine and rat bile.

Metabolism of cumene is complex and not fully elucidated; however, there are clear similarities across species and reactive intermediates of cumene can be generated by multiple metabolic pathways.