# 1 Properties and Human Exposure

Cumene is a natural component of petroleum (NAC-AEGL 2007) and an industrial chemical used primarily to manufacture phenol and acetone. It is a ubiquitous pollutant that may be released to the environment from (1) emission from petroleum products such as combustion of fossil fuels by land transportation vehicles, evaporative losses from gasoline stations, refueling losses, and oil spills, (2) emissions from its manufacturing, processing, and use, and (3) tobacco smoking.

This section describes the chemical and physical properties of cumene (Section 1.1); its uses and production (Section 1.2); biological indices of exposure (Section 1.3); the potential for environmental exposure including sources of release of cumene to the environment, cumene daily release estimates, fate and occurrence of cumene concentrations reported for air, water, and soil, and estimates of human exposure to cumene from the environment (Section 1.4); the potential for exposure from other sources such as food, cigarette smoking, and consumer products (Section 1.5); exposure in the workplace (Section 1.6); and exposure levels for people (Section 1.7). Section 1.8 summarizes the information in Sections 1.1 to 1.7. Human exposure tables and U.S. regulations and guidelines that potentially limit exposure to cumene are located in Appendix B.

## 1.1 Chemical Identification and Properties

Cumene (Figure 1-1) is structurally similar to benzene, toluene, ethylbenzene, xylenes, and styrene (Figure 1-2). Table 1-1 contains some chemical identification information for cumene.

Figure 1-1

Chemical Structure of Cumene

Figure 1-2

Chemical Structure of Some Cumene Analogues

Table 1-1 Chemical Identification of Cumene

Characteristic | Information
Chemical Abstracts index name | Cumene
CAS Registry number | 98-82-8
Molecular formula | C_9_H_12_
Synonyms | Cumol, isopropylbenzene, isopropylbenzol, (1-methylethyl)benzene, 2-phenylpropane

Sources: NTP (2009);WHO (1999).

Cumene exists as a volatile, colorless liquid with a sharp, penetrating aromatic or gasoline-like odor (NTP 2009). It is a flammable liquid with a flash point of 102°F [32.9°C], a lower flammable limit of 0.9% by volume and an upper flammable limit of 6.5% by volume (HSDB 2005). Cumene is stable under normal conditions but may become unstable at elevated temperatures and pressures. It forms cumene hydroperoxide when exposed to air for long periods and is incompatible with oxidizers, nitric acid, and sulfuric acid. Toxic gases and vapors such as carbon monoxide may be released during decomposition. Some physical and chemical properties for cumene are listed in Table 1-2.

Table 1-2 Physical and Chemical Properties of Cumene

Property | Information
Molecular weight | 120.2^a^
Melting point | −96°C^b^
Boiling point | 152.4°C^b^
Specific gravity | 0.862 at 20°C/4°C^a^
Solubility
Water (20°C) | 50 mg/L^a^ (practically insoluble)
Water (25°C) | 61.3 mg/L^b^
Most organic solvents | soluble^a^
Octanol/water partition coefficient (log K_ow_) | 3.66^b^
Vapor pressure (mm Hg) | 4.5 at 25°C^b^
Vapor density (air = 1) | 4.1^a^
Critical temperature | 358°C^a^
Henry’s law constant | 0.0115 atm-m^3^/mol at 25°C^b^
Conversion factors (cumene in air)
Parts per million (ppm) to µg/m^3^ | µg/m^3^ = 4,916.18 × (ppm)^c^
µg/m^3^ to parts per million (ppm) | ppm = 2.034 × 10^−4^ × (µg/m3)^c^

^a^ HSDB (2005).

^b^ ChemIDplus (2012).

^c^ SMARTe.org (2012).

## 1.2 Uses and Production

Cumene is used primarily to manufacture phenol and acetone (98%); but it is also used to manufacture acetophenone, alpha-methylstyrene, diisopropylbenzene, and dicumylperoxide (HSDB 2005). Cumene is also used as a constituent of some petroleum-based solvents such as naphtha, as a catalyst for acrylic and polyester resins, and as a raw material for peroxides and oxidation catalysts (NTP 2009). Other, direct uses include its use as a thinner for paints, enamels, and lacquers and as a solvent for fats and resins; as such, cumene has been suggested as a replacement for benzene. Cumene and phenol are reported to be starting materials used to make aspirin and penicillin (ICIS 2012).

Cumene is a naturally occurring component of refined fuels and it has been reported to be used in gasoline blending, diesel fuel, and high-octane motor fuels, particularly as an aviation fuel (Advameg 2012; HSDB 2005; NTP 2009). The proportion of cumene used as a blending component in fuels for internal combustion engines is difficult to estimate because manufacturers customarily do not disclose this information (NRC 1981).

The demand for cumene is largely driven by the demand for products derived from phenol and acetone (BusinessWire 2011), and demand for cumene is strongly tied to the phenol derivatives market. A major use for the cumene-derived molecules is in the production of polycarbonates via bisphenol-A (which is synthesized from two molecules of phenol and one molecule of acetone). Phenolic plastics uses (other than bisphenol-A) in the automobile industry include phenolic disc brake caliper pistons (Malviya 2006), carburetor spacers (AutoZone 2012), and ashtrays (Rebling 2012). Other applications for phenol include phenolic resins to bond construction materials (e.g., plywood and composition board), caprolactam to produce nylon-6 (e.g., carpet fibers and tire cord fabric), and alkylphenols (e.g., surfactant in detergents) (Chameides 2012; Hwang and Chen 2010; NPG6 2006a; 2006b; 2006c).

Demand for cumene ranged from 3.7 billion to 8.0 billion pounds per year from 1986 to 2003 (HSDB 2005); however, U.S. demand for cumene has decreased in recent years as increasing cumene and phenol production capacity at integrated cumene/phenol production plants in Asia decreased cumene exports from the United States (ICIS 2005). The uses of polycarbonates derived from bisphenol-A (and ultimately from cumene production of phenol and acetone) have increased in downstream industries such as electrical industries and the automobile and construction industries (NTP 1996); both the automobile and construction industries have rebounded in recent years (PRWeb 2011). In an April 2012 report, cumene demand was stable and was predicted to remain consistent for the coming months (ICIS 2012c).

Cumene is synthesized from propylene and benzene using an acidic catalyst, e.g., solid phosphoric acid, or a zeolite catalyst (ICIS 1999a; ICIS 1999b; NTP 2009). The cumene product is separated from the propylene and benzene reactants by distillation while non-reacted benzene is recycled (EC 2001). In 2011, cumene was manufactured by at least 50 companies worldwide, including at least 8 in the United States (SRI 2011). U.S. production data for cumene are shown in Table 1-3. Production data are based on Internet searches of sources dated as noted.

Table 1-3 Production Data for Cumene

Category | Years Covered | Quantity in Pounds^a^
Chemical Data Reporting Rule^b^ | 2006 | 1 billion and greater
U.S. imports (recent) | 2011 | 2.29 billion (reported as 1.04 billion kg)
U.S. imports (historical) | 1989 | 325 million (reported as 147 million kg)
U.S. exports (recent) | 2011 | 127 million (reported as 57.6 million kg)
U.S. exports (historical) | 1989 | 124 million (reported as 56 million kg)

Sources: US EPA (2010); SRI (2011); USITC (2013).

^a^ From 1/2013 Internet search; data subject to change.

^b^ Formerly called the Inventory Update Rule.

## 1.3 Biological Indices of Exposure

Biological indices of exposure to cumene have not been widely used to assess exposure, but potential biological indices include measurement of cumene in blood (see Section 1.8) and measurement of the cumene metabolite dimethylphenylcarbinol (see Section 2 for a discussion of cumene metabolism) in urine. Seńczuk and Litewka (1976) showed a directly proportional dependence between the amount of dimethylphenylcarbinol excreted in urine and the amount of cumene absorbed; however, no publication has been identified in which this metabolite was used as a biological index of exposure to cumene.

## 1.4 Potential for Environmental Exposure

This section describes sources of release of cumene to the environment (Section 1.4.1), cumene daily release estimates (Section 1.4.2), fate and occurrence of cumene in air, water, and soil (Section 1.4.3), and estimates of human exposure to cumene from the environment (Section 1.4.4).

### 1.4.1 Release of Cumene to the Environment

Sources of release of cumene to the environment can be classified as being related to cumene manufacturing, processing, and use, or emission of petroleum products. Cumene release from these sources was estimated to be 21 million pounds annually in the United States (HSDB 2005). See Section 1.5 for a discussion of consumer exposures (e.g., cigarette tobacco during consumption, office equipment, etc.).

Other, unquantified anthropogenic sources of cumene release include operations involving the vulcanization of rubber, building materials, jet engine exhaust, outboard motor operation, solvent uses, paint manufacture, pharmaceutical production, and textile plants. Cumene is also released to the environment from leather tanning, iron and steel manufacturing, paving and roofing, paint and ink formulation, printing and publishing, ore mining, coal mining, organics and plastics manufacturing, pesticide manufacturing, electroplating, and pulp and paper production (HSDB 2005).

### 1.4.2 Releases from Production, Processing, and Use

The loss of cumene to air during production has been reported to range between 0.08 kg cumene/tonne for emissions-controlled production and 0.27 kg cumene/tonne for uncontrolled production (EC 2001; Peterson 1980). The reported release factor to air for use of cumene in synthesis is 1.03 kg cumene/tonne phenol. These data indicate that the release of cumene from cumene use in synthesis of phenol is higher than the release of cumene from the production of cumene. Similarly, a release factor for combined release to air (including release to air from wastewater) of 1.31 kg cumene/tonne, a release factor for release to wastewater of 1.5 kg/tonne, and a release factor for release to soil of 0.02 kg/tonne from cumene production and use have been reported.

According to the U.S. Environmental Protection Agency (EPA) Toxics Release Inventory (TRI), total reported on- and off-site release of cumene was slightly over 1 million pounds from more than 300 facilities in 2010 (TRI 2012). Releases to air accounted for 94.1% of total releases, releases to land for 4.4%, off-site disposal for 1.3%, disposal by underground injection for 0.2%, and releases to water for 0.1%. (See Section 1.4.4 for estimates of the numbers of individuals living near facilities reporting release of cumene to the air.)

TOXMAP is a Geographic Information System (GIS) from the National Library of Medicine (NLM) that uses maps of the United States to help users visually explore data from EPA’s TRI and Superfund programs. Figure 1-3 shows a color-coded map of reported TRI on-site cumene releases into the air, water, and ground for 2010 (TOXMAP 2012). The color of each circle indicates the amount of total on-site release for calendar year 2010. Figure 1-4 shows a map of Superfund sites on the National Priorities List (NPL) at which cumene was listed as a site contaminant (TOXMAP 2012). The NPL is the list of national priorities among the known releases or threatened releases of hazardous substances, pollutants, or contaminants throughout the United States and its territories. Based on the visual depiction of cumene releases in Figure 1-3, cumene has been released at industrial facilities throughout the United States, largely in the central and northeast regions. Based on Figure 1-4, Superfund sites at which cumene was listed as a site contaminant appear to be located in the northeast and Alaska.

Figure 1-3

Map of Reported TRI On-site Cumene Releases for 2010

Figure 1-4

Map of the Superfund Sites at Which Cumene Was Listed as a Site Contaminant

In 1988, the U.S. EPA estimated that approximately 3 million pounds of cumene were released annually to the environment from cumene manufacturing and processing facilities (US EPA 1988). This estimate was derived from emission rate data for vents, flanges, drains, valves, and pumps suspected of leaking cumene in the average cumene manufacturing and/or processing unit. The lower release estimates in the 2010 TRI data may result in part because of manufacturing process improvement involving retrofitting to zeolite catalyst technology from solid phosphoric acid (SPA) catalysts.

Part of the manufacturing, processing, and use chain also includes transportation of cumene product. Based on a review of spill report data from the National Response Center covering the time period of January 1, 1990 to the present, approximately 180 spill incidents involving cumene were reported (National Response Center 2012). One such incident involved the release of up to an estimated 10,300 gallons of cumene into the Ohio River between Illinois and Kentucky after a barge carrying 960,000 gallons of cumene collided with a lock wall (Platts 2007).

### 1.4.3 Releases from Emission of Petroleum Products

Releases of cumene related to emission of petroleum products include releases during the transportation, distribution, and use of motor fuels (e.g., emissions from combustion of fossil fuels by land transportation vehicles, evaporative losses from gasoline stations, refueling losses, etc.) and accidental spills of petroleum products such as oil spills. These types of sources are more numerous than sources related to manufacturing, processing, and use; therefore, releases related to emission of petroleum products may be a larger concern to the general population.

Cumene is a naturally occurring component of crude oil, coal tars, and some plants (NTP 2009). Crude oils typically contain 0.1 weight percent (wt%) cumene but may contain up to 1.0 wt% cumene (WHO 1999). Various grades of gasoline have cumene concentrations ranging from 0.14 to 0.51 volume percent (vol%) with an average cumene concentration of 0.3 vol%. The cumene concentration in premium diesel fuel is 0.86 wt% and that in furnace oil (no. 2) is 0.6 wt%.

Emission rates from motor vehicles were studied for vapor-phase, semi-volatile, and particle-phase organics inside and outside a Los Angeles roadway tunnel in 1993; cumene was emitted at a rate of 11 mg/L of gasoline consumed (HSDB 2005). In a study to determine concentrations and emissions of gasoline and other vapors from residential vehicle garages, the average concentration of cumene was reported to be 1.64 µg/m^3^ (Batterman et al. 2006). In a study to evaluate the benefits of various vehicles with and without catalytic converters, cumene emissions were reported as 0.0002 and 0.0009 g/km for two vehicles with catalytic converters and as 0.002 g/km for a vehicle without a catalytic converter (HSDB 2005).

Though many data are available regarding environmental monitoring and sampling related to the April 4, 2010, Deepwater Horizon oil spill in the Gulf of Mexico, little information related specifically to exposure to cumene from the spill could be identified. NIOSH Health Hazard Evaluation (HHE) exposure monitoring data for Deepwater Horizon response workers include only 17 cumene concentration data points for dispersant operations and in situ burning operations ranging from 0.13 to 0.79 ppb [0.64 to 3.9 µg/m^3^] (NIOSH 2011). Based on an estimated total of 4.9 million barrels [approximately 1.5 billion pounds] of oil discharged from the Deepwater Horizon wellhead from April 20 to July 14, 2010 (FISG 2010) and the WHO estimate of crude oil typically containing 0.1 to 1.0 wt% cumene, approximately 1.5 million to 15 million pounds of cumene might have been released during the Deepwater Horizon oil spill. An Operational Science Advisory Team (OSAT) petroleum residue data analysis indicates that cumene is sufficiently volatile that it was not present in any residual petroleum hydrocarbons that might have existed on Gulf beaches after months of weathering (OSAT 2011), and results of controlled oil spills at sea confirmed that cumene disappeared within 90 minutes (Harrison 1975). No data regarding how cumene in oil is transported from deep water to the surface were identified.

### 1.4.4 Daily Release Estimates

Based on data for cumene daily release rate estimates for manufacturing, processing, and use, as well as for gasoline marketing, distribution, and use and other sources of release (see Appendix B, Table B-1, most of the cumene released into the environment from manufacturing, processing, and use is released to the air (94.1% of total reported on- and off-site releases based on the most recent TRI data). The amount of cumene released to air from cumene use in synthesis of phenol is higher than the release of cumene from the production of cumene (see Section 1.4.1). The estimated amount of cumene released to air from gasoline distribution (3,211 kg/day), and use (20,298 kg/day) (total = 23,509 kg/day) is slightly higher than the release of cumene to air from cumene production and use (17,903 kg/day) (see Appendix B, Table B-1).

### 1.4.5 Fate and Occurrence

This section describes fate and occurrence data for cumene in air (e.g., cumene air concentrations in industrial areas, urban areas, rural areas, etc.), water (e.g., cumene concentrations in drinking water, groundwater, surface water, etc.), and soil.

#### Air

If released to air, a vapor pressure of 4.5 mm Hg at 25°C indicates cumene will exist solely as a vapor in the ambient atmosphere (HSDB 2005; WHO 1999).

Review of available cumene atmospheric concentration level data for the United States and other countries shows that ranges (see Appendix B, Table B-2) for cumene atmospheric concentration measurement data for industrial, urban, and rural areas within the United States are similar to measurements in those areas for other countries (including unspecified countries), but several reported levels from outside the United States exceeded the highest value identified for U.S. data of 144 µg/m^3^ measured in Los Angeles, CA in 1966 (HSDB 2005). For both U.S. and non-U.S. data, reported concentrations in industrial settings ranged from 1.6 to 2,700 µg/m^3^, the highest value was associated with an electronics fire. For urban settings, concentrations ranged from 0.1 to 900 µg/m^3^. Reported concentrations in rural settings ranged from 0 to 34.79 µg/m^3^.

Data for cumene in residential indoor air were identified from only two studies, one in the United States in rural western Montana (Ward et al. 2009) and the other in Quebec City, Canada (Héroux et al. 2008) (see Appendix B, Table B-3). In Ward et al. (2009), maximum indoor cumene concentration levels were greater than maximum ambient cumene concentration levels (see Appendix B, Table B-3) in both the 2004 to 2005 and 2005 to 2006 sampling events. No significant correlation was found between indoor and ambient concentrations of cumene.

Based on these data, cumene has been measured in the atmosphere at significant levels at many geographical locations throughout the United States. Most likely due to the association of cumene with the combustion of petroleum, atmospheric cumene levels are several-fold higher in industrial and urban settings than in rural areas. Thus, measurable exposure of the general population to atmospheric cumene is likely in industrial and urban areas in the United States.

#### Water

Available data for cumene concentrations in drinking water in the United States indicate that drinking water is not a major source of exposure. Appendix B, Table B-4 presents cumene concentration measurement data in water and sediment for the United States, other countries, and other unspecified areas. From the large number of samples in these studies with no detectable cumene and others with levels at or below the limit of detection, it is reasonable to conclude that U.S. drinking waters only rarely contain cumene contamination above 0.5 µg/L (US EPA 1987; WHO 1999).

Cumene levels in groundwater appear to be highest near industrial sources. Elevated levels were reported in 1984 for groundwater near underground solvent storage tanks in Italy (1,581 µg/L) (EC 2001). Likewise, a level of 360 µg/L was measured near a chemical plant in an unspecified location by researchers in Czechoslovakia (Teplý and Dressler 1980). Cumene levels in groundwater are lower in areas not identified as industrial areas, with values ranging from detected but not quantified to less than 0.5 µg/L (HSDB 2005).

Levels of cumene in surface water for the United States and other countries are mostly low and similar. Levels for the United States range from detected but not quantified to 0.017 µg/L (EC 2001; HSDB 2005).

Review of the limited available cumene sediment and biota concentration level data for the United States and other countries shows elevated levels in the United States relative to other countries. Levels for sediments and biota in the United States ranging from 20 to 19,000 µg/kg were measured in Puget Sound, WA in 1979 (WHO 1999).

Cumene concentration levels in wastewater and other industrial effluents appear to vary widely. Cumene levels in unspecified wastewater ranged from 0.1 to 5 µg/L (EC 2001). Elevated cumene levels were reported around outboard motor operations (700 µg/L) and near offshore drilling platforms (140 µg/L) (WHO 1999).

No occurrences of cumene in rainwater have been reported and its removal from atmosphere in rainfall is unlikely. However, a few data have been reported for cumene in snow (see Appendix B, Table B-4).

A European Union risk assessment concluded that the weight of evidence on degradation data and the information available for other related chemicals indicate that cumene should be classified as inherently biodegradable (EC 2001). Measured and estimated bioconcentration factor (BCF) values for cumene suggest a slight potential for cumene to bioconcentrate in fish species (Ogata et al. 1984). Cumene was detected at levels of 0.5 to 1.4 ng/g wet weight in 12 of 138 sampled fish of various species from locations near a potential emission source as reported by the Japan Environment Agency in 1987 (WHO 1999).

In summary, cumene has been measured in water in many geographical locations throughout the United States. The highest cumene concentrations appear to be associated with groundwater near industrial sources and with industrial effluents. Elevated cumene levels also have been measured for sediments and biota. Surface water and drinking water concentrations are several-fold lower than concentrations associated with groundwater near industrial sources, industrial effluents, and sediments and biota. People living in the United States are not likely to be exposed to cumene from water intake.

#### Soil

The main source of soil contamination by cumene is from point emissions caused by garage spills or from locations near gasoline stations (EC 2001). (See Appendix B, Table B-5 for cumene soil concentration measurement data that have been identified.)

Cumene is expected to have low mobility in soil. Volatilization from moist soil surfaces is expected to be an important fate process. Cumene may volatilize from dry soil surfaces based on its vapor pressure; however, adsorption to soil is expected to attenuate volatilization (WHO 1999). Biodegradation is also expected to be fairly rapid. Based on these data, people living in the United States are not likely to be exposed to cumene from soil.

### 1.4.6 Estimates of Human Exposure to Cumene from the Environment

This section describes estimates of the numbers of people living near cumene-emitting facilities based on TRI and U.S. Census data and estimates of daily cumene intake from exposure to cumene from the environment.

#### Estimated Numbers of People Living near Cumene-emitting Facilities

Based on 2010 TRI data, the top 10 cumene-emitting facilities released approximately 742,000 pounds of cumene to the air, accounting for 78% of total cumene air emissions in 2010 (TRI 2012). Table 1-4 presents demographic data from EPA’s EJView website based on U.S. Census data for 2000 for areas within 0.5 mile and 1 mile of the top 10 cumene-emitting facilities in 2010. Based on these data, approximately 7,900 people lived within 0.5 mile of these facilities, and 43,400 people lived within 1 mile of these facilities.

Table 1-4 Demographic Data for Areas within 0.5 Mile and 1 Mile of the Top 10 Cumene-emitting Facilities in 2010

City | State | Cumene Air Emissions (Pounds) | Total Persons within 0.5 Mile | Total Persons within 1 Mile
Mount Vernon | IN | 243,000 | 16 | 62
Franklin Furnace | OH | 109,002 | 104 | 401
Deer Park | TX | 84,531 | 0 | 83
Philadelphia | PA | 63,370 | 7,153 | 26,670
Philadelphia | PA | 51,690 | 261 | 14,616
Pasadena | TX | 44,284 | 24 | 134
Plaquemine | LA | 40,400 | 131 | 520
Freeport | TX | 39,730 | 30 | 400
Ottawa | IL | 33,585 | 24 | 122
Theodore | AL | 32,666 | 108 | 409
Total | | 742,258 | 7,851 | 43,417

Sources: US EPA (2012); TRI (2012).

#### Estimated Daily Intake from Exposure to Cumene in the Environment

The European Union System for the Evaluation of Substances (EUSES) model has been used to estimate daily human intake of cumene for local and regional exposure levels. These estimates suggest that the greater amount of human exposure to cumene via the environment will be from the air (>97% of estimated total exposure). The local environment is considered in the European Union document to be a distance of 100 meters from a point source of release, and the regional environment is considered to be a highly industrialized area accounting for 10% of European production or use (EC 2001). Figure 1-5 depicts this information graphically for the local and regional exposure scenarios.

Figure 1-5

Estimated Human Daily Intake of Cumene for Local Exposure Level

Source: EC (2001)

## 1.5 Potential for Exposure from Other Sources: Food, Cigarette Smoking, and Consumer Products

### 1.5.1 Food

The occurrence of cumene in food may be from environmental or processing sources, or it may occur naturally (US EPA 1987). Trace quantities of cumene have been detected in papaya, sapodilla fruit, and Australian honey. Cumene has been detected but not quantified in fried chicken, tomatoes, Concord grapes, cooked rice, oat groats, baked potatoes, Beaufort cheese, fried bacon, dried legumes (beans, split peas, and lentils), southern pea seeds, and Zinfandel wine (HSDB 2005). It also has been detected in chicken and pork.

Cumene has been an analyte in the U.S. Food and Drug Administration’s Total Diet Study (TDS). Based on analytical results for TDS market baskets 1991–3 through 2003–4 collected between September 1991 and October 2003, cumene was found at levels ranging from 0.002 to 0.063 ppm in 18 different foods including fruit-flavored popsicles and sherbet, cake doughnuts (any flavor), sweet rolls and Danish pastries, and raw navel and Valencia oranges. Cumene was found at trace levels (defined by FDA as greater than or equal to the limit of detection but less than the limit of quantitation) in 18 additional foods including eggs scrambled with oil, enriched white bread, presweetened fruit-flavored cereal, regular salted margarine and butter, and catfish pan-cooked with oil (FDA 2006).

### 1.5.2 Cigarette Smoking

Cumene levels ranging from 7 to 14 µg/cigarette in condensates of cigarette smoke have been reported (WHO 1999). The U.S. Department of Agriculture (USDA) estimated that 360 billion cigarettes were consumed in the United States in 2007 (USDA 2007).

### 1.5.3 Consumer Products

Cumene is present at concentrations ranging from 1% to 5% in several consumer products including automobile products (e.g., fuel injector system cleaners), home maintenance products (e.g., roof adhesives, concrete cleaners, and degreasers), and some agricultural herbicides (e.g., weed control for wheat) (HPDB 2012). More than a dozen additional products were reported to contain cumene at less than 1% or with unspecified concentrations of cumene.

Cumene has also been determined to be a volatile organic compound released by photocopying machines during operation at an emission rate ranging from 140 to 220 µg/hour (HSDB 2005).

Cumene has been identified but not quantified in emissions from antistatic fabric softener pads and crib mattresses (Anderson and Anderson 2000a; 2000b). Cumene has also been reported to be a perfume component (NAC-AEGL 2007), but no information was identified on specific products containing cumene or possible exposure.

In summary, cumene has been detected in cigarette smoke, at trace levels in food, and in small amounts in consumer products. Cumene may occur in food naturally, or from environmental or processing sources. However, in comparison with estimated human daily intake of cumene from air, intake of cumene from food is very low (see Figure 1-5).

## 1.6 Characterization of Exposure in the Workplace

Occupational exposure to cumene may occur through inhalation and dermal contact at workplaces where cumene is produced or used (HSDB 2005). Based on data from area monitoring samples for cumene in different occupational settings (see Appendix B, Table B-6) the main exposure route for occupational populations is via inhalation, which may be up to ten thousand-fold greater than ambient atmospheric concentrations at the upper end of the range of reported concentrations. For example, overall urban atmospheric cumene levels have been reported to be 14.7 µg/m^3^, while air samples for cumene-exposed workers (performing unspecified tasks in manufacturing and processing cumene) have been reported to be as high as 150,000 µg/m^3^ (see Appendix B, Table B-2 and Table B-6). The majority of exposure levels reported, however, were less than 1 ppm (5,000 µg/m^3^). High levels of exposure also may occur for users of products containing cumene outside of the manufacturing industry (e.g., painting [up to 17,000 µg/m^3^] and car repair [up to 33,000 µg/m^3^]). The National Institute for Occupational Safety and Health (NIOSH) sampling and analysis method for cumene is NIOSH Manual of Analytical Methods (NMAM) Fourth Edition Method 1501 (NIOSH 2003). The Occupational Safety and Health Administration (OSHA) sampling and analysis method for cumene is OSHA PV2137 (OSHA 2004). Occupational populations also may be exposed via the dermal route during shutdown activities (e.g., cleaning and maintenance) at cumene manufacturing and processing facilities, but no quantitative exposure levels were identified for this route of exposure. As cumene is a component of gasoline, there also is potential occupational exposure to gasoline station employees, but no quantitative information on this exposure route was identified.

The OSHA Chemical Exposure Health Dataset contains OSHA compliance monitoring program industrial hygiene samples. Cumene sampling data are available for 1985 to 2009. Of the 558 total sample points for cumene, 509 samples from 66 facilities are personal breathing zone samples. Samples with detectable values (N = 157) range from 0.0092 to 8.0913 ppm, all of which are well below the OSHA Permissible Exposure Limit (PEL) of 50 ppm (OSHA 2011).

The NIOSH National Occupational Exposure Survey (NOES), conducted between 1981 and 1983, estimated that 14,267 workers, including 2,760 female workers, were potentially exposed to cumene in the workplace. Among the occupational descriptions with the highest numbers of employees (men and women combined) potentially exposed to cumene were miscellaneous machine operators in business services (2,823), vehicle washers and equipment cleaners at automotive dealers and service stations (1,723), janitors and cleaners in health services (1,584), and laundering and dry cleaning machine operators in personal services (1,475) (NIOSH 1990). (Note: The NOES database has not been updated since July 1, 1990, and NIOSH has not conducted any national surveys of occupational exposure since that time.) An industrial hygiene survey submitted to the U.S. EPA by the Chemical Manufacturing Association Cumene Program Panel reported information on 739 U.S. workers at manufacturing and processing facilities having either routine (393) or intermittent (346) exposure to cumene (US EPA 1988; WHO 1999). Personal exposure data for these workers are reported in Appendix B, Table B-6.

Cumene is usually produced, stored, and converted in closed systems. One European company has reported that potential contacts with cumene could occur during sampling, loading of tankers, or cleaning and maintenance activities (EC 2001).

In summary, the main exposure route for cumene in occupational settings is via inhalation. Most reported exposure levels were less than 1 ppm (5,000 µg/m^3^); however, at the upper end of the reported exposure range, occupational exposures may be as much as ten thousand-fold higher than ambient atmospheric concentrations. Further, high exposure levels (i.e., tens of thousands of µg/m^3^) also may occur in occupational populations other than those in the manufacturing industry, such as painting and car repair. Dermal exposure to cumene may occur at manufacturing and processing facilities during shutdown activities such as cleaning and maintenance. However, as accidental contacts with cumene are not expected to occur on most days and gloves may be worn to avoid direct contact with cumene, dermal exposure is expected to be low to negligible.

## 1.7 Exposure Levels for People

Trace levels of cumene were detected in some of the expired air samples collected from 28 nonsmoking, healthy volunteers who lived in an urban setting with no intentional exposure to the chemical (Krotoszynski et al. 1977). Brugnone et al. (1989) measured cumene in the blood and breath of two groups, a group of individuals belonging to a hospital staff and a group of chemical workers who were exposed to cumene from the environment rather than from their occupational duties (see Table 1-5). Chemical workers were examined in the plant infirmary in the morning before the start of the work shift, and the hospital staff was examined in the hospital infirmaries. One environmental air sample was taken per each individual biological sample. The environmental concentration of cumene was higher, although not statistically significant, in the plant than in the hospital infirmaries. Blood cumene concentration and alveolar concentration were higher in the chemical workers compared with the hospital workers, but the difference was only statistically significant for blood cumene concentration.

Table 1-5 Cumene Environmental, Alveolar, and Blood Concentration Data from Study of Chemical Workers and Hospital Staff

Type of Worker | Environmental Conc., 8 h, ng/L (i.e., µg/m^3^); Mean (Range), [N] | Alveolar Conc., ng/L (i.e., µg/m^3^); Mean (Range), [N] | Blood Conc., ng/L (i.e., µg/m^3^); Mean (Range), [N]
Chemical workers | 38.9 (1–279), [27] | 12.0 (1–81), [27] | 762* (43–3,352), [27]
Hospital workers | 9.6 (2–36), [40] | 4.7 (1–22), [38] | 176 (31–929), [33]

Source: Brugnone et al. (1989).

* p < 0.002, Wilcoxon-Mann-Whitney test.

In Perbellini et al. (1988), a study to determine 13 industrial solvents in blood, alveolar air, and urine, the concentration of cumene was measured in 49 Italian blood donors. For an environmental air concentration of 6 ± 2 ng cumene/L (geometric mean ± standard deviation) (range 1 to 21 ng/L), specimen analysis results were as follows: alveolar air, 3 ± 2 ng/L (range 1 to 14 ng/L), blood, 199 ± 2 ng/L (range 17 to 963 ng/L), and urine, 202 ± 2 ng/L (range 20 to 1,190 ng/L) (EC 2001).

## 1.8 Synthesis and Summary

Cumene (isopropylbenzene, CASRN 98-82-8) is an alkylated benzene found in fossil fuels, such as blended gasoline and kerosene, and products of incomplete combustion (IARC 2012). It is a high-production-volume chemical in the United States with the majority of its use in the synthesis of acetone and phenol.

A significant number of people in the United States are exposed to cumene as a result of its presence in fossil fuels, solvents, cigarette smoke, and the workplace. Exposure to cumene in the workplace occurs from its production and use in the chemical industry. Other evidence demonstrating exposure to cumene is that it has been detected in blood, alveolar air, expired air, and urine from people without known occupational exposure to cumene, including non-smoking individuals living in an urban environment.

Exposure to cumene occurs primarily via inhalation. Cumene has been measured in the atmosphere in many geographical locations throughout the United States, and levels are several-fold higher in industrial and urban settings than in rural areas, presumably because of cumene’s presence in petroleum emissions. As cumene is a natural component of petroleum, its emissions are ubiquitous in the environment from combustion of fossil fuels by land transportation vehicles or evaporative losses of fuel during distribution. People living in the United States are not likely to be exposed to cumene from water intake or from exposure to contaminated soil resulting from point emissions caused by garage spills or from locations near gasoline stations.

Potential exposure to cumene for occupational populations results from its primary use as a high-production-volume chemical to manufacture phenol and acetone, and the exposure can occur via both inhalation and dermal routes. Most reported levels for inhalation exposures were less than 1 ppm, but high levels up to 1,000 to 10,000 times higher have been reported; these higher exposure levels may also occur for users of products containing cumene outside of the manufacturing industry (e.g., painting and car repair).

Cumene is also present in small amounts (concentrations ranging from 1% to 5% or not quantified) in several consumer products including automobile fuel injector system cleaners, roof adhesives, some agricultural herbicides, fabric softener pads, and crib mattresses. Only trace levels of cumene have been detected in food, which may result from environmental or processing sources, or it may occur naturally. Cumene also has been detected (i.e., tens of µg per cigarette) in cigarette smoke.