# Peer Review

Peer review of the Draft RoC Monograph on Cumene was conducted by an ad hoc expert panel at a public meeting held March 21–22, 2013, at the National Institute of Environmental Health Sciences, Keystone Building, Research Triangle Park, NC (see https://ntp.niehs.nih.gov/go/38854 for materials, minutes, and panel recommendations from the peer review meeting). The selection of panel members and conduct of the peer review were performed in accordance with the Federal Advisory Committee Act and Federal policies and regulations. The panel members served as independent scientists, not as representatives of any institution, company, or governmental agency.

In this capacity, panel members had the following major responsibilities in reviewing the draft RoC monograph:

1. To comment on the draft cancer hazard evaluation for cumene, specifically, whether they are technically correct and clearly stated, whether the NTP has objectively presented and assessed the scientific evidence, and whether the scientific evidence is adequate for applying the RoC listing criteria.
2. To comment on the draft substance profile on cumene, specifically, whether the scientific justification presented in the substance profile supports the NTP’s preliminary policy decision on the RoC listing status of cumene (available in the RoC, first listed in the 14th edition, at https://ntp.niehs.nih.gov/ntp/roc/content/profiles/cumene.pdf).

The Panel was also asked to vote on the following questions:

1. Whether the scientific evidence supports the NTP’s conclusion on the level of evidence for carcinogenicity from experimental animal studies on cumene.
2. Whether the scientific evidence supports the NTP’s preliminary listing decision for cumene in the RoC.

The panel agreed with the NTP conclusions that cumene should be listed in the RoC based on sufficient evidence of carcinogenicity for lung tumors in male and female mice and liver tumors in female mice. However, the panel concluded the evidence for renal tumors in male rats was supportive rather than contributing directly to the sufficiency of evidence of carcinogenicity from studies in experimental animals. The NTP concurred with the expert panel conclusions in the revised draft RoC monograph on cumene.

## Peer Reviewers

- Lucy Anderson, Ph.D., DABT (Chair)
  Consultant for Biomedical Sciences and Toxicology
  Catonsville, Maryland, USA
- Leo Thomas Burka, Ph.D.
  Consultant
  Cary, North Carolina, USA
- Michael Elwell, D.V.M., Ph.D.
  Senior Pathologist
  Department of Pathology
  Nonclinical Safety Assessment
  Covance Laboratories Inc.
  Chantilly, Virginia, USA
- Terry Gordon, Ph.D.
  Professor
  Department of Environmental Medicine
  New York University School of Medicine
  New York, New York, USA
- Lawrence H. Lash, Ph.D.
  Professor and Associate Chair
  Department of Pharmacology
  Wayne State University School of Medicine
  Detroit, Michigan, USA
- Stephen Nesnow, Ph.D.
  Consultant
  Chapel Hill, North Carolina, USA
- Wayne T. Sanderson Ph.D., CIH
  Professor and Chair
  Department of Epidemiology
  College of Public Health
  University of Kentucky
  Lexington, Kentucky, USA
- MaryJane K. Selgrade, Ph.D.
  Senior Toxicologist
  ICF International
  Environmental Risk and Toxicology
  Durham, North Carolina, USA
- Paul A. White, Ph.D.
  Leader, Genetic Toxicology Group
  Environmental Health Sciences and Research Bureau
  Health Canada
  Ottawa, Ontario, Canada