# Abbreviations

  ^1^H NMR: proton nuclear magnetic resonance
  8-OH-dG: 8-hydroxydeoxyguanosine
  AAF: 2-acetylaminofluorene
  ACGIH: American Conference of Governmental Industrial Hygienists
  ADBAQ: 1-amino-2,4-dibromoanthraquinone
  AEGL: Acute Exposure Guideline Level
  CHO: Chinese hamster ovary
  dA: deoxyadenosine
  DEN: diethylnitrosamine
  dG: deoxyguanosine
  DNA: deoxyribonucleic acid
  EASE: Estimation and Assessment of Substance Exposure
  EG: ethylguanine
  Endo III: endonuclease III
  ENU: N-Ethyl-N-nitrosourea
  EPA: Environmental Protection Agency
  Erk MAPK: extracellular signal-regulated kinase mitogen activated pathway
  ET: ethylthymine
  EUSES: European Union System for the Evaluation of Substances
  FDA: Food and Drug Administration
  FLARE: fragment length analysis with repair enzyme
  Fpg: formamidopyrimidine
  FRTG: Flow Rate Technical Group
  G: guanine
  GAC: Genetic Alterations in Cancer
  GI: gastrointestinal
  GIS: Geographic Information System
  HDAC: histone deacetylase
  HEG: (2-hydroxyethyl) guanine
  HGPRT: hypoxanthine-guanine phosphoribosyl transferase
  HHE: Health Hazard Evaluation
  HIC: highest ineffective concentration
  HID: highest ineffective dose
  HPLC: high-performance liquid chromatography
  hr: hour
  I: inconclusive
  i.p.: intraperitoneal
  i.v.: intravenous
  kg: kilogram
  L: liter
  LEC: lowest effective concentration
  LED: lowest effective dose
  LOH: loss of heterozygosity
  m3: cubic meter
  MG: methylguanine
  mg: milligram
  mL: milliliter
  MS: mass spectrometry
  N.D.: not detected; not determined
  NA: not applicable
  NCE: normochromatic erythrocyte
  NDMA: N-nitrosodimethylamine
  NIOSH: National Institute for Occupational Safety and Health
  NLM: National Library of Medicine
  NNK: 4-(N-nitrosomethylamino)-1-(3-pyridyl)-1-butanone
  NOES: National Occupational Exposure Survey
  NPL: National Priorities List
  NR: not reported; none reported
  NS: not significant
  NT: not tested
  OEG: (2-oxoethyl)guanosine
  OGG1: 8-oxoguanine glycosylase 1
  OSAT: Operational Science Advisory Team
  OSHA: Occupational Safety and Health Administration
  OTM: olive tail moment
  PCE: polychromatic erythrocyte
  PCNA: proliferating cell nuclear antigen
  ppm: parts per million
  ROS: reactive oxygen species
  RQ: reportable quantity
  SAFE: significance analysis of function and expression
  SCE: sister-chromatid exchange
  SOCMI: synthetic organic chemical manufacturing industry
  SPA: solid phosphoric acid
  TDS: Total Diet Study
  TL: tail length
  TRI: Toxics Release Inventory
  TSCA: Toxic Substances and Recovery Act
  UDS: unscheduled DNA synthesis
  UK: United Kingdom
  VOC: volatile organic compound
  wt%: weight percent
  µg: microgram