# References

Advameg. 2012. Organic industrial chemistry. Advameg, Inc. http://www.chemistryexplained.com/Hy-Kr/Industrial-Chemistry-Organic.html. [Accessed: June 14, 2012].
Ahmad D, Caldwell J. 1994. Lack of stereoselectivity of the peroxisome proliferation induced by 2-phenylpropionic acid: Evidence against a role for lipid disturbance in peroxisome proliferation. Chirality. 6(5):365–371. 10.1002/chir.530060502 8068495
American Petroleum Institute (API). 1984. American Petroleum Institute letter to TSCA Interagency Testing Committee, U.S. EPA.
Anderson RC, Anderson JH. 2000 a. Respiratory toxicity of fabric softener emissions. J Toxicol Environ Health A. 60(2):121–136. 10.1080/009841000156538 10872633
Anderson RC, Anderson JH. 2000 b. Respiratory toxicity of mattress emissions in mice. Arch Environ Health. 55(1):38–43. 10.1080/00039890009603383 10735518
Arnts RR, Meeks SA. 1980. Biogenic hydrocarbon contribution to the ambient air of selected areas. Tulsa, Great Smokey Mountains, Rio Blanco County, CO. Research Triangle Park, NC: U.S. Environmental Protection Agency. EPA-600/3-80-023.
Arnts RR, Meeks SA. 1981. Biogenic hydrocarbon contribution to the ambient air of selected areas. Atmos Environ. 15(9):1643–1651. 10.1016/0004-6981(81)90149-9
Austin CC, Wang D, Ecobichon DJ, Dussault G. 2001 a. Characterization of volatile organic compounds in smoke at municipal structural fires. J Toxicol Environ Health A. 63(6):437–458. 10.1080/152873901300343470 11482799
AutoZone. 2012. Edelbrock/1 in. Holley 4 BBL 4 hole black phenolic plastic carburetor spacer - Not legal for sale or use on pollution controlled motor vehicles. AutoZone. http://www.autozone.com/autozone/accessories/Edelbrock-1-in-Holley-4-BBL-4-hole-black-phenolic-plastic-carburetor-spacer-Not-legal-for-sale-or-use-on-pollution-controlled-motor-vehicles/_/N-26vw;jsessionid=2A275F3928CB44A595210049BD23872C.diyprod4-b2c14?itemIdentifier=119552_0_0_&target=shelf. [Accessed: May 22, 2012].
Bachhausen P. 1990. Experiences with microbiological on-site decontamination of soil and building debris contaminated with solvents. In: Arendt F, Hinsenveld M, Van Den Brink WJ, editors. Contaminated Soil ’90. Dordrecht: Springer. p. 983–988. 10.1007/978-94-011-3270-1_212
Bakke OM, Scheline RR. 1970. Hydroxylation of aromatic hydrocarbons in the rat. Toxicol Appl Pharmacol. 16(3):691–700. 10.1016/0041-008X(70)90074-8 5422210
Batterman S, Hatzivasilis G, Jia C. 2006. Concentrations and emissions of gasoline and other vapors from residential vehicle garages. Atmos Environ. 40:1828–1844. 10.1016/j.atmosenv.2005.11.017
Bianchi AP, Varney MS, Phillips J. 1991. Analysis of volatile organic compounds in estuarine sediments using dynamic headspace and gas chromatography-mass spectrometry. J Chromatogr. 542:413–450. 10.1016/S0021-9673(01)88779-3
Bos R, Guicherit R, Hoogeveen A. 1977. Distribution of some hydrocarbons in ambient air near Delft and the influence on the formation of secondary air pollutants. Sci Total Environ. 7:269–281. 10.1016/0048-9697(77)90050-X 68543
Botta D, Castellani Pirri L, Mantica E. 1984. Ground water pollution by organic solvents and their microbial degradation products. In: Angeletti G, Bjorseth A, editors. Analysis of Organic Micropollutants in Water: Proceedings of the 3rd European Symposium, September 1983, Oslo, Norway. Boston, MA: D. Reidel Publishing Co. p. 261–275. 10.1007/978-94-009-6345-0_30
Bouscaren R, Frank R, Veldt C. 1986. Hydrocarbons: Identification of air quality problems in member states of the European communities. Commission of the European Communities. Contract No. 84-B-6642-11-015-11-N, EUR 10646 EN.
Brown DW, Friedman AJ, Burrows DG, Snyder GR, Patten BG. 1979. Investigation of petroleum in the marine environs of the Strait of Juan de Fuca and Northern Puget Sound. Washington, DC: U.S. Environmental Protection Agency. EPA 60/7-79-164.
Brown HR, Monticello TM, Maronpot RR, Randall HW, Hotchkiss JR, Morgan KT. 1991. Proliferative and neoplastic lesions in the rodent nasal cavity. Toxicol Pathol. 19(4 Pt 1):358–372. 10.1177/0192623391019004-105 1813982
Brugnone F, Perbellini L, Faccini GB, Pasini F, Maranelli G, Romeo L, Gobbi M, Zedde A. 1989. Breath and blood levels of benzene, toluene, cumene and styrene in non-occupational exposure. Int Arch Occup Environ Health. 61(5):303–311. 10.1007/BF00409385 2707867
Burmaster DE. 1982. The new pollution: Groundwater contamination. Environment. 24(2):7–36. 10.1080/00139157.1982.9932469
Burnham AK, Calder GV, Fritz JS, Junk GA, Svec HJ, Willis R. 1972. Identification and estimation of neutral organic contaminants in potable water. Anal Chem. 44(1):139–142. 10.1021/ac60309a005 5006886
BusinessWire. 2011. Cumene demand growth to replicate that of phenol according to Merchant Research and Consulting Ltd. London, UK: BusinessWire. https://www.businesswire.com/news/home/20110613005889/en. [Accessed: March 1, 2012].
Chameides B. 2012. The chemical marketplace: Coming clean on alkylphenols. Durham, NC: Duke University. https://www.nicholas.duke.edu/thegreengrok/alkylphenols. [Accessed: March 12, 2012].
Chemical Manufacturers Association (CMA). 1985. Cumene program panel: Industrial hygiene survey. Chemical Manufacturers Association.
ChemIDplus. 2012. ChemIDplus Advanced. National Library of Medicine. http://chem.sis.nlm.nih.gov/chemidplus/chemidheavy.jsp and select Registry Number and search on CAS number. [Accessed: March 9, 2012].
Chen LJ, Wegerski CJ, Kramer DJ, Thomas LA, McDonald JD, Dix KJ, Sanders JM. 2011. Disposition and metabolism of cumene in F344 rats and B6C3F1 mice. Drug Metab Dispos. 39(3):498–509. 10.1124/dmd.110.034769 21098646
Cocheo V, Bellomo ML, Bombi GG. 1983. Rubber manufacture: Sampling and identification of volatile pollutants. Am Ind Hyg Assoc J. 44(7):521–527. 10.1080/15298668391405247 6613855
Coleman WE, Munch JW, Striecher RP, Kopfler FC. 1984. The identification and measurement of components in gasoline, kerosene, and No. 2 fuel oil that partition into the aqueous phase after mixing. Arch Environ Contam Toxicol. 13:171–178. 10.1007/BF01055874
Conkle JP, Camp BJ, Welch BE. 1975. Trace composition of human respiratory gas. Arch Environ Health. 30(6):290–295. 10.1080/00039896.1975.10666702 1137435
Cruzan G, Bus J, Banton M, Gingell R, Carlson G. 2009. Mouse specific lung tumors from CYP2F2-mediated cytotoxic metabolism: An endpoint/toxic response where data from multiple chemicals converge to support a mode of action. Regul Toxicol Pharmacol. 55(2):205–218. 10.1016/j.yrtph.2009.07.002 19589367
Cruzan G, Bus J, Hotchkiss J, Harkema J, Banton M, Sarang S. 2012. CYP2F2-generated metabolites, not styrene oxide, are a key event mediating the mode of action of styrene-induced mouse lung tumors. Regul Toxicol Pharmacol. 62(1):214–220. 10.1016/j.yrtph.2011.10.007 22041433
Cruzan G, Cushman JR, Andrews LS, Granville GC, Johnson KA, Bevan C, Hardy CJ, Coombs DW, Mullins PA, Brown WR. 2001. Chronic toxicity/oncogenicity study of styrene in CD-1 mice by inhalation exposure for 104 weeks. J Appl Toxicol. 21(3):185–198. 10.1002/jat.737 11404830
Curren RD. 1987. Unscheduled DNA analysis in rat primary hepatocytes. Bethesda, MD: Microbiological Associates, Inc. Laboratory Study No. T4786.380005, EPA OTS Fiche No. 0522853.
Cushman JR, Norris JC, Dodd DE, Darmer KI, Morris CR. 1995. Subchronic inhalation toxicity and neurotoxicity assessment of cumene in Fischer 344 rats. J Am Coll Toxicol. 14(2):129–147. 10.3109/10915819509008687
Dannecker W, Schröder B, Stechmann H. 1990. Organic and inorganic substances in highway tunnel exhaust air. Sci Total Environ. 93:293–300. 10.1016/0048-9697(90)90119-F
De Fré R, Bruynseraede P, Kretzschmar JG. 1994. Air pollution measurements in traffic tunnels. Environ Health Perspect. 102 Suppl 4:31–37. 7529706
Desideri PG, Lepri L, Checchini L, Santianni D. 1994. Organic compounds in surface and deep antarctic snow. Int J Environ Anal Chem. 55(1-4):33–46. 10.1080/03067319408026207
Devereux TR, Holliday W, Anna C, Ress N, Roycroft J, Sills RC. 2002. Map kinase activation correlates with K-ras mutation and loss of heterozygosity on chromosome 6 in alveolar bronchiolar carcinomas from B6C3F1 mice exposed to vanadium pentoxide for 2 years. Carcinogenesis. 23(10):1737–1743. 10.1093/carcin/23.10.1737 12376484
Dietrich DR, Swenberg JA. 1991 b. The presence of α_2u_-globulin is necessary for d-limonene promotion of male rat kidney tumors. Cancer Res. 51(13):3512–3521. 1711412
Eastmond DA. 2012. Factors influencing mutagenic mode of action determinations of regulatory and advisory agencies. Mutat Res. 751(1):49–63. 10.1016/j.mrrev.2012.04.001 22480449
European Commission (EC). 2001. European Union risk assessment report: Cumene. Luxembourg: European Commission. EUR 19726 EN.
Fabre R, Truhaut R, Bernuchon J, Loisillier F. 1955 a. [Recherches toxicologiques sur les solvants de remplacement du benzène. III. Étude de l'isopropylbenzene ou cumène]. Arch Mal Prof. 16(4):285–299. 14388886
Federal Interagency Solutions Group (FISG). 2010. Oil budget calculator. Deepwater Horizon technical documentation. Federal Interagency Solutions Group, Oil Budget Calculator Science and Engineering Team.
Florin I, Rutberg L, Curvall M, Enzell CR. 1980. Screening of tobacco smoke constituents for mutagenicity using the Ames’ test. Toxicology. 15(3):219–232. 10.1016/0300-483X(80)90055-4 7008261
Food and Drug Administration (FDA). 2012. International Conference on Harmonisation; final recommendation for the revision of the permitted daily exposure for the solvent cumene according to the maintenance procedures for the guidance q3c impurities: Residual solvents; availability. Fed Regist. 77(36):10754–10755. 22379689
Foster P, Laffond M, Baussand P, Jacob V, Denis I. 1991. VOC measurements in the Grenoble area and study of the benzaldehyde behavior in a simulation chamber. Poll Atmos. 175–191.
Gallego E, Roca FJ, Perales JF, Guardino X, Berenguer MJ. 2008. VOCs and PAHs emissions from creosote-treated wood in a field storage area. Sci Total Environ. 402(1):130–138. 10.1016/j.scitotenv.2008.04.008 18501954
Grosjean D, Fung K. 1984. Hydrocarbons and carbonyls in Los Angeles air. J Air Pollut Control Assoc. 34:537–543. 10.1080/00022470.1984.10465772
Grosjean E, Grosjean D, Rasmussen RA. 1998. Ambient concentrations, sources, emission rates, and photochemical reactivity of C2−C10 hydrocarbons in Porto Alegre, Brazil. Environ Sci Technol. 32(14):2061–2069. 10.1021/es980106i
Guicherit R, Schulting FL. 1985. The occurence of organic chemicals in the atmosphere of The Netherlands. Sci Total Environ. 43:193–219. 10.1016/0048-9697(85)90129-9 4012295
Gulf Life Sciences Center (GLSC). 1984a. Cell transformation test of cumene. Pittsburgh, PA: Gulf Life Sciences Center. Project No. 84-2131, EPA OTS Fiche No. 0509712.
Gulf Life Sciences Center (GLSC). 1984b. Hepacyte primary culture/DNA repair test of cumene. Pittsburgh, PA: Gulf Life Sciences Center. Project No. 84-2130, EPA OTS Fiche No. 0509712.
Gulf Life Sciences Center (GLSC). 1985a. CHO/HGPRT test of cumene. Pittsburgh, PA: Gulf Life Science Center. Project No. 84-2128, EPA OTS Fiche No. 0206775.
Gulf Life Sciences Center (GLSC). 1985b. Micronucleus test of cumene. Pittsburgh, PA: Gulf Life Science Center. Project No. 84-2129, EPA OTS Fiche No. 0522838.
Hard GC. 2008. Some aids to histological recognition of hyaline droplet nephropathy in ninety-day toxicity studies. Toxicol Pathol. 36(7):1014–1017. 10.1177/0192623308327413 19126795
Harley RA, Cass GR. 1994. Modeling the concentrations of gas-phase toxic organic air pollutants: Direct emissions and atmospheric formation. Environ Sci Technol. 28(1):88–98. 10.1021/es00050a013 22175837
Harrison W. 1975. Environmental analysis for Bahamas supertanker port. In: Proceedings of the 14th International Conference on Coastal Engineering, Copenhagen, June 24-28, 1974. p. 2551–2567.
Haseman JK. 1984. Statistical issues in the design, analysis and interpretation of animal carcinogenicity studies. Environ Health Perspect. 58:385–392. 10.1289/ehp.8458385 6525993
Haseman JK, Hailey JR, Morris RW. 1998. Spontaneous neoplasm incidences in Fischer 344 rats and B6C3F1 mice in two-year carcinogenicity studies: A National Toxicology Program update. Toxicol Pathol. 26(3):428–441. 10.1177/019262339802600318 9608650
Henne KR, Fisher MB, Iyer KR, Lang DH, Trager WF, Rettie AE. 2001. Active site characteristics of CYP4B1 probed with aromatic ligands. Biochemistry. 40(29):8597–8605. 10.1021/bi010395e 11456500
Héroux MÈ, Gauvin D, Gilbert NL, Guay M, Dupuis G, Legris M, Lévesque B. 2008. Housing characteristics and indoor concentrations of selected volatile organic compounds (VOCs) in Quebec City, Canada. Indoor Built Environ. 17(2):128–137. 10.1177/1420326X07089005
Hoenerhoff MJ, Hong HH, Ton TV, Lahousse SA, Sills RC. 2009. A review of the molecular mechanisms of chemically induced neoplasia in rat and mouse models in national toxicology program bioassays and their relevance to human cancer. Toxicol Pathol. 37(7):835–848. 10.1177/0192623309351726 19846892
Hong HH, Ton TV, Kim Y, Wakamatsu N, Clayton NP, Chan PC, Sills RC, Lahousse SA. 2008. Genetic alterations in K-ras and p53 cancer genes in lung neoplasms from B6C3F1 mice exposed to cumene. Toxicol Pathol. 36(5):720–726. 10.1177/0192623308320280 18648094
HPDB. 2012. Household Products Database. Bethesda, MD: National Library of Medicine. http://householdproducts.nlm.nih.gov/advancedsearch.htm and select “Ingredient” and search CAS No. [Accessed: February 18, 2012].
HSDB. 2005. Hazardous Substances Data Bank. Bethesda, MD: National Library of Medicine. http://toxnet.nlm.nih.gov/cgi-bin/sis/htmlgen?HSDB and search on CAS number or compound name. [Accessed: November 28, 2011].
Hung IF, Liao MH. 1991. Aromatic hydrocarbons in indoor air. J Environ Sci Health A. 26(4):487–492.
Hurford N, Law RJ, Fileman TW, Payne AP, Colcomb-Heiliger K. 1990. Concentrations of chemicals in the North Sea due to operational discharges from chemical tankers - Results from the second survey. Oil Chem Pollut. 7(4):251–270. 10.1016/S0269-8579(05)80043-7
Hurford N, Law RJ, Payne AP, Fileman TW. 1989. Concentrations of chemicals in the North Sea arising from discharges from chemical tankers. Oil Chem Pollut. 5(6):391–410. 10.1016/S0269-8579(89)80018-8
Hwang SY, Chen SS. 2010. Cumene. In: Kirk-Othmer Encyclopedia of Chemical Technology. John Wiley and Sons, Inc. p. 10. 10.1002/0471238961.0321130519030821.a01.pub3
Independent Commodity Intelligence Services (ICIS). 1999a. Cumene production via zeolites gaining. https://www.icis.com/Articles/1999/09/13/94700/cumene-production-via-zeolites-gaining.html. [Accessed: March 22, 2012].
Independent Commodity Intelligence Services (ICIS). 1999b. New zeolite catalyst technology has ensured that global cumene supply meets increased demand for phenol. https://www.icis.com/Articles/1999/11/29/100160/Cumene.html. [Accessed: February 23, 2012].
Independent Commodity Intelligence Services (ICIS). 2005. Chemical profile: Cumene. https://www.icis.com/Articles/2005/09/05/2009822/chemical-profile-cumene.html. [Accessed: February 23, 2012].
Independent Commodity Intelligence Services (ICIS). 2012. What are petrochemicals? Reed Business Information, Ltd. http://www.icistrainingsite.com/p/what-are-petrochemicals. [Accessed: May 16, 2012].
Independent Commodity Intelligence Services (ICIS). 2012c. U.S. April cumene prices assessed at rollover on feedstocks. https://www.icis.com/Articles/2012/04/06/9548399/us-april-cumene-prices-assessed-at-rollover-on-feedstocks.html. [Accessed: May 24, 2012].
International Agency for Research on Cancer (IARC). 1999. Species differences in thyroid, kidney and urinary bladder carcinogenesis. IARC Scientific Publications No. 147. Lyon, France: International Agency for Research on Cancer.
International Agency for Research on Cancer (IARC). 2012. Cumene. In: Some Chemicals Present in Industrial and Consumer Products, Food and Drinking-Water. IARC Monographs on the Evaluation of Carcinogenic Risks to Humans, vol. 101. Lyon, France: International Agency for Research on Cancer. p. 325–348.
Ishida T, Matsumoto T. 1992. Enantioselective metabolism of cumene. Xenobiotica. 22(11):1291–1298. 10.3109/00498259209053157 1492421
Isidorov VA, Zenkevich IG, Ioffe BV. 1983. Methods and results of gas chromatographic-mass spectrometric determination of volatile organic substances in an urban atmosphere. Atmos Environ. 17(7):1347–1353. 10.1016/0004-6981(83)90409-2
Jackson MA, Lea I, Rashid A, Peddada SD, Dunnick JK. 2006. Genetic alterations in cancer knowledge system: Analysis of gene mutations in mouse and human liver and lung tumors. Toxicol Sci. 90(2):400–418. 10.1093/toxsci/kfj101 16410370
Japan Environment Agency (JEA). 1987. Chemicals in the environment: A report of 1987 survey. Tokyo, Japan: Japan Environment Agency, Environmental Health Department, Office of Health Studies.
Jenkins LJ Jr, Jones RA, Siegel J. 1970. Long-term inhalation screening studies of benzene, toluene, o-xylene, and cumene on experimental animals. Toxicol Appl Pharmacol. 16(3):818–823. 10.1016/0041-008X(70)90088-8 4987190
Jensen TE, Young W, Ball JC, Freeman LE. 1988. Direct-acting mutagenicity of diesel particulate extract is unchanged by addition of neat aromatic compounds to diesel fuel. JAPCA. 38(1):56–58. 10.1080/08940630.1988.10466354 3356998
Johansen SS, Hansen AB, Mosboek H, Arvin E. 1997. Identification of heteroaromatic and other organic compounds in ground water at creosote-contaminated sites in Denmark. Groundwater Monit Rem. 17(2):106–115. 10.1111/j.1745-6592.1997.tb01283.x
Jüttner F. 1988. Motor-boat derived volatile organic compounds (VOC) in lakewater. Z Wasser Abwasser Forsch. 21(2):36–39.
Keith LH, Garrison AW, Allen FR, Carter MH, Floyd TL, Pope JD, Thruston AD. 1976. Identification of organic compounds in drinking water from thirteen U.S. cities. In: Keith LH, editor. Identification and Analysis of Organic Pollutants in Water. Ann Arbor, MI: Ann Arbor Science. p. 329–373.
Kim SJ, Rim KT, Lee SB, Kim HY. 2008. Measurement of DNA damage with Fpg/Endo III FLARE assay and real time RT-PCR in SD rats exposed to cumene. Mol Cell Toxicol. 4(3):211–217.10.1007/s13273-020-00076-8
Kino K, Sugiyama H. 2005. UVR-induced G-C to C-G transversions from oxidative DNA damage. Mutat Res. 571(1-2):33–42. 10.1016/j.mrfmmm.2004.10.010 15748636
Kirkland D, Speit G. 2008. Evaluation of the ability of a battery of three in vitro genotoxicity tests to discriminate rodent carcinogens and non-carcinogens III. Appropriate follow-up testing in vivo. Mutat Res. 654(2):114–132. 10.1016/j.mrgentox.2008.05.002 18585956
Kliest J, Fast T, Boley JSM, Van de Wiel HJ, Bloemen H. 1989. The relationship between soil contaminated with volatile organic compounds and indoor air pollution. Environ Int. 15:419–425. 10.1016/0160-4120(89)90057-3
Krotoszynski B, Gabriel G, O’Neil H. 1977. Characterization of human expired air: A promising investigative and diagnostic technique. J Chromatogr Sci. 15(7):239–244. 10.1093/chromsci/15.7.239 893644
Lawlor T, Wagner VO. 1987. Salmonella/Mammalian-microsome preincubation mutagenicity assay (Ames Test). Microbiological Associates, Inc. NTIS/OTS 0522851.
Lebret E, Van de Wiel HJ, Bos HP, Noij D, Boleij JSM. 1986. Volatile organic compounds in Dutch homes. Environ Int. 12:323–332. 10.1016/0160-4120(86)90046-2
Lonneman WA, Bellar TA, Altshuller AP. 1968. Aromatic hydrocarbons in the atmosphere of the Los Angeles basin. Environ Sci Technol. 2(11):1017–1020. 10.1021/es60022a002
Lonneman WA, Seila RL, Bufalini JJ. 1978. Ambient air hydrocarbon concentrations in Florida. Environ Sci Technol. 12(4):459–463. 10.1021/es60140a010
Malins DC, McCain BB, Brown DW, Chan SL, Myers MS, Landahl JT, Prohaska PG, Friedman AJ, Rhodes LD, Burrows DG, et al. 1984. Chemical pollutants in sediments and diseases of bottom-dwelling fish in Puget Sound, Washington. Environ Sci Technol. 18(9):705–713. 10.1021/es00127a013
Malkinson AM. 1989. The genetic basis of susceptibility to lung tumors in mice. Toxicology. 54(3):241–271. 10.1016/0300-483X(89)90062-0 2650016
Malviya VU. 2006. A brief study of phenolic disc brake caliper pistons. Huddersfield, UK: University of Huddersfield.
McDonald TJ, Kennicut II MC, Brooks JM. 1988. Volatile organic compounds at a coastal Gulf of Mexico site. Chemosphere. 17(1):123–136. 10.1016/0045-6535(88)90050-1
Miller DF, Alkezweeny AJ. 1980. Aerosol formation in urban plumes over Lake Michigan. Ann N Y Acad Sci. 338:219–232. 10.1111/j.1749-6632.1980.tb17123.x
Montz WE Jr, Puyear RL, Brammer JD. 1982. Identification and quantification of water-soluble hydrocarbons generated by two-cycle outboard motors. Arch Environ Contam Toxicol. 11(5):561–565. 10.1007/BF01056363 7149772
NAC-AEGL. 2007. Acute Exposure Guideline Levels (AEGLs) for cumene (CAS Reg. No. 98-82-8). Washington, DC: U.S. Environmental Protection Agency. Interim 1: 8/2007. https://web.archive.org/web/20090710133710/http://www.epa.gov/oppt/aegl/index.htm.
National Institute for Occupational Safety and Health (NIOSH). 1990. National Occupational Exposure Survey (1981-1983). Washington, DC: National Institute for Occupational Safety and Health. https://www.cdc.gov/noes/noes4/20850sco.html.
National Institute for Occupational Safety and Health (NIOSH). 2003. Hydrocarbons, aromatic. Method 1501. In: NIOSH Manual of Analytical Methods. 4th ed. Washington, DC: National Institute for Occupational Safety and Health. p. 1–7.
National Institute for Occupational Safety and Health (NIOSH). 2011. HHE search results: Cumene. Atlanta, GA: Centers for Disease Control and Prevention. https://www2a.cdc.gov/hhe/search.asp and search on cumene. [Accessed: September 12, 2012].
National Research Council (NRC). 1981. The alkyl benzenes. Washington, DC: National Academy Press.
National Response Center. 2012. National Response Center Database. Washington, DC: United States Coast Guard. http://www.nrc.uscg.mil/foia.html. [Accessed: March 15, 2012].
National Toxicology Program (NTP). 1979. Bioassay of styrene for possible carcinogenicity (CAS No. 100-42-5). Bethesda, MD: National Cancer Institute. Technical Report Series No. 185, NIH Publication No. 79-1741.
National Toxicology Program (NTP). 1990. Toxicology and carcinogenesis studies of toluene (CAS No. 108-88-3) in F344/N rats and B6C3F_1_ mice (inhalation studies). Research Triangle Park, NC: National Toxicology Program. NTP TR 371, NIH Publication No. 90-2826.
National Toxicology Program (NTP). 1996. NTP nomination history and review: Cumene. Research Triangle Park, NC: National Toxicology Program.
National Toxicology Program (NTP). 1999. Toxicology and carcinogenesis studies of ethylbenzene (CAS. No. 100-41-4) in F344/N rats and B6C3F_1_ mice (inhalation studies). Research Triangle Park, NC: National Toxicology Program. NTP TR 466, NIH Publications No. 99-3956.
National Toxicology Program (NTP). 2007. Toxicology and carcinogenesis studies of α-methylstyrene (CAS No. 98-83-9) in F344/N rats and B6C3F_1_ mice (inhalation studies). Research Triangle Park, NC: National Toxicology Program. NTP TR 543, NIH Publication No. 08-4474.
National Toxicology Program (NTP). 2009. Toxicology and carcinogenesis studies of cumene (CAS No. 98-82-8) in F344/N rats and B6C3F_1_ mice (inhalation studies). Research Triangle Park, NC: National Toxicology Program. NTP TR 542, NIH Publication No. 09-5885.
National Toxicology Program (NTP). 2011. Styrene. In: Report on Carcinogens. 12th ed. Research Triangle Park, NC: National Toxicology Program. p. 383–391.
National Toxicology Program (NTP). 2012. Final report on the cumene (CASRN 98-82-8) genotoxicity studies. Research Triangle Park, NC: National Toxicology Program.
Norppa H, Vainio H. 1983. Induction of sister-chromatid exchanges by styrene analogues in cultured human lymphocytes. Mutat Res. 116(3-4):379–387. 10.1016/0165-1218(83)90076-9 6835253
NPG6. 2006a. Carpet fibers. Nylon-6 Promotional Group. http://npg-6.com/internet/en/html/algemeen/applications/carpetfibers.pshe. [Accessed: March 3, 2012].
NPG6. 2006b. Industrial fiber. Nylon-6 Promotional Group. http://npg-6.com/internet/en/html/algemeen/applications/tirecord.pshe. [Accessed: March 12, 2012].
NPG6. 2006c. Textile fibers. Nylon-6 Promotional Group. http://npg-6.com/internet/en/html/algemeen/applications/textilefibers.pshe. [Accessed: March 12, 2012].
Occupational Safety and Health Administration (OSHA). 2004. Analytical methods: Cumene. Washington, DC: United States Department of Labor. https://www.osha.gov/dts/sltc/methods/partial/pv2137/pv2137.html. [Accessed: April 9, 2013].
Occupational Safety and Health Administration (OSHA). 2011. Chemical exposure health data. Washington, DC: Occupational Safety and Health Administration. https://www.osha.gov/opengov/healthsamples.html. [Accessed: April 10, 2013].
Ogata M, Fujisawa K, Ogino Y, Mano E. 1984. Partition coefficients as a measure of bioconcentration potential of crude oil compounds in fish and shellfish. Bull Environ Contam Toxicol. 33(5):561–567. 10.1007/BF01625584 6498361
Oldham RG, et al. 1979. Proc Spec Conf Cont Specific (toxic) Pollut. Pitsburgh, PA: Air Poll Control Assoc.
Operational Science Advisory Team (OSAT). 2011. Summary report for fate and effects of remnant oil remaining in the beach environment. Annex F: Human health considerations. Operational Science Advisory Team. http://www.restorethegulf.gov.
Pellizzari ED, Castilo NP, Willis S, Smith D, Bursey JT. 1979. Identification of organic components in aqueous effluents from energy-related processes. In: Van Hall CE, editor. Measurement of Organic Pollutants in Water and Wastewater: Symposium on Water, June 1978, Denver, CO. Philadelphia, PA: American Society for Testing and Materials, ASTM Committee D19. p. 256–274. 10.1520/STP35020S
Perbellini L, Pasini F, Faccini GB, Danzi B, Gobbi M, Zedde A, Cirillo P, Brugnone F. 1988. [Determination of industrial solvents in blood, alveolar air and urine in a group of blood donors]. Med Lav. 79(6):460–467. 3246970
Peterson CA. 1980. Cumene. In: Organic Chemical Manufacturing. Volume 7: Selected Processes. EPA-450/3-80-028b. Research Triangle Park, NC: U.S. Environmental Protection Agency. p. 3-1 to 3-9, I1-VII-4.
Petersson B, Curvall M, Enzell CR. 1982. Effects of tobacco smoke compounds on the ciliary activity of the embryo chicken trachea in vitro. Toxicology. 23(1):41–55. 10.1016/0300-483X(82)90040-3 7089984
Pfuhler S, Albertini S, Fautz R, Herbold B, Madle S, Utesch D, Poth A. 2007. Genetic toxicity assessment: Employing the best science for human safety evaluation part IV: Recommendation of a working group of the Gesellschaft fuer Umwelt-Mutationsforschung (GUM) for a simple and straightforward approach to genotoxicity testing. Toxicol Sci. 97(2):237–240. 10.1093/toxsci/kfm019 17303579
Platts. 2007. Efforts continue to clean up Ohio River cumene barge spill. Platts, McGraw-Hill Companies, Inc. http://www.arizonaenergy.org/News_07/News_Mar07/Efforts%20continue%20to%20clean%20up%20Ohio%20River%20cumene%20barge%20spill.htm. [Accessed: January 1, 2012].
PRWeb. 2011. Cumene industry reached healthy growth rates compatible to phenol according to Merchant Research & Consulting Ltd. Vocus PRW Holdings, LLC. http://www.prweb.com/releases/2011/11/prweb8977757.htm. [Accessed: February 23, 2012].
Putman DL. 1987a. Chromosome aberrations in Chinese hamster ovary (CHO) cells. Microbiological Associates, Inc. NTIS/OTS 0522852.
Putman DL. 1987b. Morphological transformation of BALB/3T3 mouse embryo cells in the absence of exogenic metabolic activation. Microbiological Associates, Inc. NTIS/OTS 0206782.
Rauschenbach MO, Zharova EI, Sergeeva TI, Ivanova VD, Probatova NA. 1975. Blastomogenic activity of p-hydroxyphenyllactic acid in mice. Cancer Res. 35(3):577–585. 163684
Rebling. 2012. Thermostats - Phenolic. Warrington, PA: Rebling Plastics. https://www.reblingplastics.com/phenolic.htm. [Accessed: May 22, 2012].
Robinson D, Smith JN, Williams RT. 1955. Studies in detoxication. 60. The metabolism of alkylbenzenes: Isopropylbenzene (cumene) and derivatives of hydratropic acid. Biochem J. 59(1):153–159. 10.1042/bj0590153 14351158
Rosman LB, Beylin VG, Gaddamidi V, Hooberman BH, Sinsheimer JE. 1986. Mutagenicity of para-substituted α-methylstyrene oxide derivatives with Salmonella. Mutat Res. 171(2-3):63–70. 10.1016/0165-1218(86)90036-4 3528837
Sauer TC. 1981. Volatile liquid hydrocarbon characterization of underwater hydrocarbon vents and formation waters from offshore production operations. Environ Sci Technol. 15(8):917–923. 10.1021/es00090a005 22284001
Scheffers TML. 1985. Development of effect-specific limit values (ESLVs) for solvent mixtures in painting. Ann Occup Hyg. 29(2):191–199.
Seila RL. 1979. Nonurban hydrocarbon concentrations in ambient air north of Houston, TX. Research Triangle Park, NC: U.S. Environmental Protection Agency, Office of Research and Development. EPA 600/3-79-101, NTIS PB 298-227.
Seńczuk W, Litewka B. 1976. Absorption of cumene through the respiratory tract and excretion of dimethylphenylcarbinol in urine. Br J Ind Med. 33(2):100–105. 10.1136/oem.33.2.100 1276088
Shiraishi H, Pilkington NH, Otsuki A, Fuwa K. 1985. Occurrence of chlorinated polynuclear aromatic hydrocarbons in tap water. Environ Sci Technol. 19(7):585–590. 10.1021/es00137a001 22148299
Sills RC, Boorman GA, Neal JE, Hong HL, Devereux TR. 1999 a. Mutations in ras genes in experimental tumours of rodents. IARC Sci Publ. (146):55–86. 10353384
Sills RC, Hong HL, Melnick RL, Boorman GA, Devereux TR. 1999 b. High frequency of codon 61 K-ras A—>T transversions in lung and Harderian gland neoplasms of B6C3F1 mice exposed to chloroprene (2-chloro-1,3-butadiene) for 2 years, and comparisons with the structurally related chemicals isoprene and 1,3-butadiene. Carcinogenesis. 20(4):657–662. 10.1093/carcin/20.4.657 10223196
Simmon VF, Kauhanen K, Tardiff RG. 1977. Mutagenic activity of chemicals identified in drinking water. In: Scott D, Bridges BA, Sobels FH, editors. Progress in Genetic Toxicology. Amsterdam, Netherlands: Elsevier/North Holland Biomedical Press. p. 249–258.
SMARTe.org. 2012. Understanding units of measurement. Sustainable Management Approaches and Revitalization Tools - electronic. http://www.smarte.org/smarte/resource/sn-units-of-measure.xml?mode=search.
Snider EH, Manning FS. 1982. A survey of pollutant emission levels in waste waters and residuals from the petroleum refining industry. Environ Int. 7(4):237–258. 10.1016/0160-4120(82)90114-3
Soussi T. 2012. p53 mutations in lung cancer. The TP53 Website. http://p53.free.fr/Database/p53_cancer/p53_Lung.html. [Accessed: April 17, 2013].
SRI. 2011. Directory of chemical producers. Menlo Park, CA: SRI Consulting. Database edition. [Accessed: September 26, 2011].
Stanley LA. 1995. Molecular aspects of chemical carcinogenesis: The roles of oncogenes and tumour suppressor genes. Toxicology. 96(3):173–194. 10.1016/0300-483X(94)02991-3 7900159
Stepan S, et al. 1981. Australian Water Resources Council Conference Series 1. p. 415-424.
Stuermer DH, Ng DJ, Morris CJ. 1982. Organic contaminants in groundwater near an underground coal gasification site in Northern Wyoming. Environ Sci Technol. 16(9):582–587. 10.1021/es00103a009 22284199
Swenberg JA, Lehman-McKeeman LD. 1999. α_2_-Urinary globulin-associated nephropathy as a mechanism of renal tubule cell carcinogenesis in male rats. IARC Sci Publ. (147):95–118. 10457913
Tardiff RG, Carlson GP, Simmon VF. 1976. Halogenated organics in tap water: A toxicological evaluation. In: Jolley RL, editor. Water Chlorination: Environmental Impact and Health Effects, vol. 1. Ann Arbor, MI: Ann Arbor Science Publishers, Inc. p. 195–209.
Teplý J, Dressler M. 1980. Direct determination of organic compounds in water using steam-solid chromatography. J Chromatogr. 191:221–229. 10.1016/S0021-9673(00)86382-7
Tester DJ, Harker RJ. 1981. Groundwater pollution investigations in the Great Ouse basin. Water Pollut Control. 80(5):614–631.
Thompson DC, Perera K, London R. 1995. Quinone methide formation from para isomers of methylphenol (cresol), ethylphenol, and isopropylphenol: Relationship to toxicity. Chem Res Toxicol. 8(1):55–60. 10.1021/tx00043a007 7703367
Toxics Release Inventory (TRI). 2012. TRI Explorer chemical report. U.S. Environmental Protection Agency. https://www.epa.gov/triexplorer and select Cumene. [Accessed: March 7, 2012].
TOXMAP. 2012. TOXMAP®: Environmental health e-maps. Bethesda, MD: National Library of Medicine. http://toxmap.nlm.nih.gov/toxmap/home/welcome.do and search on cumene. [Accessed: May 9, 2012].
Tsani-Bazaca E, McIntyre A, Lester J, Perry R. 1982. Ambient concentrations and correlations of hydrocarbons and halocarbons in the vicinity of an airport. Chemosphere. 11(1):11–23. 10.1016/0045-6535(82)90084-4
United States International Trade Commission (USITC). 2013. USITC interactive tariff and trade dataweb. United States International Trade Commission. https://dataweb.usitc.gov/scripts/user_set.asp and search on HTS no. 2902700000. [Accessed: January 10, 2013].
U.S. Department of Agriculture (USDA). 2007. Tobacco outlook. Washington, DC: United States Department of Agriculture, Economic Research Service. https://www.ers.usda.gov/publications/tbs-tobacco-outlook.aspx#.UjeO37y25i4.
U.S. Environmental Protection Agency (US EPA). 1979. Hydrocarbons in Houston air. Research Triangle Park, NC: U.S. Environmental Protection Agency. EPA-600/3-79-018.
U.S. Environmental Protection Agency (US EPA). 1986. Report on the interim database for state and local air toxic volatile organic chemical measurements. Research Triangle Park, NC: U.S. Environmental Protection Agency. EPA 450/4-86-012.
U.S. Environmental Protection Agency (US EPA). 1987. Health and environmental effects document for cumene. Cincinnati, OH: U.S. Environmental Protection Agency.
U.S. Environmental Protection Agency (US EPA). 1988. Cumene; final test rule. Fed Regist. 53(44):28195–28206.
U.S. Environmental Protection Agency (US EPA). 1991a. Technical guidance - Stage II vapor recovery systems for control of vehicle refueling emissions at gasoline dispensing facilities. Research Triangle Park, NC: U.S. Environmental Protection Agency. EPA-450/3-91-022a.
U.S. Environmental Protection Agency (US EPA). 1991b. Alpha_2u_-globulin-associated renal nephropathy with chemically induced renal toxicity and neoplasia in the male rat. Washington, DC: U.S. Environmental Protection Agency. EPA/625/3-91/019F.
U.S. Environmental Protection Agency (US EPA). 1997. Toxicological review of cumene (CAS No. 98-82-8) in support of summary information on the Integrated Risk Information System. Washington, DC: U.S. Environmental Protection Agency.
U.S. Environmental Protection Agency (US EPA). 2010. Non-confidential 2006 IUR records by chemical, including manufacturing, processing and use information. Washington, DC: U.S. Environmental Protection Agency. https://cfpub.epa.gov/iursearch/index.cfm and search by CAS no.
U.S. Environmental Protection Agency (US EPA). 2012. EJView mapping tool. Washington, DC: U.S. Environmental Protection Agency. http://epamap14.epa.gov/ejmap/entry.html. [Accessed: March 13, 2012].
U.S. Food and Drug Administration (FDA). 2006. US Food and Drug Administration - Total Diet Study market baskets 1991-3 through 2003-4. College Park, MD: U.S. Food and Drug Administration.
Waggot A, et al. 1981. In: Cooper WJ, editor. Chem Water Reuse, vol. 2. Ann Arbor, MI. p. 55–99.
Wakamatsu N, Collins JB, Parker JS, Tessema M, Clayton NP, Ton TV, Hong HH, Belinsky S, Devereux TR, Sills RC, et al. 2008. Gene expression studies demonstrate that the K-ras/Erk MAP kinase signal transduction pathway and other novel pathways contribute to the pathogenesis of cumene-induced lung tumors. Toxicol Pathol. 36(5):743–752. 10.1177/0192623308320801 18648096
Wakeham SG, Goodwin JT, Davis AC. 1983. Distributions and fate of volatile organic-compounds in Narragansett Bay, Rhode Island. Can J Fish Aquat Sci. 40 Suppl 2:s304–s321. 10.1139/f83-336
Ward TJ, Underberg H, Jones DRF, Hamilton J, Adams E. 2009. Indoor/ambient residential air toxics results in rural western Montana. Environ Monit Assess. 153(1-4):119–126. 10.1007/s10661-008-0342-2 18548326
Westrick JJ, Mello JW, Thomas RF. 1984. The groundwater supply survey. J Am Water Works Assoc. 76(5):52–59. 10.1002/j.1551-8833.1984.tb05334.x
Wolf MA, Rowe VK, McCollister DD, Hollingsworth RL, Oyen F. 1956. Toxicological studies of certain alkylated benzenes and benzene; experiments on laboratory animals. AMA Arch Ind Health. 14(4):387–398. 13361560
World Health Organization (WHO). 1999. Concise International Chemical Assessment Document 18: Cumene. Geneva, Switzerland: World Health Organization.
Xie Y, Yang H, Cunanan C, Okamoto K, Shibata D, Pan J, Barnes DE, Lindahl T, McIlhatton M, Fishel R, et al. 2004. Deficiencies in mouse Myh and Ogg1 result in tumor predisposition and G to T mutations in codon 12 of the K-ras oncogene in lung tumors. Cancer Res. 64(9):3096–3102. 10.1158/0008-5472.CAN-03-3834 15126346
Yang LL. 1987. CHO/HGPRT mutation assay. Microbiological Associates, Inc. NTIS/OTS 0522853.
Zeiger E, Anderson B, Haworth S, Lawlor T, Mortelmans K. 1992. Salmonella mutagenicity tests: V. Results from the testing of 311 chemicals. Environ Mol Mutagen. 19 Suppl 21:2–141. 10.1002/em.2850190603 1541260
Zhang Z, Wang Y, Vikis HG, Johnson L, Liu G, Li J, Anderson MW, Sills RC, Hong HL, Devereux TR, et al. 2001. Wildtype Kras2 can inhibit lung carcinogenesis in mice. Nat Genet. 29(1):25–33. 10.1038/ng721 11528387