# Introduction and Methods

Cumene (isopropylbenzene, CASRN 98-82-8) is an alkylated benzene found in fossil fuels, such as blended gasoline and kerosene, and products of incomplete combustion (IARC 2012). It is a high-production-volume chemical in the United States with the majority of its use in the synthesis of acetone and phenol.

Cumene was selected as a candidate substance for the Report on Carcinogens (RoC) based on widespread current U.S. exposure and an adequate database of cancer studies. The National Toxicology Program (NTP) completed a series of cumene inhalation toxicology and carcinogenesis studies (NTP 2009) and disposition and metabolism studies in rats and mice (Chen et al. 2011).

## Monograph Contents

This RoC monograph on cumene reviewed the relevant scientific information, assessed its quality, applied the RoC listing criteria to the scientific information, and recommended an RoC listing status for cumene.

The monograph for cumene provides information on the following topics: human exposure and chemical properties (Section 1), disposition and toxicokinetics (Section 2), cancer in experimental animals (Section 4), and mechanistic data and other related effects (Section 5), including studies of relevant toxicological effects, genetic toxicology, and potential mechanisms of carcinogenicity. When human cancer studies are reviewed, they are discussed in Section 3; however, no cancer studies in humans with exposure specifically to cumene were identified. The information in Section 6 is a synthesis of Sections 2 through 5.

The information reviewed in Sections 2 through 5 (and synthesized in Section 6) came from publicly available, peer-reviewed sources. Information in Section 1, including chemical and physical properties, analytical methods, production, use, and occurrence, came from publicly available, published or unpublished sources.

The cancer hazard evaluation for cumene focuses on the evaluation of the cancer studies in experimental animals and mechanistic data, and also whether there is any evidence that the potential modes of action by which cumene might cause cancer are not relevant to humans.

## Process for Preparation of the Cancer Hazard Evaluation

The process for preparing the monograph included approaches for obtaining public and scientific input and using systematic methods (e.g., standardized methods for identifying the literature (see Appendix A), inclusion/exclusion criteria, extraction of data and evaluation of study quality using specific guidelines, and assessment of the level of evidence for carcinogenicity using established criteria). In addition, the NTP conducted some genotoxicity studies in rodents that were peer reviewed and are publicly available on the NTP website (https://ntp.niehs.nih.gov/go/37895).

The Office of the Report on Carcinogens (ORoC) followed the approaches outlined in the concept document, which discusses the scientific issues and questions relevant to the evaluation of cumene carcinogenicity, the scope and focus of the monograph, and the approaches to obtain scientific and public input to address the key scientific questions and issues, for preparing the cancer hazard evaluation. The ORoC presented the draft concept document on cumene to the NTP Board of Scientific Counselors (BSC) at the June 21–22, 2012 meeting that provided opportunity for written and oral public comments and is available on the RoC website (https://ntp.niehs.nih.gov/go/37895). The draft monograph was peer reviewed in a public forum in March 2013 (see “Peer Review of the Draft RoC Monograph on Cumene” above), revised accordingly, and presented to the BSC at a June 2013 meeting.

### Key Scientific Questions and Issues Relevant for the Cancer Hazard Evaluation

The cancer hazard evaluation focuses on studies of cumene in experimental animals and mechanistic data. It also identifies and discusses studies of structurally related compounds and metabolites to determine whether this information can inform mechanisms of carcinogenicity of cumene.

The key scientific questions identified in the concept, which concern the results in experimental animals and mechanisms of carcinogenicity are:

- What is the level of evidence (sufficient or not sufficient) for the carcinogenicity of cumene from studies in experimental animals? What are the tissue sites?
- What are the potential modes of action by which cumene may cause cancer? Is there evidence that any mechanism is not relevant to humans?
- What is the evidence that the renal tumors observed in male rats are caused by an α_2u_-globulin-associated renal nephropathy mechanism? Are there other potential mechanisms by which cumene could cause renal cancer in male rats?

### Approach for Obtaining Scientific and Public Input

Additional scientific input was obtained for the possible role of α_2u_-globulin as a cause of renal tumors in male rats from NTP scientists with expertise in genetic toxicology, toxicology, and pathology. These scientists were assembled to discuss α_2u_-globulin nephropathy and renal tumors in relation to the guidelines published by IARC (1999) and the sequence of events identified by EPA for this mechanism of renal carcinogenicity and to provide their individual input to the Office of the RoC (ORoC). Their individual comments on the animal cancer data were considered by the ORoC staff in drafting the mechanistic section and the overall synthesis of neoplastic findings in experimental animals. The discussions of the potential mechanisms(s) of actions were reviewed by an external technical advisor, who provided input on the discussions, especially those on the strength of the genotoxicity data for cumene. (Technical advisors are identified on the “CONTRIBUTORS” page.)

Public comments on scientific issues were requested on cumene by Federal Register notices at several times prior to and during the development of the final RoC monograph, including a request for information on the nomination, and for comment on the draft concept document (which outlined the rationale and approach for conducting the scientific review) and comment on the draft RoC monograph. In addition, the NTP posted its preliminary literature search strategy and list of references for public input on the ORoC webpage for cumene (https://ntp.niehs.nih.gov/go/37895) several months prior to the release of the draft monograph. No information or comments on cumene were received from the public as of the date on this document.

### Methods for Writing the Monograph

The procedures by which relevant literature was identified, data were systematically extracted and summarized, and the monograph was written, together with the processes for scientific review, quality assurance, and assessment and synthesis of data, are described below.

The preparation of the RoC monograph on cumene began with development of a literature search strategy to obtain information relevant to the topics listed above for Sections 1 through 5 using search terms developed in collaboration with a reference librarian (see Appendix A for a detailed description of the literature search strategy). The citations (N = 1,450) identified from these searches were uploaded to a web-based systematic review software for evaluation by two separate reviewers using inclusion/exclusion criteria, and 182 references were selected for final inclusion in the monograph using these criteria. Studies identified from the literature searches but excluded from the review include publications on chemicals other than cumene (or relevant structurally related compounds such as cumene metabolites and analogues), and studies involving exposure to cumene that reported results for topics not covered in this monograph (see Monograph Contents).

Information for the exposure, relevant cancer, and mechanistic sections was systematically extracted in tabular format and/or summarized in the text, following specific procedures developed by ORoC, from studies selected for inclusion in the monograph. All sections of the monograph underwent scientific review and quality assurance (QA) (i.e., assuring that all the relevant data and factual information extracted from the publications have been reported accurately) by a separate reviewer. Any discrepancies between the writer and the reviewer were resolved by mutual discussion in reference to the original data source.

Strengths, weaknesses, and data quality of the cancer studies for cumene in experimental animals were assessed based on a series of questions related to characterization of the substance tested, the features of animal husbandry, the design of the study, the methods for clinical observations and necropsy, and the manner in which the data were reported (see Appendix C). Relevant genotoxicity and mechanistic studies were also assessed for their strengths and weaknesses.

Human exposure information was assessed to determine whether the evidence indicates that a significant number of persons residing in the United States are exposed to cumene (see Foreword for information regarding the congressional mandate for the RoC). However, for many substances, this information is not available, and typically, U.S. exposure can be inferred from data on use, production volume, occupational monitoring, environmental (occurrence), estimated daily intake, and biomonitoring. Because cancer has a long latency period, past exposure is also considered in the assessment.

RoC listing criteria (see text box) were applied to the available database of carcinogenicity data to assess the level of evidence (sufficient or not sufficient) for the carcinogenicity of cumene from studies in experimental animals. This initial conclusion does not integrate the experimental animal and mechanism data. The evaluation of the mechanistic data included a complete discussion and assessment of the strength of evidence for potential modes of action of cumene-induced neoplasia, including metabolic activation, cytotoxicity, genetic-related effects, epigenetic effects, and α_2u_-globulin-associated nephropathy. The RoC listing criteria were then applied to the body of knowledge (animal and mechanistic) for cumene to reach a listing recommendation.

RoC Listing Criteria

##### Known to Be Human Carcinogen:

There is sufficient evidence of carcinogenicity from studies in humans*, which indicates a causal relationship between exposure to the agent, substance, or mixture, and human cancer.

##### Reasonably Anticipated to Be Human Carcinogen:

There is limited evidence of carcinogenicity from studies in humans*, which indicates that causal interpretation is credible, but that alternative explanations, such as chance, bias, or confounding factors, could not adequately be excluded, OR

there is sufficient evidence of carcinogenicity from studies in experimental animals, which indicates there is an increased incidence of malignant and/or a combination of malignant and benign tumors (1) in multiple species or at multiple tissue sites, or (2) by multiple routes of exposure, or (3) to an unusual degree with regard to incidence, site, or type of tumor, or age at onset, OR

there is less than sufficient evidence of carcinogenicity in humans or laboratory animals; however, the agent, substance, or mixture belongs to a well-defined, structurally related class of substances whose members are listed in a previous Report on Carcinogens as either known to be a human carcinogen or reasonably anticipated to be a human carcinogen, or there is convincing relevant information that the agent acts through mechanisms indicating it would likely cause cancer in humans.

Conclusions regarding carcinogenicity in humans or experimental animals are based on scientific judgment, with consideration given to all relevant information. Relevant information includes, but is not limited to, dose response, route of exposure, chemical structure, metabolism, pharmacokinetics, sensitive sub-populations, genetic effects, or other data relating to mechanism of action or factors that may be unique to a given substance. For example, there may be substances for which there is evidence of carcinogenicity in laboratory animals, but there are compelling data indicating that the agent acts through mechanisms which do not operate in humans and would therefore not reasonably be anticipated to cause cancer in humans.

*This evidence can include traditional cancer epidemiology studies, data from clinical studies, and/or data derived from the study of tissues or cells from humans exposed to the substance in question that can be useful for evaluating whether a relevant cancer mechanism is operating in people.