# Appendix D Genotoxicity Studies

The nine tables on the following pages contain data discussed in the “Mechanisms and Other Relevant Effects” section (Section 5) for genetic and related effects (Section 5.1) and mechanistic considerations (Section 5.2).

Data are reported for in vitro studies of cumene mutagenicity in bacteria and yeast (Table D-1), in vitro genotoxicity studies of cumene in mammalian cells (Table D-2), in vivo studies of cytogenetic effects of cumene in mammals (Table D-3), K-ras mutations in spontaneous and cumene-induced lung tumors in mice (Table D-4), p53 mutations in spontaneous and cumene-induced lung tumors in mice (Table D-5), in vitro and in vivo genetic toxicology tests results for α-methylstyrene (Table D-6, Table D-7), genes significantly altered in tumors with and without K-ras mutations (Table D-8), K-ras mutation spectra from mouse lung tumors (Table D-9), and primary K-ras mutations in spontaneous and chemically induced mouse lung tumors and DNA adducts.

Table D-1 In Vitro Studies of Cumene Mutagenicity in Bacteria and Yeast

Reference | Strain | Method | LED/HID | | Results | | Cytotoxicity | | Evaluation: Limitations and Conclusions
Reference | Strain | Method | −S9 | +S9 | −S9 | +S9 | −S9 | +S9 | Evaluation: Limitations and Conclusions
Bacteria: Salmonella Typhimurium
Tardiff et al. (1976) | TA100 | Spot test | NR | NT | + | NT | NR | NT | Qualitative assay Incomplete reporting of results and methods^a^ Results reported positive in initial test but negative in subsequent tests by coauthor (see Simmon et al. (1977))
Simmon et al. (1977) | TA98, TA100, TA1535, TA1537, TA1538 | Plate incorporation | NR 5 mg/plate | NR 5 mg/plate | − | − | NR | NR | Incomplete reporting of methods (test doses not specified^b^) and results^a^ Not mutagenic
Simmon et al. (1977) | TA98, TA100, TA1535, TA1537, TA1538 | Plate incorporation/ closed chamber, test chemical in separate dish | NR | NR | − | − | NR | NR | Closed chamber appropriate for volatile chemical but incomplete reporting of methods (test doses not specified) and results^a^ Not mutagenic
Florin et al. (1980) | TA98, TA100, TA1535, TA1537 | Spot test | 3 µmol/ plate | 3 µmol/ plate | − | − | NR | NR | Qualitative assay Not mutagenic
Florin et al. (1980) | TA98, TA100 | Plate incorporation | 3 µmol/ plate | 3 µmol/ plate | − | − | ≥3 µmol/ plate | ≥3 µmol/ plate | Incomplete reporting of methods (only high dose provided) and results^a^ Not mutagenic
Lawlor and Wagner (1987), cited in US EPA (1997), WHO (1999), EC (2001) | TA98, TA100, TA1535, TA1537 | Preincubation | 2,000 µg/ plate | 2,000 µg/ plate | − | − | 2,000 µg/ plate | 2,000 µg/ plate | Limited information on results provided in review papers. Not mutagenic
NTP (2009) | TA 97, TA98, TA100, TA1535 | Preincubation | 166 µg/plate for TA98, TA100 100 µg/plate for TA97, TA 1535 | 333 µg/ plate for TA98, TA100 166 µg/ plate for TA97, TA 1535 | − | − | Toxicity for most strains at highest dose tested | Toxicity for most strains at highest dose tested | S9 from Aroclor 1254-induced rat and hamster liver, 10% and 30%; tested to toxicity (except TA1535, not toxic) Not mutagenic
NTP (2012) | TA98, TA100 | Preincubation protocol modified by using sealed tubes | TA98: 500 µg/plate | TA98: 500 µg/ plate | − | − | TA98: 125 µg/ plate | TA98: 250 µg/ plate | S9 from Aroclor 1254-induced rat liver, 10%; tested to toxicity. Not mutagenic
NTP (2012) | TA98, TA100 | Preincubation protocol modified by using sealed tubes | TA100: 250 µg/plate | TA100: 500 µg/ plate | − | − | TA100: 100 µg/ plate | TA100: 250 µg/ plate | S9 from Aroclor 1254-induced rat liver, 10%; tested to toxicity. Not mutagenic
Bacteria: Escherichia Coli
NTP (2012) | WP2 uvrA (pKM101) | Preincubation protocol modified by using sealed tubes | 250 µg/plate | 500 µg/ plate | − | − | 100 µg/ plate | 500 µg/ plate | S9 from Aroclor 1254-induced rat liver, 10%; tested to toxicity. Not mutagenic
Yeast: Saccharomyces Cerevisiae D3
Simmon et al. (1977) | S. cerevisiae D3 (heterozygous in ade2 of chromosome XV) | Suspension | NR | NR | − | − | NR | NR | Incomplete reporting of methods (test doses not specified) and results^a^ Not mutagenic

LED/HID = lowest effective dose, highest ineffective dose; NR = not reported (although tested); NT = not tested.

^a^ Authors only report conclusion of findings (e.g., positive or negative) and do not provide actual data (e.g., number of revertant colonies).

^b^ Test doses not specified, authors stated “tested up to 5 mg/plate or a dose which gave a toxic response, whichever was lower.

Table D-2 In Vitro Genotoxicity Studies of Cumene in Mammalian Cells

Reference | Effect | Test System | Concentration (LEC or HIC) | Cytotoxicity (% Survival) | Results | | Evaluation: Limitations and Conclusions^a^
Reference | Effect | Test System | Concentration (LEC or HIC) | Cytotoxicity (% Survival) | −S9 | +S9 | Evaluation: Limitations and Conclusions^a^
GLSC (1985a), as described in WHO (1999), NTP (2009) | Point mutation | Chinese hamster ovary (CHO) cells HGPRT locus | NR | Toxic at ≥128 µg/mL (both ±S9) | − | − | Initially called negative, but variable background and colony-forming efficiency warranted retest (see Yang (1987)), which also was negative Limited information on methods and results provided in review papers Negative
Yang (1987), as described in EC (2001)^b^, NTP (2009) | Point mutation | Chinese hamster ovary (CHO) cells HGPRT locus | 225 µg/mL (both ±S9) | Toxic ≥150 µg/mL (−S9); cloning efficiency <10% at dose ≥150 µg/mL (−S9) | − | − | Cloning efficiencies for ≥150 µg/mL not valid for evaluation; retest of Gulf Life Sciences Center (1985a) study Limited information on methods and results provided in review papers Negative
Putman (1987a), as described in EC (2001)^b^ | Chromosomal aberrations | CHO cells | 200 µg/mL (−S9) 225 µg/mL (+S9) | Toxic at 200 µg/mL (−S9) 225 µg/mL (+S9) | − | I | Although +S9 treatment with 156 µg/mL showed statistically significant increase in chromosomal aberrations compared with vehicle control, results were within historical control range and were considered negative by authors Limited information on methods and results provided in review papers. Inconclusive
GLSC (1984a), as described in US EPA (1997) | Cell transformation | BALB/3T3 mouse embryo cells | 60 µg/mL | | + | NT | Limited information on methods and results provided in review paper Initially reported positive but retested, see Putman (1987b) Results equivocal because not reproducible
Putman (1987b), as described in US EPA (1997), WHO (1999), EC (2001) | Cell transformation | BALB/3T3 mouse embryo cells | 500 µg/mL | Toxic at ≥250 µg/mL | − | NT | HID with acceptable toxicity was 200 µg/mL Retest of Gulf Life Sciences Center (1984a) Limited information provided in review papers Negative
GLSC (1984b), as described in US EPA (1997), WHO (1999) | Unscheduled DNA synthesis | F344 rat primary hepatocytes | 16 µg/mL | Toxic at ≥128 µg/mL | + | NA | Limited information on methods and results provided in review papers. Initially reported positive at 16 and 32 µg/mL, but inconsistent response in replicates and high background warranted retesting (see Curren (1987)) Results equivocal because not reproducible
Curren (1987), as described in US EPA (1997), WHO (1999), EC (2001), NTP (2009) | Unscheduled DNA synthesis | F344 rat primary hepatocytes | 24 µg/mL | Toxic at ≥24 µg/mL | − | NA | Limited information on results and methods provided in review papers Retest of Gulf Life Sciences Center (1984b) study Negative

LEC/HIC = lowest effective concentration/highest ineffective concentration tested, I = inconclusive, NA = not applicable, NT = not tested.

^a^ Evaluations of studies presented in this table are limited by the information provided in the cited review papers.

^b^ Based on discrepancies or omission in the peer-reviewed report, data was checked in primary (unpublished) report.

Table D-3 In Vivo Studies of Cytogenetic Effects of Cumene in Mammals

Reference | Endpoint | Species/Sex/# | Exposure | Results (Mean ± S.E.) | | | | | Evaluation: Limitations and Conclusions
GLSC (1985b), as described in US EPA (1997), WHO (1999), EC (2001), NTP (2009) | Micronucleus formation bone marrow polychromatic erythrocytes^a^ | Crl:CDR-1 (ICR) BR Swiss mice male and female, 10/sex/group | Gavage 250, 500, 1,000 mg/kg bw Exposure 2 days Sacrificed on d3 and d4 | Negative for all treatment doses | | | | | Limited information of methods and results provided in review papers. No significant change in PCE:NCE. Negative
NTP (2009) | Micronucleus formation peripheral blood erythrocytes | B6C3F_1_ mice male and female, 9-10/sex/group | Inhalation, two trials Trial 1: 62.5 to 1,000 ppm Trial 2: 62.5 to 500 ppm Exposure for three months | Dose (ppm) | MN-NCEs/1,000 NCEs | | | | Negative: No increase in MN frequency at all treatment doses in both sexes. No dose-related change in % PCE, an indicator of bone marrow toxicity, was seen.
NTP (2009) | Micronucleus formation peripheral blood erythrocytes | B6C3F_1_ mice male and female, 9-10/sex/group | Inhalation, two trials Trial 1: 62.5 to 1,000 ppm Trial 2: 62.5 to 500 ppm Exposure for three months | Male | | | | | Negative: No increase in MN frequency at all treatment doses in both sexes. No dose-related change in % PCE, an indicator of bone marrow toxicity, was seen.
NTP (2009) | Micronucleus formation peripheral blood erythrocytes | B6C3F_1_ mice male and female, 9-10/sex/group | Inhalation, two trials Trial 1: 62.5 to 1,000 ppm Trial 2: 62.5 to 500 ppm Exposure for three months | Air | 2.40 ± 0.69 | | | | Negative: No increase in MN frequency at all treatment doses in both sexes. No dose-related change in % PCE, an indicator of bone marrow toxicity, was seen.
NTP (2009) | Micronucleus formation peripheral blood erythrocytes | B6C3F_1_ mice male and female, 9-10/sex/group | Inhalation, two trials Trial 1: 62.5 to 1,000 ppm Trial 2: 62.5 to 500 ppm Exposure for three months | 62.5 | 2.20 ± 0.66 | | | | Negative: No increase in MN frequency at all treatment doses in both sexes. No dose-related change in % PCE, an indicator of bone marrow toxicity, was seen.
NTP (2009) | Micronucleus formation peripheral blood erythrocytes | B6C3F_1_ mice male and female, 9-10/sex/group | Inhalation, two trials Trial 1: 62.5 to 1,000 ppm Trial 2: 62.5 to 500 ppm Exposure for three months | 125 | 2.10 ± 0.48 | | | | Negative: No increase in MN frequency at all treatment doses in both sexes. No dose-related change in % PCE, an indicator of bone marrow toxicity, was seen.
NTP (2009) | Micronucleus formation peripheral blood erythrocytes | B6C3F_1_ mice male and female, 9-10/sex/group | Inhalation, two trials Trial 1: 62.5 to 1,000 ppm Trial 2: 62.5 to 500 ppm Exposure for three months | 250 | 1.80 ± 0.36 | | | | Negative: No increase in MN frequency at all treatment doses in both sexes. No dose-related change in % PCE, an indicator of bone marrow toxicity, was seen.
NTP (2009) | Micronucleus formation peripheral blood erythrocytes | B6C3F_1_ mice male and female, 9-10/sex/group | Inhalation, two trials Trial 1: 62.5 to 1,000 ppm Trial 2: 62.5 to 500 ppm Exposure for three months | 500 | 2.00 ± 0.26 | | | | Negative: No increase in MN frequency at all treatment doses in both sexes. No dose-related change in % PCE, an indicator of bone marrow toxicity, was seen.
NTP (2009) | Micronucleus formation peripheral blood erythrocytes | B6C3F_1_ mice male and female, 9-10/sex/group | Inhalation, two trials Trial 1: 62.5 to 1,000 ppm Trial 2: 62.5 to 500 ppm Exposure for three months | 1,000 | 2.20 ± 0.42 | | | | Negative: No increase in MN frequency at all treatment doses in both sexes. No dose-related change in % PCE, an indicator of bone marrow toxicity, was seen.
NTP (2009) | Micronucleus formation peripheral blood erythrocytes | B6C3F_1_ mice male and female, 9-10/sex/group | Inhalation, two trials Trial 1: 62.5 to 1,000 ppm Trial 2: 62.5 to 500 ppm Exposure for three months | Female | | | | | Negative: No increase in MN frequency at all treatment doses in both sexes. No dose-related change in % PCE, an indicator of bone marrow toxicity, was seen.
NTP (2009) | Micronucleus formation peripheral blood erythrocytes | B6C3F_1_ mice male and female, 9-10/sex/group | Inhalation, two trials Trial 1: 62.5 to 1,000 ppm Trial 2: 62.5 to 500 ppm Exposure for three months | Air | 2.30 ± 0.40 | | | | Negative: No increase in MN frequency at all treatment doses in both sexes. No dose-related change in % PCE, an indicator of bone marrow toxicity, was seen.
NTP (2009) | Micronucleus formation peripheral blood erythrocytes | B6C3F_1_ mice male and female, 9-10/sex/group | Inhalation, two trials Trial 1: 62.5 to 1,000 ppm Trial 2: 62.5 to 500 ppm Exposure for three months | 62.5 | 1.33 ± 0.37 | | | | Negative: No increase in MN frequency at all treatment doses in both sexes. No dose-related change in % PCE, an indicator of bone marrow toxicity, was seen.
NTP (2009) | Micronucleus formation peripheral blood erythrocytes | B6C3F_1_ mice male and female, 9-10/sex/group | Inhalation, two trials Trial 1: 62.5 to 1,000 ppm Trial 2: 62.5 to 500 ppm Exposure for three months | 125 | 1.70 ± 0.30 | | | | Negative: No increase in MN frequency at all treatment doses in both sexes. No dose-related change in % PCE, an indicator of bone marrow toxicity, was seen.
NTP (2009) | Micronucleus formation peripheral blood erythrocytes | B6C3F_1_ mice male and female, 9-10/sex/group | Inhalation, two trials Trial 1: 62.5 to 1,000 ppm Trial 2: 62.5 to 500 ppm Exposure for three months | 250 | 2.10 ± 0.53 | | | | Negative: No increase in MN frequency at all treatment doses in both sexes. No dose-related change in % PCE, an indicator of bone marrow toxicity, was seen.
NTP (2009) | Micronucleus formation peripheral blood erythrocytes | B6C3F_1_ mice male and female, 9-10/sex/group | Inhalation, two trials Trial 1: 62.5 to 1,000 ppm Trial 2: 62.5 to 500 ppm Exposure for three months | 500 | 2.10 ± 0.35 | | | | Negative: No increase in MN frequency at all treatment doses in both sexes. No dose-related change in % PCE, an indicator of bone marrow toxicity, was seen.
NTP (2009) | Micronucleus formation peripheral blood erythrocytes | B6C3F_1_ mice male and female, 6/sex/group | Gavage Males: 312 to 1,250 mg/kg/day Females: 250 to 1,000 mg/kg/day Exposure once daily for four days; final dose was administered 21 hr following third dose, peripheral blood collected 3 hr later | Dose (mg/kg) | MN-NCEs/1,000 NCEs | | | | PCE-MN based on evaluating 20,000 reticulocytes (CD71-positive erythrocytes). NCE-MN based on evaluating 1x10^6^ erythrocytes In male mice, the percentage of PCE, a measure of bone marrow toxicity, increased over the dose range examined (p = 0.031), although the increase did not reach the level of statistical significance, which was set at p < 0.025.^b^ PCE-MN are considered more sensitive than NCE-MN values because damaged erythrocytes in the erythrocyte population do not reach peak levels until 28 days of repeat dosing. Negative: No increased in MN frequency for all treatment doses
NTP (2009) | Micronucleus formation peripheral blood erythrocytes | B6C3F_1_ mice male and female, 6/sex/group | Gavage Males: 312 to 1,250 mg/kg/day Females: 250 to 1,000 mg/kg/day Exposure once daily for four days; final dose was administered 21 hr following third dose, peripheral blood collected 3 hr later | Male
NTP (2009) | Micronucleus formation peripheral blood erythrocytes | B6C3F_1_ mice male and female, 6/sex/group | Gavage Males: 312 to 1,250 mg/kg/day Females: 250 to 1,000 mg/kg/day Exposure once daily for four days; final dose was administered 21 hr following third dose, peripheral blood collected 3 hr later | 0 | 1.48 ± 0.04
NTP (2009) | Micronucleus formation peripheral blood erythrocytes | B6C3F_1_ mice male and female, 6/sex/group | Gavage Males: 312 to 1,250 mg/kg/day Females: 250 to 1,000 mg/kg/day Exposure once daily for four days; final dose was administered 21 hr following third dose, peripheral blood collected 3 hr later | 312 | 1.47 ± 0.04
NTP (2009) | Micronucleus formation peripheral blood erythrocytes | B6C3F_1_ mice male and female, 6/sex/group | Gavage Males: 312 to 1,250 mg/kg/day Females: 250 to 1,000 mg/kg/day Exposure once daily for four days; final dose was administered 21 hr following third dose, peripheral blood collected 3 hr later | 625 | 1.47 ± 0.03
NTP (2009) | Micronucleus formation peripheral blood erythrocytes | B6C3F_1_ mice male and female, 6/sex/group | Gavage Males: 312 to 1,250 mg/kg/day Females: 250 to 1,000 mg/kg/day Exposure once daily for four days; final dose was administered 21 hr following third dose, peripheral blood collected 3 hr later | 1,250 | 1.51 ± 0.03
NTP (2009) | Micronucleus formation peripheral blood erythrocytes | B6C3F_1_ mice male and female, 6/sex/group | Gavage Males: 312 to 1,250 mg/kg/day Females: 250 to 1,000 mg/kg/day Exposure once daily for four days; final dose was administered 21 hr following third dose, peripheral blood collected 3 hr later | Female
NTP (2009) | Micronucleus formation peripheral blood erythrocytes | B6C3F_1_ mice male and female, 6/sex/group | Gavage Males: 312 to 1,250 mg/kg/day Females: 250 to 1,000 mg/kg/day Exposure once daily for four days; final dose was administered 21 hr following third dose, peripheral blood collected 3 hr later | 0 | 1.20 ± 0.02
NTP (2009) | Micronucleus formation peripheral blood erythrocytes | B6C3F_1_ mice male and female, 6/sex/group | Gavage Males: 312 to 1,250 mg/kg/day Females: 250 to 1,000 mg/kg/day Exposure once daily for four days; final dose was administered 21 hr following third dose, peripheral blood collected 3 hr later | 250 | 1.17 ± 0.02
NTP (2009) | Micronucleus formation peripheral blood erythrocytes | B6C3F_1_ mice male and female, 6/sex/group | Gavage Males: 312 to 1,250 mg/kg/day Females: 250 to 1,000 mg/kg/day Exposure once daily for four days; final dose was administered 21 hr following third dose, peripheral blood collected 3 hr later | 500 | 1.16 ± 0.02
NTP (2009) | Micronucleus formation peripheral blood erythrocytes | B6C3F_1_ mice male and female, 6/sex/group | Gavage Males: 312 to 1,250 mg/kg/day Females: 250 to 1,000 mg/kg/day Exposure once daily for four days; final dose was administered 21 hr following third dose, peripheral blood collected 3 hr later | 1,000 | 1.12 ± 0.01
NTP (2009) | Micronucleus formation peripheral blood erythrocytes | B6C3F_1_ mice male and female, 6/sex/group | Gavage Males: 312 to 1,250 mg/kg/day Females: 250 to 1,000 mg/kg/day Exposure once daily for four days; final dose was administered 21 hr following third dose, peripheral blood collected 3 hr later | Dose (mg/kg) | MN-PCEs/1,000 NCEs
NTP (2009) | Micronucleus formation peripheral blood erythrocytes | B6C3F_1_ mice male and female, 6/sex/group | Gavage Males: 312 to 1,250 mg/kg/day Females: 250 to 1,000 mg/kg/day Exposure once daily for four days; final dose was administered 21 hr following third dose, peripheral blood collected 3 hr later | Male
NTP (2009) | Micronucleus formation peripheral blood erythrocytes | B6C3F_1_ mice male and female, 6/sex/group | Gavage Males: 312 to 1,250 mg/kg/day Females: 250 to 1,000 mg/kg/day Exposure once daily for four days; final dose was administered 21 hr following third dose, peripheral blood collected 3 hr later | 0 | 2.75 ± 0.17
NTP (2009) | Micronucleus formation peripheral blood erythrocytes | B6C3F_1_ mice male and female, 6/sex/group | Gavage Males: 312 to 1,250 mg/kg/day Females: 250 to 1,000 mg/kg/day Exposure once daily for four days; final dose was administered 21 hr following third dose, peripheral blood collected 3 hr later | 312 | 2.34 ± 0.11
NTP (2009) | Micronucleus formation peripheral blood erythrocytes | B6C3F_1_ mice male and female, 6/sex/group | Gavage Males: 312 to 1,250 mg/kg/day Females: 250 to 1,000 mg/kg/day Exposure once daily for four days; final dose was administered 21 hr following third dose, peripheral blood collected 3 hr later | 625 | 2.90 ± 0.23
NTP (2009) | Micronucleus formation peripheral blood erythrocytes | B6C3F_1_ mice male and female, 6/sex/group | Gavage Males: 312 to 1,250 mg/kg/day Females: 250 to 1,000 mg/kg/day Exposure once daily for four days; final dose was administered 21 hr following third dose, peripheral blood collected 3 hr later | 1,250 | 3.05 ± 0.29
NTP (2009) | Micronucleus formation peripheral blood erythrocytes | B6C3F_1_ mice male and female, 6/sex/group | Gavage Males: 312 to 1,250 mg/kg/day Females: 250 to 1,000 mg/kg/day Exposure once daily for four days; final dose was administered 21 hr following third dose, peripheral blood collected 3 hr later | Trend test: p = 0.067
NTP (2009) | Micronucleus formation peripheral blood erythrocytes | B6C3F_1_ mice male and female, 6/sex/group | Gavage Males: 312 to 1,250 mg/kg/day Females: 250 to 1,000 mg/kg/day Exposure once daily for four days; final dose was administered 21 hr following third dose, peripheral blood collected 3 hr later | Female
NTP (2009) | Micronucleus formation peripheral blood erythrocytes | B6C3F_1_ mice male and female, 6/sex/group | Gavage Males: 312 to 1,250 mg/kg/day Females: 250 to 1,000 mg/kg/day Exposure once daily for four days; final dose was administered 21 hr following third dose, peripheral blood collected 3 hr later | 0 | 2.37 ± 0.07
NTP (2009) | Micronucleus formation peripheral blood erythrocytes | B6C3F_1_ mice male and female, 6/sex/group | Gavage Males: 312 to 1,250 mg/kg/day Females: 250 to 1,000 mg/kg/day Exposure once daily for four days; final dose was administered 21 hr following third dose, peripheral blood collected 3 hr later | 250 | 2.23 ± 0.12
NTP (2009) | Micronucleus formation peripheral blood erythrocytes | B6C3F_1_ mice male and female, 6/sex/group | Gavage Males: 312 to 1,250 mg/kg/day Females: 250 to 1,000 mg/kg/day Exposure once daily for four days; final dose was administered 21 hr following third dose, peripheral blood collected 3 hr later | 500 | 2.44 ± 0.19
NTP (2009) | Micronucleus formation peripheral blood erythrocytes | B6C3F_1_ mice male and female, 6/sex/group | Gavage Males: 312 to 1,250 mg/kg/day Females: 250 to 1,000 mg/kg/day Exposure once daily for four days; final dose was administered 21 hr following third dose, peripheral blood collected 3 hr later | 1,000 | 1.89 ± 0.14
NTP (2009) | Micronucleus formation peripheral blood erythrocytes | B6C3F_1_ mice male and female, 6/sex/group | Gavage Males: 312 to 1,250 mg/kg/day Females: 250 to 1,000 mg/kg/day Exposure once daily for four days; final dose was administered 21 hr following third dose, peripheral blood collected 3 hr later | Trend test: p = 0.985
NTP (2009) | Micronucleus formation bone marrow polychromatic erythrocytes | F344/N rats male, 5/group | Intraperitoneal injection, two trials Trial 1: 78 to 2,500 mg/kg for three days, sacrificed d4 Trial 2: 312 to 2,500 mg/kg for three days, sacrificed d4 Exposure three times at 24-hour intervals | Dose (mg/kg) | MN-PCEs/1,000 PCEs^b,c^ | | | | Data from high dose (2,500 mg/kg) excluded from trend test in both trials due to high animal mortality (survival 2/5 in Trial 1 and 3/5 in Trial 2). No dose-related change in the percent PCE was seen. Positive
NTP (2009) | Micronucleus formation bone marrow polychromatic erythrocytes | F344/N rats male, 5/group | Intraperitoneal injection, two trials Trial 1: 78 to 2,500 mg/kg for three days, sacrificed d4 Trial 2: 312 to 2,500 mg/kg for three days, sacrificed d4 Exposure three times at 24-hour intervals | Trial 1
NTP (2009) | Micronucleus formation bone marrow polychromatic erythrocytes | F344/N rats male, 5/group | Intraperitoneal injection, two trials Trial 1: 78 to 2,500 mg/kg for three days, sacrificed d4 Trial 2: 312 to 2,500 mg/kg for three days, sacrificed d4 Exposure three times at 24-hour intervals | 0 | 0.50 ± 0.16
NTP (2009) | Micronucleus formation bone marrow polychromatic erythrocytes | F344/N rats male, 5/group | Intraperitoneal injection, two trials Trial 1: 78 to 2,500 mg/kg for three days, sacrificed d4 Trial 2: 312 to 2,500 mg/kg for three days, sacrificed d4 Exposure three times at 24-hour intervals | 78.13 | 1.20 ± 0.25
NTP (2009) | Micronucleus formation bone marrow polychromatic erythrocytes | F344/N rats male, 5/group | Intraperitoneal injection, two trials Trial 1: 78 to 2,500 mg/kg for three days, sacrificed d4 Trial 2: 312 to 2,500 mg/kg for three days, sacrificed d4 Exposure three times at 24-hour intervals | 156.25 | 1.20 ± 0.34
NTP (2009) | Micronucleus formation bone marrow polychromatic erythrocytes | F344/N rats male, 5/group | Intraperitoneal injection, two trials Trial 1: 78 to 2,500 mg/kg for three days, sacrificed d4 Trial 2: 312 to 2,500 mg/kg for three days, sacrificed d4 Exposure three times at 24-hour intervals | 312.5 | 1.30 ± 0.54*
NTP (2009) | Micronucleus formation bone marrow polychromatic erythrocytes | F344/N rats male, 5/group | Intraperitoneal injection, two trials Trial 1: 78 to 2,500 mg/kg for three days, sacrificed d4 Trial 2: 312 to 2,500 mg/kg for three days, sacrificed d4 Exposure three times at 24-hour intervals | 625 | 0.80 ± 0.41
NTP (2009) | Micronucleus formation bone marrow polychromatic erythrocytes | F344/N rats male, 5/group | Intraperitoneal injection, two trials Trial 1: 78 to 2,500 mg/kg for three days, sacrificed d4 Trial 2: 312 to 2,500 mg/kg for three days, sacrificed d4 Exposure three times at 24-hour intervals | 1,250 | 2.60 ± 0.29***
NTP (2009) | Micronucleus formation bone marrow polychromatic erythrocytes | F344/N rats male, 5/group | Intraperitoneal injection, two trials Trial 1: 78 to 2,500 mg/kg for three days, sacrificed d4 Trial 2: 312 to 2,500 mg/kg for three days, sacrificed d4 Exposure three times at 24-hour intervals | 2,500 | 1.25 ± 0.25
NTP (2009) | Micronucleus formation bone marrow polychromatic erythrocytes | F344/N rats male, 5/group | Intraperitoneal injection, two trials Trial 1: 78 to 2,500 mg/kg for three days, sacrificed d4 Trial 2: 312 to 2,500 mg/kg for three days, sacrificed d4 Exposure three times at 24-hour intervals | Trend test: p < 0.001***
NTP (2009) | Micronucleus formation bone marrow polychromatic erythrocytes | F344/N rats male, 5/group | Intraperitoneal injection, two trials Trial 1: 78 to 2,500 mg/kg for three days, sacrificed d4 Trial 2: 312 to 2,500 mg/kg for three days, sacrificed d4 Exposure three times at 24-hour intervals | Trial 2
NTP (2009) | Micronucleus formation bone marrow polychromatic erythrocytes | F344/N rats male, 5/group | Intraperitoneal injection, two trials Trial 1: 78 to 2,500 mg/kg for three days, sacrificed d4 Trial 2: 312 to 2,500 mg/kg for three days, sacrificed d4 Exposure three times at 24-hour intervals | 0 | 0.50 ± 0.27
NTP (2009) | Micronucleus formation bone marrow polychromatic erythrocytes | F344/N rats male, 5/group | Intraperitoneal injection, two trials Trial 1: 78 to 2,500 mg/kg for three days, sacrificed d4 Trial 2: 312 to 2,500 mg/kg for three days, sacrificed d4 Exposure three times at 24-hour intervals | 312 | 1.70 ± 0.20**
NTP (2009) | Micronucleus formation bone marrow polychromatic erythrocytes | F344/N rats male, 5/group | Intraperitoneal injection, two trials Trial 1: 78 to 2,500 mg/kg for three days, sacrificed d4 Trial 2: 312 to 2,500 mg/kg for three days, sacrificed d4 Exposure three times at 24-hour intervals | 625 | 1.40 ± 0.33*
NTP (2009) | Micronucleus formation bone marrow polychromatic erythrocytes | F344/N rats male, 5/group | Intraperitoneal injection, two trials Trial 1: 78 to 2,500 mg/kg for three days, sacrificed d4 Trial 2: 312 to 2,500 mg/kg for three days, sacrificed d4 Exposure three times at 24-hour intervals | 1,250 | 1.80 ± 0.34***
NTP (2009) | Micronucleus formation bone marrow polychromatic erythrocytes | F344/N rats male, 5/group | Intraperitoneal injection, two trials Trial 1: 78 to 2,500 mg/kg for three days, sacrificed d4 Trial 2: 312 to 2,500 mg/kg for three days, sacrificed d4 Exposure three times at 24-hour intervals | 2,500 | 1.50 ± 1.00*
NTP (2009) | Micronucleus formation bone marrow polychromatic erythrocytes | F344/N rats male, 5/group | Intraperitoneal injection, two trials Trial 1: 78 to 2,500 mg/kg for three days, sacrificed d4 Trial 2: 312 to 2,500 mg/kg for three days, sacrificed d4 Exposure three times at 24-hour intervals | Trend test: p = 0.085
NTP (2012) | Micronucleus formation peripheral blood erythrocytes | F344/DuCrl rats male, 6/group | Gavage 200 to 800 mg/kg/day Exposure once daily for four days; final dose was administered 21 hr following third dose, peripheral blood collected 3 hr later | Dose (mg/kg) | MN-PCEs/1,000 PCEs | | | | PCE-MN restricted to youngest reticulocytes (cells with the highest CD71 expression using cell cytometry); 20,000 evaluated PCE (20,000). Technique considered as sensitive as measuring bone marrow PCE for short term studies in rats. NCEs were measured but are not presented because no increase was seen with EMS, the positive control. The PCE results are the more valid population to evaluate because they are the least altered by the efficient action by the rat spleen in sequestering and destroying micronucleated erythrocytes. In rats, the percentage of PCE was reduced significantly (30% reduction from control) at the top dose, indicating that this dose of cumene induced bone marrow toxicity over the 4-day treatment period. However, the degree of reduction was not excessive (OECD Guideline 474 permits a reduction to a level of 20% of the control value). Negative: no increased MN frequency at all treatment doses
NTP (2012) | Micronucleus formation peripheral blood erythrocytes | F344/DuCrl rats male, 6/group | Gavage 200 to 800 mg/kg/day Exposure once daily for four days; final dose was administered 21 hr following third dose, peripheral blood collected 3 hr later | 0 | 0.33 ± 0.03
NTP (2012) | Micronucleus formation peripheral blood erythrocytes | F344/DuCrl rats male, 6/group | Gavage 200 to 800 mg/kg/day Exposure once daily for four days; final dose was administered 21 hr following third dose, peripheral blood collected 3 hr later | 200 | 0.27 ± 0.05
NTP (2012) | Micronucleus formation peripheral blood erythrocytes | F344/DuCrl rats male, 6/group | Gavage 200 to 800 mg/kg/day Exposure once daily for four days; final dose was administered 21 hr following third dose, peripheral blood collected 3 hr later | 400 | 0.33 ± 0.05
NTP (2012) | Micronucleus formation peripheral blood erythrocytes | F344/DuCrl rats male, 6/group | Gavage 200 to 800 mg/kg/day Exposure once daily for four days; final dose was administered 21 hr following third dose, peripheral blood collected 3 hr later | 800 | 0.18 ± 0.06
Kim et al. (2008) | Fpg/Endo III FLARE Assay oxidative damage Hepatocytes Lymphocytes Olive tail moment (OTM) Tail length (TL) Conditions: Buffer Fpg excision repair enzyme (Fpg) Endonuclease III (Endo) | Sprague-Dawley rats male, 20/group | Inhalation (whole body) 0, 8, 80, 800 ppm 6 hours/day for up to13 weeks; Buffer (no enzyme), Fpg:Endo II: olive tail moment and tail length measured in hepatocytes and lympocytes and OGG1 mRNA expression measured in hepatocytes at 1, 14, 28, and 90 days | For hepatocytes with endonuclease, OTM values for 1 and 90 day exposures were significantly increased for 8 ppm (compared with control) but reduced for 800 ppm (compared with 8 ppm). There was little effect on TL values under any conditions. For lymphocytes, both OTM and TL values were reported to have several statistically significant results under various conditions. However, any pattern of results is obscured by an incomplete and inconsistent statistical analyses and no clear conclusions can be drawn from the results of this study. | | | | | Unacceptably high measures of background (0 ppm treatment) of DNA damage in controls; wide variation in DNA damage of controls across time periods; large standard deviations for all data. Inappropriate and inconsistent statistical analyses: reference group changes with no rationale (e.g., sometimes is unexposed only and other times is a combined group of the unexposed and low or unexposed, low and medium exposure groups). No adjustment made for multiple comparisons. Inadequate documentation (i.e., incomplete and unclear reporting of methods and disussion of findings).
NTP (2012) | DNA damage (Comet assay) | F344/DuCrl rats male, 6/group | Gavage 200 to 800 mg/kg/day Exposure once daily for four days; final dose was administered 21 hr following third dose, peripheral blood, liver, lung and kidney tissue collected 3 hr later | Tissue | mg/kg | | %Tail DNA^b,c^ | | Positive responses: Liver: Statistically significant for high dose pairwise comparison to control group (p = 0.004) and for trend test (p = 0.002).^c^
NTP (2012) | DNA damage (Comet assay) | F344/DuCrl rats male, 6/group | Gavage 200 to 800 mg/kg/day Exposure once daily for four days; final dose was administered 21 hr following third dose, peripheral blood, liver, lung and kidney tissue collected 3 hr later | Blood | 0 | | 3.664 ± 0.394 | | Positive responses: Liver: Statistically significant for high dose pairwise comparison to control group (p = 0.004) and for trend test (p = 0.002).^c^
NTP (2012) | DNA damage (Comet assay) | F344/DuCrl rats male, 6/group | Gavage 200 to 800 mg/kg/day Exposure once daily for four days; final dose was administered 21 hr following third dose, peripheral blood, liver, lung and kidney tissue collected 3 hr later | Blood | 200 | | 3.575 ± 0.195 | | Positive responses: Liver: Statistically significant for high dose pairwise comparison to control group (p = 0.004) and for trend test (p = 0.002).^c^
NTP (2012) | DNA damage (Comet assay) | F344/DuCrl rats male, 6/group | Gavage 200 to 800 mg/kg/day Exposure once daily for four days; final dose was administered 21 hr following third dose, peripheral blood, liver, lung and kidney tissue collected 3 hr later | Blood | 400 | | 4.188 ± 0.402 | | Positive responses: Liver: Statistically significant for high dose pairwise comparison to control group (p = 0.004) and for trend test (p = 0.002).^c^
NTP (2012) | DNA damage (Comet assay) | F344/DuCrl rats male, 6/group | Gavage 200 to 800 mg/kg/day Exposure once daily for four days; final dose was administered 21 hr following third dose, peripheral blood, liver, lung and kidney tissue collected 3 hr later | Blood | 800 | | 4.011 ± 0.416 | | Positive responses: Liver: Statistically significant for high dose pairwise comparison to control group (p = 0.004) and for trend test (p = 0.002).^c^
NTP (2012) | DNA damage (Comet assay) | F344/DuCrl rats male, 6/group | Gavage 200 to 800 mg/kg/day Exposure once daily for four days; final dose was administered 21 hr following third dose, peripheral blood, liver, lung and kidney tissue collected 3 hr later | Liver | 0 | | 5.876 ± 0.616 | | Positive responses: Liver: Statistically significant for high dose pairwise comparison to control group (p = 0.004) and for trend test (p = 0.002).^c^
NTP (2012) | DNA damage (Comet assay) | F344/DuCrl rats male, 6/group | Gavage 200 to 800 mg/kg/day Exposure once daily for four days; final dose was administered 21 hr following third dose, peripheral blood, liver, lung and kidney tissue collected 3 hr later | Liver | 200 | | 6.967 ± 0.415 | | Positive responses: Liver: Statistically significant for high dose pairwise comparison to control group (p = 0.004) and for trend test (p = 0.002).^c^
NTP (2012) | DNA damage (Comet assay) | F344/DuCrl rats male, 6/group | Gavage 200 to 800 mg/kg/day Exposure once daily for four days; final dose was administered 21 hr following third dose, peripheral blood, liver, lung and kidney tissue collected 3 hr later | Liver | 400 | | 7.505 ± 0.637 | | Positive responses: Liver: Statistically significant for high dose pairwise comparison to control group (p = 0.004) and for trend test (p = 0.002).^c^
NTP (2012) | DNA damage (Comet assay) | F344/DuCrl rats male, 6/group | Gavage 200 to 800 mg/kg/day Exposure once daily for four days; final dose was administered 21 hr following third dose, peripheral blood, liver, lung and kidney tissue collected 3 hr later | Liver | 800 | | 8.465 ± 0.730*** | | Positive responses: Liver: Statistically significant for high dose pairwise comparison to control group (p = 0.004) and for trend test (p = 0.002).^c^
NTP (2012) | DNA damage (Comet assay) | F344/DuCrl rats male, 6/group | Gavage 200 to 800 mg/kg/day Exposure once daily for four days; final dose was administered 21 hr following third dose, peripheral blood, liver, lung and kidney tissue collected 3 hr later | Trend test: p = 0.002*** | | | | | Positive responses: Liver: Statistically significant for high dose pairwise comparison to control group (p = 0.004) and for trend test (p = 0.002).^c^
NTP (2012) | DNA damage (Comet assay) | F344/DuCrl rats male, 6/group | Gavage 200 to 800 mg/kg/day Exposure once daily for four days; final dose was administered 21 hr following third dose, peripheral blood, liver, lung and kidney tissue collected 3 hr later | Lung | 0 | | 6.374 ± 0.327 | | Positive responses: Liver: Statistically significant for high dose pairwise comparison to control group (p = 0.004) and for trend test (p = 0.002).^c^
NTP (2012) | DNA damage (Comet assay) | F344/DuCrl rats male, 6/group | Gavage 200 to 800 mg/kg/day Exposure once daily for four days; final dose was administered 21 hr following third dose, peripheral blood, liver, lung and kidney tissue collected 3 hr later | Lung | 200 | | 6.344 ± 0.696 | | Positive responses: Liver: Statistically significant for high dose pairwise comparison to control group (p = 0.004) and for trend test (p = 0.002).^c^
NTP (2012) | DNA damage (Comet assay) | F344/DuCrl rats male, 6/group | Gavage 200 to 800 mg/kg/day Exposure once daily for four days; final dose was administered 21 hr following third dose, peripheral blood, liver, lung and kidney tissue collected 3 hr later | Lung | 400 | | 7.201 ± 1.029 | | Positive responses: Liver: Statistically significant for high dose pairwise comparison to control group (p = 0.004) and for trend test (p = 0.002).^c^
NTP (2012) | DNA damage (Comet assay) | F344/DuCrl rats male, 6/group | Gavage 200 to 800 mg/kg/day Exposure once daily for four days; final dose was administered 21 hr following third dose, peripheral blood, liver, lung and kidney tissue collected 3 hr later | Lung | 800 | | 7.395 ± 0.450 | | Positive responses: Liver: Statistically significant for high dose pairwise comparison to control group (p = 0.004) and for trend test (p = 0.002).^c^
NTP (2012) | DNA damage (Comet assay) | F344/DuCrl rats male, 6/group | Gavage 200 to 800 mg/kg/day Exposure once daily for four days; final dose was administered 21 hr following third dose, peripheral blood, liver, lung and kidney tissue collected 3 hr later | Kidney | 0 | | 8.176 ± 0.474 | | Positive responses: Liver: Statistically significant for high dose pairwise comparison to control group (p = 0.004) and for trend test (p = 0.002).^c^
NTP (2012) | DNA damage (Comet assay) | F344/DuCrl rats male, 6/group | Gavage 200 to 800 mg/kg/day Exposure once daily for four days; final dose was administered 21 hr following third dose, peripheral blood, liver, lung and kidney tissue collected 3 hr later | Kidney | 200 | | 7.530 ± 1.005 | | Positive responses: Liver: Statistically significant for high dose pairwise comparison to control group (p = 0.004) and for trend test (p = 0.002).^c^
NTP (2012) | DNA damage (Comet assay) | F344/DuCrl rats male, 6/group | Gavage 200 to 800 mg/kg/day Exposure once daily for four days; final dose was administered 21 hr following third dose, peripheral blood, liver, lung and kidney tissue collected 3 hr later | Kidney | 400 | | 7.681 ± 0.910 | | Positive responses: Liver: Statistically significant for high dose pairwise comparison to control group (p = 0.004) and for trend test (p = 0.002).^c^
NTP (2012) | DNA damage (Comet assay) | F344/DuCrl rats male, 6/group | Gavage 200 to 800 mg/kg/day Exposure once daily for four days; final dose was administered 21 hr following third dose, peripheral blood, liver, lung and kidney tissue collected 3 hr later | Kidney | 800 | | 7.085 ± 0.393 | | Positive responses: Liver: Statistically significant for high dose pairwise comparison to control group (p = 0.004) and for trend test (p = 0.002).^c^
NTP (2012) | DNA damage (Comet assay) | B6C3F_1_ mice male and female. 6/sex/group | Gavage Males: 312 to 1,250 mg/kg/day Females: 250 to 1,000 mg/kg/day Exposure once daily for four days; final dose was administered 21 hr following third dose, peripheral blood, liver, lung, and kidney tissue collected 3 hr later. | Male | | | | | –
NTP (2012) | DNA damage (Comet assay) | B6C3F_1_ mice male and female. 6/sex/group | | Tissue | | mg/kg | | %Tail DNA^b,c^ | –
NTP (2012) | DNA damage (Comet assay) | B6C3F_1_ mice male and female. 6/sex/group | | Blood | | 0 | | 2.409 ± 0.375 | –
NTP (2012) | DNA damage (Comet assay) | B6C3F_1_ mice male and female. 6/sex/group | | Blood | | 312 | | 2.442 ± 0.248 | –
NTP (2012) | DNA damage (Comet assay) | B6C3F_1_ mice male and female. 6/sex/group | | Blood | | 625 | | 2.580 ± 0.511 | –
NTP (2012) | DNA damage (Comet assay) | B6C3F_1_ mice male and female. 6/sex/group | | Blood | | 1,250 | | 2.006 ± 0.274 | –
NTP (2012) | DNA damage (Comet assay) | B6C3F_1_ mice male and female. 6/sex/group | | Liver | | 0 | | 7.498 ± 0.784 | –
NTP (2012) | DNA damage (Comet assay) | B6C3F_1_ mice male and female. 6/sex/group | | Liver | | 312 | | 9.284 ± 0.351 | –
NTP (2012) | DNA damage (Comet assay) | B6C3F_1_ mice male and female. 6/sex/group | | Liver | | 625 | | 7.632 ± 0.546 | –
NTP (2012) | DNA damage (Comet assay) | B6C3F_1_ mice male and female. 6/sex/group | | Liver | | 1,250 | | 8.333 ± 1.067 | –
NTP (2012) | DNA damage (Comet assay) | B6C3F_1_ mice male and female. 6/sex/group | | Lung | | 0 | | 11.875 ± 1.212 | –
NTP (2012) | DNA damage (Comet assay) | B6C3F_1_ mice male and female. 6/sex/group | | Lung | | 312 | | 12.145 ± 0.800 | –
NTP (2012) | DNA damage (Comet assay) | B6C3F_1_ mice male and female. 6/sex/group | | Lung | | 625 | | 13.676 ± 1.330 | –
NTP (2012) | DNA damage (Comet assay) | B6C3F_1_ mice male and female. 6/sex/group | | Lung | | 1,250 | | 12.983 ± 1.252 | –
NTP (2012) | DNA damage (Comet assay) | B6C3F_1_ mice male and female. 6/sex/group | | Kidney | | 0 | | 3.497 ± 0.198 | –
NTP (2012) | DNA damage (Comet assay) | B6C3F_1_ mice male and female. 6/sex/group | | Kidney | | 312 | | 4.037 ± 0.456 | –
NTP (2012) | DNA damage (Comet assay) | B6C3F_1_ mice male and female. 6/sex/group | | Kidney | | 625 | | 3.385 ± 0.261 | –
NTP (2012) | DNA damage (Comet assay) | B6C3F_1_ mice male and female. 6/sex/group | | Kidney | | 1,250 | | 3.753 ± 0.483 | –
NTP (2012) | DNA damage (Comet assay) | B6C3F_1_ mice male and female. 6/sex/group | | Female | | | | | [underlined: Positive responses:] Female: Lung: Statistically significant for high dose pairwise comparison to control group (p = 0.016) and for trend test (p = 0.008).^c^
NTP (2012) | DNA damage (Comet assay) | B6C3F_1_ mice male and female. 6/sex/group | | Tissue | | mg/kg | | %Tail DNA^b,c^ | [underlined: Positive responses:] Female: Lung: Statistically significant for high dose pairwise comparison to control group (p = 0.016) and for trend test (p = 0.008).^c^
NTP (2012) | DNA damage (Comet assay) | B6C3F_1_ mice male and female. 6/sex/group | | Blood | | 0 | | 2.097 ± 0.175 | [underlined: Positive responses:] Female: Lung: Statistically significant for high dose pairwise comparison to control group (p = 0.016) and for trend test (p = 0.008).^c^
NTP (2012) | DNA damage (Comet assay) | B6C3F_1_ mice male and female. 6/sex/group | | Blood | | 250 | | 2.362 ± 0.357 | [underlined: Positive responses:] Female: Lung: Statistically significant for high dose pairwise comparison to control group (p = 0.016) and for trend test (p = 0.008).^c^
NTP (2012) | DNA damage (Comet assay) | B6C3F_1_ mice male and female. 6/sex/group | | Blood | | 500 | | 1.949 ± 0.210 | [underlined: Positive responses:] Female: Lung: Statistically significant for high dose pairwise comparison to control group (p = 0.016) and for trend test (p = 0.008).^c^
NTP (2012) | DNA damage (Comet assay) | B6C3F_1_ mice male and female. 6/sex/group | | Blood | | 1,000 | | 2.063 ± 0.245 | [underlined: Positive responses:] Female: Lung: Statistically significant for high dose pairwise comparison to control group (p = 0.016) and for trend test (p = 0.008).^c^
NTP (2012) | DNA damage (Comet assay) | B6C3F_1_ mice male and female. 6/sex/group | | Liver | | 0 | | 10.417 ± 1.676 | [underlined: Positive responses:] Female: Lung: Statistically significant for high dose pairwise comparison to control group (p = 0.016) and for trend test (p = 0.008).^c^
NTP (2012) | DNA damage (Comet assay) | B6C3F_1_ mice male and female. 6/sex/group | | Liver | | 250 | | 11.182 ± 1.913 | [underlined: Positive responses:] Female: Lung: Statistically significant for high dose pairwise comparison to control group (p = 0.016) and for trend test (p = 0.008).^c^
NTP (2012) | DNA damage (Comet assay) | B6C3F_1_ mice male and female. 6/sex/group | | Liver | | 500 | | 10.993 ± 0.958 | [underlined: Positive responses:] Female: Lung: Statistically significant for high dose pairwise comparison to control group (p = 0.016) and for trend test (p = 0.008).^c^
NTP (2012) | DNA damage (Comet assay) | B6C3F_1_ mice male and female. 6/sex/group | | Liver | | 1,000 | | 9.303 ± 1.834 | [underlined: Positive responses:] Female: Lung: Statistically significant for high dose pairwise comparison to control group (p = 0.016) and for trend test (p = 0.008).^c^
NTP (2012) | DNA damage (Comet assay) | B6C3F_1_ mice male and female. 6/sex/group | | Lung | | 0 | | 6.785 ± 0.324 | [underlined: Positive responses:] Female: Lung: Statistically significant for high dose pairwise comparison to control group (p = 0.016) and for trend test (p = 0.008).^c^
NTP (2012) | DNA damage (Comet assay) | B6C3F_1_ mice male and female. 6/sex/group | | Lung | | 250 | | 7.328 ± 0.551 | [underlined: Positive responses:] Female: Lung: Statistically significant for high dose pairwise comparison to control group (p = 0.016) and for trend test (p = 0.008).^c^
NTP (2012) | DNA damage (Comet assay) | B6C3F_1_ mice male and female. 6/sex/group | | Lung | | 500 | | 7.787 ± 0.698 | [underlined: Positive responses:] Female: Lung: Statistically significant for high dose pairwise comparison to control group (p = 0.016) and for trend test (p = 0.008).^c^
NTP (2012) | DNA damage (Comet assay) | B6C3F_1_ mice male and female. 6/sex/group | | Lung | | 1,000 | | 8.723 ± 0.660* | [underlined: Positive responses:] Female: Lung: Statistically significant for high dose pairwise comparison to control group (p = 0.016) and for trend test (p = 0.008).^c^
NTP (2012) | DNA damage (Comet assay) | B6C3F_1_ mice male and female. 6/sex/group | | Trend test: p = 0.008*^c^ | | | | | [underlined: Positive responses:] Female: Lung: Statistically significant for high dose pairwise comparison to control group (p = 0.016) and for trend test (p = 0.008).^c^
NTP (2012) | DNA damage (Comet assay) | B6C3F_1_ mice male and female. 6/sex/group | | Kidney | | 0 | | 5.646 ± 0.746 | [underlined: Positive responses:] Female: Lung: Statistically significant for high dose pairwise comparison to control group (p = 0.016) and for trend test (p = 0.008).^c^
NTP (2012) | DNA damage (Comet assay) | B6C3F_1_ mice male and female. 6/sex/group | | Kidney | | 250 | | 4.416 ± 0.275 | [underlined: Positive responses:] Female: Lung: Statistically significant for high dose pairwise comparison to control group (p = 0.016) and for trend test (p = 0.008).^c^
NTP (2012) | DNA damage (Comet assay) | B6C3F_1_ mice male and female. 6/sex/group | | Kidney | | 500 | | 4.406 ± 0.436 | [underlined: Positive responses:] Female: Lung: Statistically significant for high dose pairwise comparison to control group (p = 0.016) and for trend test (p = 0.008).^c^
NTP (2012) | DNA damage (Comet assay) | B6C3F_1_ mice male and female. 6/sex/group | | Kidney | | 1,000 | | 5.512 ± 0.301 | [underlined: Positive responses:] Female: Lung: Statistically significant for high dose pairwise comparison to control group (p = 0.016) and for trend test (p = 0.008).^c^

* p < 0.05 (compared with controls unless otherwise noted), **p < 0.006, ***p < 0.005.

Endo = endonuclease, detects oxidized pyrimidines; FLARE = Fragment Length Analysis using Repair Enzymes; Fpg = formamidopyrimidine-DNA glycosylase, detects altered (oxidized and ring opened) purines; OGG1 = 8-Oxoguanine glycosylase; OTM = olive tail moment; MN = micronucleated; NCE = normochromatic erythrocyte; PCE = polychromatic erythrocyte; TL = tail length.

^a^ Not specified in peer-reviewed reports, so cell type determined from primary (unpublished) report.

^b^ Dose-related trend; significant at p ≤ 0.025;Pairwise comparison with the control group; significant at p ≤ 0.025.

^c^ Levene’s test is used to determine if variance among groups is equal. If equal, linear regression analysis and pairwise differences are evaluated using William’s test. When variances are unequal, Jonckheere’s test is used to evaluate linear trend data and Dunn’s test is used for pairwise comparisons with control group.

Table D-4 K-ras Mutations in Spontaneous and Cumene-induced Lung Tumors in Mice

Treatment (ppm) | N | No. with K-ras (%) | Codon 12 - GGT (%)^a^ | | | | Codon 61–CAA (%)^a^
Treatment (ppm) | N | No. with K-ras (%) | GAT | TGT | GTT | CGT | CGA | CAT | CTA | CAC
Controls
Historical | 117 | 33 (28) | 14 (42) | 5 (15) | 1 (3) | 0 | 2 (6) | 4 (12) | 0 | 1 (3)
Concurrent | 7 | 1 (14) | 0 | 0 | 0 | 0 | 1 (100) | 0 | 0 | 0
Cumene
125 | 4 | 1 (25) | 0 | 1 (100) | 0 | 0 | 0 | 0 | 0 | 0
250 | 13 | 10 (77) | 0 | 0 | 1 (10) | 2 (20) | 5 (50) | 0 | 0 | 2 (20)
500 | 18 | 17 (94) | 4 (24) | 1 (6) | 6 (35) | 0 | 4 (24) | 0 | 0 | 0
1,000 | 17 | 17 (100) | 2 (12) | 3 (18) | 4 (24) | 1 (6) | 4 (24) | 0 | 1 (6) | 0
Total | 52 | 45 (87) | 6 (13) | 5 (11) | 11 (24) | 3 (7) | 13 (29) | 0 | 1 (2) | 2 (4)

Source: Hong et al. (2008).

^a^ Number of tumors with a specific K-ras mutation/total number of tumors with K-ras mutations.

Table D-5 p53 Mutations in Spontaneous and Cumene-induced Lung Tumors in Mice

Treatment (ppm)^a^ | N | Activated p53 (%) | Tumors with Mutations (%)^b^ | | p53 Protein Expression
Treatment (ppm)^a^ | N | Activated p53 (%) | Exon 5^c^ | Exon 7 | p53 Protein Expression
0 | 7 | 0 | 0 | 0 | 1 (14)
125 | 4 | 0 | 0 | 0 | 1 (25)
250 | 13 | 5 (38) | 4 (80) | 1 (20) | 6 (46)
500 | 18 | 11 (61) | 10 (91) | 1 (9) | 8 (44)
1,000 | 17 | 11 (65) | 10 (91) | 1 (9) | 14 (82)
Total | 52 | 27 (52) | 24 (89) | 3 (11) | 29 (56)

Source: Hong et al. (2008).

^a^ 125 ppm (females only), 1,000 ppm (males only).

^b^ Number of tumors with a specific p53 mutation/total number of tumors with p53 mutations. No mutation detected in exons 6 and 8.

^c^ Three tumors had CGC > CAC transitions in codon 155; one tumor had CAG > TAG transition in codon 13 (Wakamatsu et al. 2008).

Table D-6 In Vitro Genetic Toxicology Test Results for α-Methylstyrene

Reference | Effect | Test System | Results | Concentration or Dose (LEC or LED HIC or HID) | Cytotoxicity (% Survival) | Evaluation: Limitations and Conclusions
NTP (2007) | Reverse mutation | Salmonella typhimurium (TA97, TA98, TA100, TA1535) preincubation assay | Negative for both ±S9, both rat and hamster S9 (10% and 30%) | −S9: 100 µg/plate +S9: 333 µg/plate | −S9: toxic at 333 µg/plate for TA98 and TA100; not tested >100 µg/plate for TA97 and TA1535 (not toxic at these doses) +S9 (rat or hamster 10%): toxic >333 µg/plate for all strains | Results were similar for all bacteria strains; tests were conducted up to 3,333 µg/plate for strains TA98 and TA100, both with 30% rat or 30% hamster S9: all showed toxicity but were not mutagenic.
NTP (2007) | Chromosomal aberrations | Chinese hamster ovary (CHO) cells | Negative for both ±S9 | Negative at HID 200 µg/mL (toxic at higher dose tested) | Toxic at 251.3 µg/mL for both ±S9 | –
Norppa and Vainio (1983) | Sister chromatid exchange | Human whole blood lymphocytes | Weakly positive (for treatment −S9; did not test +S9) | Positive response at ~3 mM^a^ (response ≥20% increase over solvent control) | > ~3 mM^a^ | Data in graphical format Results not double the mean # SCEs/cell; decreased response at higher concentrations may be related to toxicity
NTP (2007) | Sister chromatid exchange | CHO cells | −S9: Negative at 50 µg/mL +S9: Positive for 50, 124.4, 149.9 µg/mL | −S9: 166.7 50 µg/mL (HID) +S9: 50 µg/mL (LED) | For both ±S9: toxic at 166.7 µg/mL | For −S9, negative at 50 µg/mL but toxic at next dose of 166.7 µg/mL (no intermediate doses tested)

LED or LEC, HID or HIC = lowest effective dose or concentration/highest ineffective dose or concentration tested, NT = not tested.

^a^ Dose level estimated from figure.

Table D-7 In Vivo Genetic Toxicology Test Results for α-Methylstyrene

Reference | Effect | Test System | Exposure (ppm) | Results^a^ NCEs | Dose (LED or HID) | Evaluation: Limitations and Conclusions
NTP (2007) | Micronucleus induction | Females B6C3F_1_ mice 3-month inhalation exposure peripheral blood | 0 | 5.10 ± 0.46 | 1,000 ppm | Positive response at highest dose tested and for trend test; 1,000 normochromatic (NCEs) and 1,000 polychromatic erythrocytes (PCEs) scored in 10 animals/exposure group No increase in MN-PCE seen at the 1,000 ppm dose. No dose-related change in the percent PCE was seen.
NTP (2007) | Micronucleus induction | Females B6C3F_1_ mice 3-month inhalation exposure peripheral blood | 75 | 2.40 ± 0.43 | 1,000 ppm
NTP (2007) | Micronucleus induction | Females B6C3F_1_ mice 3-month inhalation exposure peripheral blood | 150 | 2.90 ± 0.90 | 1,000 ppm
NTP (2007) | Micronucleus induction | Females B6C3F_1_ mice 3-month inhalation exposure peripheral blood | 300 | 3.60 ± 0.48 | 1,000 ppm
NTP (2007) | Micronucleus induction | Females B6C3F_1_ mice 3-month inhalation exposure peripheral blood | 600 | 5.30 ± 0.42 | 1,000 ppm
NTP (2007) | Micronucleus induction | Females B6C3F_1_ mice 3-month inhalation exposure peripheral blood | 1,000 | 9.13 ± 0.77*** | 1,000 ppm
NTP (2007) | Micronucleus induction | Females B6C3F_1_ mice 3-month inhalation exposure peripheral blood | Trend test | p < 0.001 | 1,000 ppm
NTP (2007) | Micronucleus induction | Males B6C3F_1_ mice 3-month inhalation exposure peripheral blood | 0 | 5.30 ± 0.50 | 1,000 ppm | Negative response; 1,000 normochromatic (NCEs) and 1,000 polychromatic erythrocytes (PCEs) scored in 10 animals/exposure group. No increase in MN-PCE seen at the 1,000 ppm dose. No dose-related change in the percent PCE was seen.
NTP (2007) | Micronucleus induction | Males B6C3F_1_ mice 3-month inhalation exposure peripheral blood | 75 | 5.80 ± 0.44 | 1,000 ppm
NTP (2007) | Micronucleus induction | Males B6C3F_1_ mice 3-month inhalation exposure peripheral blood | 150 | 5.80 ± 0.63 | 1,000 ppm
NTP (2007) | Micronucleus induction | Males B6C3F_1_ mice 3-month inhalation exposure peripheral blood | 300 | 5.00 ± 0.65 | 1,000 ppm
NTP (2007) | Micronucleus induction | Males B6C3F_1_ mice 3-month inhalation exposure peripheral blood | 600 | 4.60 ± 0.45 | 1,000 ppm
NTP (2007) | Micronucleus induction | Males B6C3F_1_ mice 3-month inhalation exposure peripheral blood | 1,000 | 6.30 ± 1.02 | 1,000 ppm
NTP (2007) | Micronucleus induction | Males B6C3F_1_ mice 3-month inhalation exposure peripheral blood | Trend test | p = 0.346 | 1,000 ppm

*** p < 0.005 compared with chamber controls.

NCE = normochromatic erythrocytes; NR = none reported.

^a^ Mean ± standard error.

Table D-8 Genes Significantly Altered in Tumors with and without K-ras Mutations

Gene Class | Genes | K-ras Mutation
Gene Class | Genes | With | Without
Promote MAPK activation | Mif, Avpi, Map2K1, Ereg, Mapbpip, Klf5 | ↑ | nc
Activated by MAPK signaling | Ccnd1, Ptges, Areg | ↑ | nc
Inactivate MAPK signaling | Dusp14, Dusp3 | ↓ | nc
Inactivate MAPK signaling | Reck, Dusp1, Dusp4, Cav1, Loxl1 | ↓ | ↓
Anti-apoptosis | Clu | ↑ | ↑
Anti-apoptosis | Areg, Cks1b | ↑ | nc
Enhance tumor cell metastasis | Krt18, Krt8, Lasp1, Mif, MMP14, Tacstd1 | ↑ | nc
Increased tumor malignancy | Eno1, Gpr30, Srd5a1, Slc2a1 | ↑ | nc
Induce angiogenesis | Slc2a1, Gnb2l1, Ptges | ↑ | nc
Increased in metastatic tumors | Sdc1, Ccnd1 | ↑ | nc
Invasion inhibitors | Reck, Gsn, Lims2, Cav1, Gpx3 | ↓ | ↓
Tumor suppressors | Ptprd, Igsf4a, Fhl1, Pdzd2, Cdkn2d, Cdh5, Loxl1, Akap12 | ↓ | ↓
Tumor suppressors, cell motility and proliferation inhibitors | IGFBP4, Sod3, Rb1, Cebpd, Vwf, Dlc1 | ↓ | nc

Source: Wakamatsu et al. (2008).

nc = no change.

Table D-9 K-ras Mutation Spectra from Mouse Lung Tumors

Chemical | Tumors with Mutations/Total Tumors Examined | Mutation (%) | | Other Prominent Mutations (%)
Chemical | Tumors with Mutations/Total Tumors Examined | GC > TA (Codon 12) | AT > GC (Codon 61) | Other Prominent Mutations (%)
Cumene^a^ | 45/52 | 36 | 29 | GC > AT (13)
Ethyl carbamate (urethane) | 278/421 | 0 | 31 | AT > TA (64)
Vinyl carbamate | 58/71 | 8 | 42 | AT > TA (33)
Diethylnitrosamine (DEN) | 28/42 | 11 | 71 | GC > AT (18)
N-Ethyl-N-nitrosourea (ENU) | 11/11 | 0 | 64 | GC > AT (27)
N-Nitrosodimethylamine (NDMA) | 103/137 | 1 | 5 | GC > AT (94)
4-(N-nitrosomethylamino)-1-(3-pyridyl)-1-butanone (NNK) | 221/273 | 2 | 1 | GC > AT (96)
Cyclopenta[cd]pyrene | 20/27 | 40 | 0 | GC > CG (50)
Benz[j]aceanthrylene | 23/23 | 35 | 0 | GC > CG (65)
Benzo[b]fluoranthene | 25/29 | 92 | 0 | GC > CG (4) GC > AT (4)
Benzo[a]pyrene | 43/51 | 81 | 0 | GC > AT (19)
5-Methylchrysene | 44/49 | 73 | 0 | GC > CG (27)
1-Nitropyrene | 12/35 | 0 | 83 | GC > AT (17)
Spontaneous^b^ | 181/368 | 18 | 23 | GC > AT (28) AT > TA (19)
Spontaneous^a^ | 33/117 | 18 | 6 | GC > AT (42) AT > TA (12)

Sources: Hong et al. (2008), Jackson et al. (2006).

% = Number of tumors with a specific K-ras mutation/total number of tumors with K-ras mutations.

^a^ From Hong et al. (2008).

^b^ Genetic Alterations in Cancer Knowledge System (Accessed on July 6, 2012, available at: http://tools.niehs.nih.gov/gac/datamining/genetics/).