# Appendix B Human Exposure Tables and Regulations and Guidelines

## B.1 Human Exposure Tables

The six tables on the following pages contain data discussed in the “Properties and Human Exposure” section (Section 1) for the potential for environmental exposure (Section 1.4) and the characterization of exposure in the workplace (Section 1.6).

Data are reported for cumene for daily release rates (Table B-1), atmospheric concentration levels (Table B-2), residential indoor air concentration levels (Table B-3), water and sediment concentration levels (Table B-4), soil concentration measurement data (Table B-5), and work area monitoring samples in different occupational settings (Table B-6).

Table B-1 Cumene Daily Release Rate Estimates

Location Reference | Media | Source | Emission Rate (kg/day)
Los Angeles, CA (measured 2 days, 1987) (Harley and Cass 1994)^a^ | Air | All sources | 2,300
United States estimated value (US EPA 1988)^b^ | Air | All sources | [26,027^c^] (reported as 9,500 tonnes/yr)
European Union estimated value (EC 2001)^d^ | Air^e^ | Production and use | 17,903
European Union estimated value (EC 2001)^d^ | Air^e^ | Gasoline distribution | 3,211^f^
European Union estimated value (EC 2001)^d^ | Air^e^ | Motor exhaust | 20,298^g^
European Union estimated value (EC 2001)^d^ | Air^e^ | Total | 41,412
European Union estimated value (EC 2001)^d^ | Water^h^ | Production and use | 20,500
European Union estimated value (EC 2001)^d^ | Soil^i^ | Production and use | 273
European Union reported value (EC 2001)^d^ | Air 1993 | Production | [342^c^] (reported as 125 tonnes/yr)
European Union reported value (EC 2001)^d^ | 1995 | Production | [205^c^] (reported as 75 tonnes/yr)

Sources: EC (2001); HSDB (2005); IARC (2012); WHO (1999) (Note: IARC (2012) also reported data from the other 3 sources).

^a^ As cited by HSDB (2005).

^b^ As cited by WHO (1999).

^c^ Based on division by 365 days per year; estimated daily rates would be higher if production processes are assumed to occur on fewer (e.g., 300) days per year.

^d^ As cited by EC (2001).

^e^ Assumes maximum production per site of 500,000 tonnes (4,100,000 tonnes/year for entire European Union) and a release factor of 1.31 kg/tonne (see Section 1.4.1).

^f^ Assumes cumene as 0.2% of hydrocarbon loss, VOC emission factor of 5 kg/tonne delivered, and 117,205,000 tonnes/yr of gasoline for the entire European Union.

^g^ Assumes 0.2% cumene in motor vehicle exhaust, emission of 617,400 tonnes VOC/yr in the United Kingdom, and a population ratio of 6 to extrapolate to the entire European Union.

^h^ Assumes maximum production per site of 500,000 tonnes and a release factor of 1.5 kg/tonne (see Section 1.5.1).

^i^ Assumes maximum production per site of 500,000 tonnes and a release factor of 0.02 kg/tonne (see Section 1.5.1).

Table B-2 Cumene Atmospheric Concentration Levels

Country | Location/Sample | Mean Concentration^a^, µg/m^3^, ppm | Concentration Range^a^, µg/m^3^, ppm | References
Industrial Settings
United States | Deer Park, TX (near Shell Oil Refinery) | – | 29.4 (downwind) [0.006] and 53.9 (upwind) [0.01] | Oldham et al. (1979) ^b^
Sweden | Near factory | – | 4.5 [0.0009] | Petersson et al. (1982) ^c^
Spain | Field storage area for creosote-treated wood near Sant Martí de Torroella and Sant Joan de Vilatorrada | – | 2,440 (day 1 of residence in storage field) – 275 (day 8 of residence in storage field) [0.5–0.06] | Gallego et al. (2008)
United Kingdom | Gatwick airport–ambient air | – | 1.6–12 [0.0003–0.002] | Tsani-Bazaca et al. (1982) ^c^
Not reported | Electronics factory fire | [340] (reported as 0.07 ppm) | [2–2,700] (reported as 0.0004 to 0.55 ppm) | Austin et al. (2001a)
Urban Settings
United States | Urban overall | 14.7 [0.003] | – | WHO (1999) ^d^
United States | Boston, MA | – | 0.1 [0.00002] | US EPA (1986) ^c^
United States | Chicago, IL | – | 0.59–1.1 [0.0001–0.0002] | US EPA (1986) ^c^
United States | Houston, TX (21 samples, 88% positive) | 12.15 [0.002] | None detected–24.89 [None detected–0.005] | US EPA (1979) ^bd^
United States | Houston, TX (urban and industrial areas) | – | 0–42.2 [0–0.009] | US EPA (1979) ^c^
United States | Houston, TX, 1973–1974 | – | 0.14–0.81 [0.00003–0.0002] | US EPA (1986) ^c^
United States | Los Angeles, CA (10 samples, 80% positive) | 16.7 [0.003] | <2.45–36 [<0.0005–0.007] | US EPA (1987) ^bd^
United States | Los Angeles, CA, 1966 (136 samples, 100% positive) | 14.7 (144 max) [0.003 (0.03 max)] | – | Lonneman et al. (1968) ^bd^
United States | Los Angeles, CA, 1981 (17 samples, 94% positive) | – | None detected–9.8 [None detected–0.002] | Grosjean and Fung (1984) ^bd^
United States | Miami, FL (urban air) | – | 1.11–2.59 [0.0002–0.0005] | Lonneman et al. (1978) ^c^
United States | St. Petersburg, FL (urban air) | – | 0.83–1.29 [0.0002–0.0003] | Lonneman et al. (1978) ^c^
Belgium | Antwerp Belgium Craeybeckx tunnel – normal traffic conditions, 1991 | 0.003 g/kg carbon^e^ | – | De Fré et al. (1994) ^b^
Belgium | Antwerp Belgium Craeybeckx tunnel – congested traffic conditions, 1991 | 0.009 g/kg carbon^e^ | – | De Fré et al. (1994) ^b^
Brazil | Porte Alegre, 1996–1997 | [900] (reported as 0.9 mg/m^3^) | – | Grosjean et al. (1998) ^b^
China | Taiwan urban air – away from heavy traffic | – | 0.5 [0.0001] | Hung and Liao (1991) ^c^
China | Taiwan urban air – near heavy traffic | – | 0.6–0.9 [0.0001–0.0002] | Hung and Liao (1991) ^c^
France | Grenoble area, 1987 | 1.6 [0.0003] | 0.9–7.45 [0.0002–0.002] | Foster et al. (1991) ^cd^
Germany | Hamburg – Major road tunnel | – | 3–3.8 [0.0006–0.0008] | Dannecker et al. (1990) ^c^
Germany | Urban air | – | 6–9 [0.001–0.002] | Bouscaren et al. (1986) ^c^
Italy | Milan – urban air | – | 1.1–1.8 [0.0002–0.0004] | EC (2001)^c^
Italy | Rome – urban air | – | 1.1 [0.0002] | EC (2001) ^c^
Netherlands | Delft ambient air | – | <0.49–1.96 [<0.0001–0.0004] | Bos et al. (1977) ^c^
Netherlands | Rotterdam and Ede – near homes | – | 0.3 [0.00006] | Lebret et al. (1986) ^c^
Netherlands | Urban air | – | 0.3 [0.00006] | Bouscaren et al. (1986)^c^
Sweden | Göteborg | – | 0.6 [0.0001] | Petersson et al. (1982) ^c^
United Kingdom | London – urban air | – | 5 [0.001] | Tsani-Bazaca et al. (1982) ^c^
United Kingdom | Southampton estuary – ambient air | – | 0.6–410 [0.0001–0.08] | EC (2001) ^c^
United Kingdom | Urban air | – | 1–20 [0.0002–0.004] | Bouscaren et al. (1986) ^c^
Former USSR | Leningrad – urban air, 1977–1979 | 8.3 [0.002] | 0.98–11.76 [0.0002–0.002] | Isidorov et al. (1983) ^cd^
Rural Settings
United States | Rural overall | 2.5 [0.0005] | – | WHO (1999) ^d^
United States | Great Smoky Mountains, TN | – | 0.28–0.65 [0.00006–0.0001] | Arnts and Meeks (1981) ^c^
United States | Jones State Forest, TX, near Houston (15 samples, 100% positive) | 2.45 [0.0005] | 0.108–9.8 [0.00002–0.002] | Seila (1979) ^bd^
United States | Lake Michigan, 1,000–3,000 feet above (2 samples, 100% positive) | 0.49 [0.0001] | – | Miller and Alkezweeny (1980) ^b^
United States | Missoula, MT, 2004–2005 (35 samples) | <0.04 (median) [0.000008] | <0.04–0.1 [<0.000008–0.00002] | Ward et al. (2009)
United States | Missoula, MT, 2005–2006 (51 samples) | <0.04^f^ (median) [0.000008] | <0.04^f^–0.3 [<0.000008–0.00006] | Ward et al. (2009)
United States | Rio Blanco County, CO | – | 1.57 [0.0003] | Arnts and Meeks (1981) ^c^
United States | Smoky Mountains National Park, TN, near campfires (9 samples, 44% positive) | 0.245 [0.00005] | <0.049–0.392 [<0.00001–0.00008] | Arnts and Meeks (1980) ^b^
Nepal | Mount Everest | – | 0.07 [0.00001] | EC (2001) ^c^
Netherlands | Rural air | – | 0–5 [0–0.001] | Bouscaren et al. (1986) ^c^
Sweden | Rural sample | – | 0.02 [0.000004] | Petersson et al. (1982)^c^
Netherlands | Ambient air | – | 0.49–34.79 [0.0001–0.007] | Guicherit and Schulting (1985) ^c^

Sources: EC (2001); HSDB (2005); IARC (2012); WHO (1999) (Note: IARC 2012 reported data from the other 3 sources).

^a^ Values in brackets ([ ]) were converted from µg/m^3^ to ppm or vice versa using the conversion factors in Table 1-2.

^b^ As cited by HSDB (2005).

^c^ As cited by EC (2001).

^d^ As cited by WHO (1999).

^e^ Cumene concentration in relation to the total amount of carbon-based pollutants.

^f^ Reported as ng/m^3^; however, the correct units are µg/m^3^ (T.J. Ward, personal communication to Sanford Garner, ILS, Inc., June 15, 2012).

Table B-3 Cumene Residential Indoor Air Concentration Levels

Country | Location/Sample | Report | Mean Concentration^a^, µg/m^3^, ppm | Concentration Range^a^, µg/m^3^, ppm
United States | Missoula, MT, 2004–2005 (35 samples) | Ward et al. (2009) | 0.1 (median) [0.00002] | <0.04–1.7 [0.000008–0.0004]
United States | Missoula, MT, 2005–2006 (51 samples) | Ward et al. (2009) | <0.04^b^ (median) [<0.000008] | <0.04–2.4^b^ [0.000008–0.0005]
Canada | Quebec City (96 samples, 95 above detection limit^c^) | Héroux et al. (2008) | 0.88 (geometric mean) [0.0002] | 0.10–45.48 [0.00002–0.009]

^a^ Values in brackets were converted to ppm using the conversion factor in Table 1-2.

^b^ Reported as ng/m^3^; however, the correct units are µg/m^3^ (T.J. Ward, personal communication to Sanford Garner, ILS, Inc., June 15, 2012).

^c^ Detection limit = 0.2 µg/m^3^. For concentrations < detection limit, 0.1 µg/m^3^ was used for calculations.

Table B-4 Cumene Water and Sediment Concentration Levels

Country or Industrial Site | Location/Sample | Mean Concentration, µg/L (for Water), µg/kg (for Sediment) | Concentration Range, µg/L (for Water), µg/kg (for Sediment) | References
Drinking Water
United States | Drinking water – Terrebonne-Parish, Louisiana | – | 0.01 | Keith et al. (1976) ^a^
United States | Drinking water – 9 other cities | – | Not detected | Keith et al. (1976) ^a^
United States | Drinking water – Cincinnati, OH | – | 0.014 | Coleman et al. (1984) ^ab^
United States | Drinking water – 945 U.S. systems | – | Not detected (detection limit = 0.5) | Westrick et al. (1984) ^a^
United States | Drinking water – New York State | – | Detected but not quantified | Burmaster (1982) ^ab^
Japan | Tap water | – | Detected but not quantified | Shiraishi et al. (1985) ^b^
Groundwater
United States | Groundwater – 50 states and Puerto Rico | – | <0.5 | Westrick et al. (1984) ^b^
United States | Groundwater – Ames, Iowa | – | Detected but not quantified | Burnham et al. (1972) ^b^
United States | Groundwater – New York State | – | Detected but not quantified | Burmaster (1982) ^b^
United States | Groundwater – Wyoming (underground coal gasification plants) | – | 19–54 | Stuermer et al. (1982) ^c^
United States | Groundwater – Hoe Creek, WV (underground coal gasification plants) (3 samples) | 35 | 19–59 | Stuermer et al. (1982) ^b^
Australia | Groundwater – Melbourne (near a dump site) | – | Detected but not quantified | Stepan et al. (1981) ^b^
Denmark | Fredericia, groundwater contaminated with creosote and/or gasoline (5 samples) | – | None detected–3 | Johansen et al. (1997) ^b^
Denmark | Holte, groundwater from shallow sandy aquifer contaminated with creosote and/or gasoline (3 samples) | – | 2–22 | Johansen et al. (1997) ^b^
Italy | Groundwater (underground solvent storage tanks near chemical plants) | – | 1,581 | Botta et al. (1984) ^ac^
United Kingdom | Groundwater – East Anglia (near an airfield) | – | 1–30 | Tester and Harker (1981) ^c^
United Kingdom | Groundwater - Great Ouse Basin, near a gasoline storage tank (5 samples) | 9.8 | 0.01–30 | Tester and Harker (1981) ^b^
Unspecified country | Groundwater (near chemical plants) | 11 | – | Pellizzari et al. (1979) ^a^
Unspecified country | Groundwater | 360 | – | Teplý and Dressler (1980) ^a^
Unspecified country | Groundwater (petroleum plants and refineries) | 5 | – | Snider and Manning (1982) ^a^
Surface Water
United States | Surface water – Narraganset Bay, RI | – | Detected but not quantified | Wakeham et al. (1983) ^b^
United States | Surface water–River Brazos, Texas | – | 0.006–0.017 | McDonald et al. (1988) ^c^
Germany | Surface water – Lake Constance | – | 0.006–0.028 | Jüttner (1988) ^c^
Germany | Surface water – River Rhine | – | 0.028 | European Commission (2001) ^c^
Japan | Surface water | – | 0.09–0.44 | Japan Environment Agency (1987) ^a^
Spain | Surface water – River Gallego | – | [<0.000001] (reported as <0.001 ng/L) | European Commission (2001) ^c^
United Kingdom | Surface water – British North Sea | – | 0.001–0.069 | Hurford et al. (1990; 1989)^c^
United Kingdom | Surface water – River Lee (2 samples) | – | <0.1 and >0.1 | Waggot et al. (1981) ^b^
United Kingdom | Solent estuary | – | 0.01–47.3 | European Commission (2001)^c^
Sediment and Biota
United States | Sediments and biota – Puget Sound, WA | [2,300] (reported as 2.3 µg/g) | [20–19,000] (reported as 0.02–19 µg/g) | Brown et al. (1979)^a^
United States | Sediment – Strait of Juan de Fuca, WA^d^ | – | [20–5,500] (reported as 0.02–5.5 µg/g) | Brown et al. (1979) ^bc^
United States | Sediment – Puget Sound, WA | – | Detected but not quantified | Malins et al. (1984) ^b^
Japan | Sediment – near potential emission source (6 of 11 samples) | – | 0.58–11 (detection limit = 0.5 ng/g) | Japan Environment Agency (1987) ^a^
United Kingdom | Sediment - Southampton | – | 0.25–43.37 | Bianchi et al. (1991) ^c^
Wastewater
Germany | Wastewater | – | 0.5–5 | European Commission (2001) ^c^
Sweden | Wastewater – Göteborg | – | 0.1–0.8 | European Commission (2001)^c^
Other Levels in Water
Around outboard motor operations | – | – | 700 | Montz et al. (1982) ^a^
Near offshore drilling platform | Sea water – Gulf of Mexico | – | 140 | Sauer (1981) ^a^
Snow
Antarctica | Snow – 1987/88 expedition (8 surface snow samples) | [0.008] (reported as 8 ng/L) | – | Desideri et al. (1994) ^b^
Antarctica | Snow – 1988/89 expedition (8 surface snow samples) | [0.016] (reported as 16 ng/L) | – | Desideri et al. (1994) ^b^
Antarctica | Snow – 1990/91 expedition (8 surface snow and 6 deep snow samples) | Not detected | – | Desideri et al. (1994) ^b^

Sources: EC (2001); HSDB (2005); IARC (2012); WHO (1999) (Note: IARC (2012) reported data from the other 3 sources).

^a^ As cited by WHO (1999).

^b^ As cited by HSDB (2005).

^c^ As cited by EC (2001).

^d^ Incorrectly reported as Alaska in EC (2001).

Table B-5 Cumene Soil Concentration Measurement Data

Country or Industrial Site | Location/Sample | Report | Mean Concentration, µg/kg | Concentration Range, µg/kg
Germany | Soil – beneath a building | Bachhausen (1990) ^a^ | – | [24,000] (reported as 24 mg/kg)
Netherlands | Soil – contaminated sites | European Commission (2001) ^b^ | – | 12–20
Not reported | Soil – garage spills | Kliest et al. (1989) ^b^ | – | [10,000–305,000] (reported as 10 to 305 mg/kg)

Sources: EC (2001); HSDB (2005); IARC (2012) (Note: IARC (2012) reported data from the other 2 sources).

^a^ As cited by HSDB (2005).

^b^ As cited by EC (2001).

Table B-6 Work Area Monitoring Samples (Measured Levels) for Cumene in Different Occupational Settings

Occupational Setting | Number of Samples | Mean Concentration, ppm [µg/m^3^] | Concentration Range, ppm [µg/m^3^] | References
8-hour Time Weighted Average (TWA)
Manufacture – all job categories | 7 European companies | 0.1–0.65 (range of means from individual companies) [490–3,200] | 0.05–4.46 [250–22,000] | European Commission (2001) ^a^
Cumene production plant – specific jobs: runner, filling station attendant, laboratory co-worker, chemical technology co-worker | Personal air samples | – | <1 [<4,900] | European Commission (2001) ^a^
Manufacture – long-term exposure, 1991 | 40 to 50 samples (8-h TWA) | – | <0.1 [<490] | European Commission (2001) ^a^
Offset printing works | 17 person-related measurements | – | 0.1–1.3 [490–6,400] | European Commission (2001) ^a^
Printing of signs using lacquering machines | 2 person-related measurements | – | 0.2 [980] | European Commission (2001)^a^
Maintenance painters – 23 different job locations | 45 person-related measurements | – | 0–0.81 [0–4,000] | Scheffers (1985) ^a^
Short-Term (10–20 minute or 20–30 minute) Exposure Data
Car repair work (manual compressed air-spray guns in spray booths) | 8 person-related measurements | – | 1.9–6.7 [9,300–33,000] | European Commission (2001) ^a^
Rubber Manufacturing Processes
Shoe sole factory, vulcanization area | 13 samples | – | 0.012–0.05 [59–250] | Cocheo et al. (1983) ^a^
Tire retreading factory, vulcanization area | 6 samples | – | 0.0004–0.04 [2–200] | Cocheo et al. (1983) ^a^
Tire retreading factory, extrusion area | 6 samples | – | 0–0.002 [0–10] | Cocheo et al. (1983) ^a^
Electrical cable insulation plant, extrusion area | 10 samples | – | Not detected | Cocheo et al. (1983) ^a^
1-Hour Exposure Duration–90% Value
Production of paints | 125 samples | – | 0.8 [3,900] | European Commission (2001)^a^ (1991–1995, Germany)
Surface treatment, manual (painting, paint rolling) | 255 samples | – | 3.4 [17,000] | European Commission (2001)^a^ (1991–1995, Germany)
Surface treatment, manual (spraying) | 300 samples | – | 1.01 [5,000] | European Commission (2001)^a^ (1991–1995, Germany)
Surface treatment, mechanical | 84 samples | – | 0.8 [3,900] | European Commission (2001)^a^ (1991–1995, Germany)
Other Monitoring Data
Cumene Production and Processing
Distillation | Not reported | 0.45 [2,200] | 0.0001–3.35 [0.49–16,000] | Chemical Manufacturers Association (1985) ^b^
Oxidation | Not reported | 0.93 [4,600] | 0.0001–5.58 [0.49–27,000] | Chemical Manufacturers Association (1985) ^b^
Laboratory | Not reported | 0.39 [1,900] | 0.34–0.44 [1,700–2,200] | Chemical Manufacturers Association (1985) ^b^
Repair | Not reported | 1.33 [6,500] | 0.16–2.50 [790–12,000] | Chemical Manufacturers Association (1985) ^b^
Recovery | Not reported | 0.31 [1,500] | 0.001–1.20 [4.9–5,900] | Chemical Manufacturers Association (1985) ^b^
Cumene unit | Not reported | 0.19 [930] | 0.078–0.620 [380–3,000] | Chemical Manufacturers Association (1985) ^b^
Cumene Exposed Workers, 1973–1984 | 1,487 air samples | | | Chemical Manufacturers Association (1985) ^c^
Cumene Exposed Workers, 1973–1984 | 6 samples | – | 4–30 [20,000–150,000] | Chemical Manufacturers Association (1985) ^c^
Cumene Exposed Workers, 1973–1984 | 4 samples | – | 3–4 [15,000–20,000] | Chemical Manufacturers Association (1985) ^c^
Cumene Exposed Workers, 1973–1984 | 25 samples | – | 1–2 [4,900–9,800] | Chemical Manufacturers Association (1985) ^c^
Cumene Exposed Workers, 1973–1984 | Remaining samples | – | <1 [<4,900] | Chemical Manufacturers Association (1985) ^c^
Exposure from solvents, United Kingdom | Not reported | – | Up to 0.6 [2,900] | European Commission (2001) ^a^
Gasoline delivery truck drivers | Not reported | – | <0.01–0.04 [<49–197] | American Petroleum Institute (1984) ^b^

Sources: EC (2001); HSDB (2005); IARC (2012); WHO (1999) (Note: IARC (2012) reported data from the other 3 sources).

^a^ As cited by EC (2001).

^b^ As cited by HSDB (2005).

^c^ As cited by WHO (1999) for an industrial survey submitted to US EPA.

## B.2 Regulations and Guidelines

Table B-7 Existing Standards and Guidelines for Cumene (ppm)

Type of Guideline | Duration of Exposure
Type of Guideline | 10 Minutes | 30 Minutes | 1 Hour | 4 Hours | 8 Hours
AEGL-1 (non-disabling) | 50 | 50 | 50 | 50 | 50
AEGL-2 (disabling) | 550 | 380 | 300 | 190 | 130
AEGL-3 (lethal) | 1,300 | 920 | 730 | 460 | 300
Permissible Exposure Limits – Time Weighted Average (OSHA) | – | – | – | – | 50 (skin)^a^
Recommended Exposure Limits – Time Weighted Average (NIOSH) | – | – | – | – | 50 (skin)^a^
Immediately Dangerous to Life and Health (NIOSH) | – | 900 | – | – | –
Threshold Limit Value –Time Weighted Average (ACGIH) | – | – | – | – | 50

Source: NAC-AEGL (2007).

AEGL = Acute Exposure Guideline Level.

^a^ The (skin) designation indicates the potential for dermal absorption; skin exposure should be prevented as necessary through the use of substitution, engineering controls, good work practices, gloves, coveralls, goggles, and other appropriate equipment. This designation is separate from the Permissible Exposure Limit or Recommended Exposure Limit values shown and is not associated with inhalation exposure limits.

The regulations listed below do not contain specific exposure limits for cumene, but their application has the potential to reduce exposure to cumene.

### B.2.1 U.S. EPA

#### B.2.1.1 Clean Air Act

Standards of Performance for Equipment Leaks of Volatile Organic Compounds (VOC) in the Synthetic Organic Chemical Manufacturing Industry (SOCMI):

Requires all newly constructed, modified, and reconstructed SOCMI process units to use the best demonstrated system of continuous emission reduction for equipment leaks of VOC.

#### B.2.1.2 National Emission Standards for Hazardous Air Pollutants:

Requires major and area sources to sharply reduce routine emissions of toxic air pollutants in accordance with specific performance-based standards for all air emission sources that emit one or more of the listed pollutants. Cumene is listed as a hazardous air pollutant.

#### B.2.1.3 Comprehensive Environmental Response, Compensation, and Liability Act

Reportable quantity (RQ) = 5,000 lb.

#### B.2.1.4 Regional Screening Levels (Formerly Called Preliminary Remediation Goals):

Screening levels for cumene are as follows: Residential soil = 2,100 mg/kg; Industrial soil = 11,000 mg/kg; Residential air = 420 µg/m^3^ [0.09 ppm]; Industrial air = 1,800 µg/m^3^ [0.4 ppm]; Tap water = 390 µg/L.

#### B.2.1.5 Resource Conservation and Recovery Act

When cumene becomes a waste, it must be managed according to Federal and/or State hazardous waste regulations. Listed hazardous waste code = U055.

### B.2.2 U.S. Food and Drug Administration

In the Federal Register of February 23, 2012 (FDA 2012), FDA finalized a recommendation to revise the safety classification of cumene in the guidance for the pharmaceutical industry entitled “Q3C Impurities: Residual Solvents.” FDA recommended that cumene be moved from listing as a Class 3 solvent (i.e., a solvent with low toxicity) to a Class 2 solvent with a permitted daily exposure (PDE) of 0.7 mg/day and a concentration limit of 70 ppm.