# Appendix A Literature Search Strategy

This document identifies the data sources, search terms, and search strategies that were used to identify literature for the monograph on cumene (CASRN 98-82-8). The literature search strategy used for cumene involved several approaches designed to identify potentially useful information for the broad range of topics covered by a Report on Carcinogens (RoC) monograph, as listed below.

- Properties and Human Exposure (focusing on the U.S. population)
- Disposition (ADME) and Toxicokinetics
- Human Cancer Studies (if available)
- Studies of Cancer in Experimental Animals
- Mechanisms and Other Relevant Effects
  - Genotoxicity
  - Toxicity as It Relates to Mechanisms
  - Mechanisms of Carcinogenicity

The methods for identifying the relevant literature for the cumene monograph including (1) the search strategy, (2) updating the literature search, and (3) review of citations using web-based systematic review software are illustrated in Figure A-1 and discussed below.

Figure A-1

Literature Search Strategy and Review

## A.1 Search Strategies

Relevant literature is identified using search terms, data sources, and strategies as discussed below.

1. General data search: This search covers a broad range of general data sources (see Table A-1) for information relevant to many or all of the wide range of monograph topics pertaining to cumene.
2. Exposure-related data search: This search covers a broad range of potential sources (see Table A-2) for exposure-related information and physical-chemical properties.
3. Database searches in PubMed, Scopus, and Web of Science: The majority of the primary literature used to draft the cumene monograph was identified from searches of these three extensive databases available through the NIEHS Library. Synonyms, metabolites, and the chemical class for cumene were identified from the sources listed in Table A-3 and the search terms are listed in Table A-4. Information on metabolites and structurally related chemicals may be important for evaluating potential mechanisms of carcinogenicity. These searches were combined with the search terms listed in Table A-4 for each of the monograph topics listed above to create the specific literature searches in Table A-5. See Table A-4 for details on this approach and Table A-5 for topic-specific search terms.
4. Searches for human cancer studies are somewhat unique because they involve the identification of search terms for exposure scenarios that might result in exposure of people to cumene. For cumene, these exposure-related search terms were based on its use in the manufacture of acetone and phenol, and those search terms were combined with search terms specific for human cancer
5. QUOSA library of occupational case-control studies search of the QUOSA-based library of approximately 6,000 occupational case-control studies, approximately 60% of which are currently available as searchable full-text pdfs, was conducted using the synonyms “cumene,” “isopropylbenzene,” and the CASRN number (98-82-8).
6. Special topic-focused searches: The two specific topics for which additional searches were conducted for cumene are listed below and described in Table A-3.
  - α_2u_-Globulin-associated renal nephropathy
  - Role of genotoxic mechanisms in K-ras mutations in mouse lung tumors
7. Secondary sources: Citations identified from authoritative reviews or from primary references located by literature search, together with publications citing key papers identified using the Web of Science “Cited Reference Search,” were also added.

## A.2 Updating the Literature Search

The literature search was updated prior to submitting the draft monograph for peer review and prior to finalizing the monograph. Monthly search alerts for cumene synonyms, metabolites, chemical class, exposure scenarios (human cancer), and topic-focused searches were created in PubMed, Scopus, and Web of Science, and the results of these searches from the closing date of the initial search were downloaded for review.

## A.3 Review of Citations Using Web-based Systematic Review Software

Citations retrieved from literature searches were uploaded to web-based systematic review software and screened using inclusion and exclusion criteria. Multi-level reviews of the literature were conducted, with initial reviews (Level 1) based on titles and abstracts only to identify citations that could be excluded and to assign the included literature to one or more monograph topics; subsequent reviews (Level 2) for literature assigned to the various monograph topics (Exposure, ADME & TK, Human cancer studies, etc.) were based on full-text (i.e., PDFs) of the papers and were carried out by the writer and scientific reviewer for each monograph section. Two reviewers, at least one of whom is a member of the ORoC at NIEHS, participated at each level of review.

The questions based on inclusion/exclusion criteria for Levels 1 and 2 are listed below.

Inclusion/Exclusion Questions for Literature

Level 1:

1. Is this paper relevant or possibly relevant for any section(s) of the monograph? Check all that apply.
  - Properties and Human Exposure
  - Toxicokinetics (also includes ADME, i.e., absorption, distribution, metabolism, and excretion)
  - Human Cancer Studies
  - Studies of Cancer in Experimental Animals
  - Mechanisms- Genetic Toxicology
  - Mechanisms- Toxicity
  - Mechanisms of Carcinogenicity
2. If this paper contains potentially relevant information, what type of paper is it?
  - Primary research report
  - Review article
  - Meta-analysis
  - Other
3. If this paper is not useful, check all the reasons that apply.
  - It does not contain relevant information on the candidate substance or any related substance (metabolite or structural analogues).
  - It is related to the candidate substance but does not contain information relevant to any topic covered by the monograph.
  - It is an abstract or proceedings report.
  - It is not peer reviewed.

Note: In the context of the systematic review of literature used for cumene, “relevant information” as it applies to primary screening can include any of the following:

- The article specifically mentions cumene, a metabolite, or structural analogue and reports information on one of the topics included in a cancer hazard evaluation (see Question #1 above for a list of topics)
- The article does not specifically mention the cumene or any related substance, but it does one of the following:
  - It reports information on one of the topics included in a cancer hazard evaluation with potential for exposure to cumene and should be included until full-text review, which would provide more information if the study is specific for exposure to cumene or a related substance.
  - It reports information on an exposure scenario that could include exposure to cumene.
  - It reports information on methodology that is potentially informative for evaluating cancer or mechanistic studies on exposure to cumene.
  - It reports information on a potential mode of action that may be informative for cumene.

Level 2:

Exposure

1. Does this paper contain information that is useful for the Exposure section? If “Yes” we will obtain a pdf if one is not already available.
  - Yes
  - No

Note: In the context of the systematic review of literature used for cumene, “useful information” as it applies to screening for the exposure section can include information, from either primary research papers, review articles, databases, or other published sources, on any of the following topics: occupational exposure, environmental occurrence, occurrence in consumer products, food, cigarette smoke, or other sources, biological indices of exposure, and Federal regulations or guidelines to reduce exposure.

Toxicokinetics (including Absorption, Distribution, Metabolism, and Excretion)

1. Does this paper contain information that is useful for the Toxicokinetics section? If “Yes” we will obtain a pdf if one is not already available.
  - Yes
  - No

Note: In the context of the systematic review of literature used for cumene, “useful information” as it applies to screening for the toxicokinetics (and ADME) section can include (but is not limited to) information from primary research papers or review articles on any of the following topics: absorption, distribution, metabolism, excretion (ADME), toxicokinetics, and physiologically based pharmacokinetic models (PBPK).

Human Cancer

1. Does this paper contain information that is useful for the human cancer section? If “Yes” we will obtain a pdf if one is not already available.
  - Yes
  - No

Note: In the context of the systematic review of literature used for cumene, “useful information” as it applies to screening for the human cancer section can include, but is not limited to, epidemiologic studies, descriptive studies, pooled analyses, meta-analyses, case reports, reviews, letters to editors, exposure-assessment studies (for use in epidemiologic studies) and information on co-exposures or potential confounders and other special topics of relevance to the evaluation.

Animal Tumors

1. Does this paper contain information that is useful for the animal tumor section? If “Yes” we will obtain a pdf if one is not already available.
  - Yes
  - No

Note: In the context of the systematic review of literature used for cumene, “useful information” as it applies to screening for the animal tumors section can include, but is not limited to, information from primary research papers or review articles on (1) chronic studies (ideally for lifetime of the animal) in experimental animals that are assessing neoplastic endpoints, non-cancer data important for cancer assessment, such as preneoplastic lesions that are considered part of a morphologic continuum to neoplasia, or (2) subchronic studies in experimental animals that provide information on preneoplastic lesions, neoplastic lesions, or on dose setting for chronic studies.

Genetic Toxicology

1. Does this paper contain information that is useful for the genetic toxicology section? If “Yes” we will obtain a pdf if one is not already available.
  - Yes
  - No

Note: In the context of the systematic review of literature used for cumene, “useful information” as it applies to screening for the genetic toxicology section can include information from primary research papers or review articles on studies in experimental systems (both in vitro and in vivo) and in exposed humans assessing the following endpoints: both direct and indirect DNA or chromosomal damage, events associated with mutagenesis, cellular transformation, or other related effects.

Toxicity

1. Does this paper contain information that is useful for the toxicology (toxicity) section? If “Yes” we will obtain a pdf if one is not already available.
  - Yes
  - No

Note: In the context of the systematic review of literature used for cumene, “useful information” as it applies to screening for the toxicity section can include any of the following: information from primary research papers or review articles on toxicity of cumene to organs or tissues that were identified as tumor sites from studies in experimental animals.

Mechanism Data

1. Does this paper contain information that is useful for the mechanism data section? If “Yes” we will obtain a pdf if one is not already available.
  - Yes
  - No

Note: In the context of the systematic review of literature used for cumene, “useful information” as it applies to screening for the mechanism data section can include information from primary research papers or review articles on data related to molecular alterations associated with carcinogenicity or potential modes of action, such as genotoxicity, epigenetics, gene expression, immune-response modulation, inflammation, cytotoxicity and compensatory cell proliferation, mitogenicity, chronic metabolic or physiologic overload, nutrient deficiency, and interference with intercellular communication, for cumene, its metabolites and analogues.

Table A-1 General Sources Checklist for: Cumene

Source | Name of Document
A) Comprehensive Sources or Reviews
1) NTP technical reports | NTP 2009
2) NTP nomination for toxicological evaluation documents | NTP 1996
3) IARC monographs | –
4) ATSDR Toxicological Profiles | –
5) EPA IRIS | EPA 1997
6) NAS Reports and Publications | –
7) WHO (IPCS) INCHEM-related documents (a-k below)
a) CICADS | WHO 1999
b) EHC | –
c) HSGs | –
d) IPCSs | IPCS 2004
e) JECFA | –
f) JMPR | –
g) KemI-Riskline | –
h) PDs | –
i) PIMS | –
j) SIDS | –
k) UKPID | –
8) California EPA Prop 65 hazard identification documents | CAEPA 2010
10) New York State Department of Health- Health Topics A to Z | –
B) General Information Sources
1) U.S. National Library of Medicine (NLM)- TOXNET
a) HSDB | HSDB 2005
b) CCRIS | CCRIS 2011
c) GENETOX | GeneTox 1991
d) ITER | ITER 2012
e) LactMed | –
f) CPD | –
g) CTD | CTD 2012
2) PubChem | PubChem 2012
3) Kirk-Othmer Encyclopedia | Hwang and Chen 2010
4) USGS (Minerals) | –
C) European Union – Sources to Search
1) International Uniform Chemical Information Database (IUCLID) | IUCLID 2000
2) European Chemicals Agency | ECHA 2011 UKCA 2008
3) The International Portal on Food Safety, Animal and Plant Health (IPFSAPH) | –
4) The European Food Safety Authority | –
5) European Centre for Disease Prevention and Control (ECDC) | –
6) European Monitoring Centre for Drugs and Drug Addiction | –

Table A-2 Exposure-related Sources Checklist for: Cumene

Source | Name of Document
Exposure- and Properties-Specific Sources
1) U.S. National Library of Medicine (NLM)- TOXNET
a) ChemIDplus | ChemIDplus 2012
b) Haz-Map | Haz-Map 2012
c) HPDB | HPDP 2012
d) TOXMAP | TOXMAP 2012
2) Akron database | Akron 2010
3) SRI Directory of Chemical Producers | SRI 2011
4) Chem Sources Suppliers | ChemSources 2011
5) National Health and Nutrition Examination Survey (NHANES) data studies | NHANES 2010
6) National Occupational Exposure Survey (NOES) (1981-1983) | NIOSH 1990
7) National Institute for Occupational Safety and Health (NIOSH) – Health Hazard Evaluations | Burton and McCullough 2002
8) National Response Center (NRC) Database | NRC 2012
9) U.S. International Trade Commission (USITC)- Import/Export data | USITC 2011
10) EPA Toxics Release Inventory (TRI) | TRI 2012
11) EPA AP-42, Compilation of Air Pollutant Emission Factors | –
12) EPA Enforcement and Compliance History Online (ECHO) Database | –
13) EPA EJView Database | EPA 2012
14) EPA HPV Challenge Program Chemical List | –
15) EPA Inventory Update Rule (IUR) | EPA 2011a
16) EPA Locating and Estimating (L&E) documents | –
17) EPA/Office of Pesticide Programs (OPP) Chemical Ingredients Database | –
18) Food and Drug Administration (FDA) Pesticide Monitoring Database | –
19) FDA Orange Book | –
20) FDA Total Diet Study | FDA 2005 FDA 2006
21) Medline Plus | –
22) United States Patent Office | USPTO 2012
23) Trademark Electronic Search System (TESS) | TESS 2012
24) Material Safety Data Sheets (MSDS) | Citgo 2005 MSDSXchange 2012
25) Dow Chemical Product Safety Assessments | –

Table A-3 Data Sources for Cumene Searches

Information Type | Data Sources
Synonyms | National Library of Medicine databases (e.g., ChemIDplus, Hazardous Substances Data Base)
Metabolites | Robinson et al. (1955), Bakke and Scheline (1970), Ishida and Matsumoto (1992), Henne et al. (2001)
α_2u_-Globulin-associated renal nephropathy | IARC Scientific Publications No. 147, Species Differences in Thyroid, Kidney and Urinary Bladder Carcinogenesis (IARC 1999) U.S. EPA, Alpha_2u_-Globulin-Associated Renal Nephropathy with Chemically Induced Renal Toxicity and Neoplasia in the Male Rat. Prepared for the Risk Assessment Forum. EPA/625/3-91/019F, Washington, DC, September (US EPA 1991b)
K-ras mutations in mouse lung tumors | Additional publications were identified from literature cited in the NTP (2009) technical report and in other publications (e.g., Hong et al. (2008), Wakamatsu et al. (2008), Hoenerhoff et al. (2009)) identified from the search for information on potential mechanisms of carcinogenicity. Information and additional publications were also obtained from the NTP’s Genetic Alterations in Cancer (GAC) database (https://www.niehs.nih.gov/research/resources/databases/gac/description/index.cfm).

Table A-4 Literature Search Approach for Cumene

Substance | Search Terms | Topics (Combined with)^a^
Cumene synonyms | cumene OR 98-82-8 OR isopropylbenzene OR isopropylbenzol OR (1-methylethyl)benzene OR 2-phenylpropane Combine with- NOT cumene hydroperoxide^b^ | Human exposure Toxicokinetics Human cancer studies Cancer studies in experimental animals Genotoxicity Toxicity Mechanism
Cumene metabolites and their synonyms | 2-phenyl-2-propanol, 2-phenyl-1,2-propanediol, 2-phenylpropanoic acid, 2-phenylmalonic acid, 2-hydroxy-2-phenylpropionic acid, dihydroxycumene monosulfate, 2-(2-hydroxy-2-propyl)phenylsulfate, 2-hydroxy-2-phenylpropylsulfate, 2-phenyl-1,2-propandiol monoglucuronide, 2-phenyl-1,2-propandiol 1-glucuronide, 2-phenyl-2-propanol glucuronide, 2-phenylpropionylglucuronide, 2-phenylpropionylglycine, S-(2-hydroxy-2-phenylpropyl)-N-acetylcysteine, 2-phenyl-1-propanol glucuronide, 2-phenyl-1-propanol | Human cancer studies Cancer studies in experimental animals (for the mechanistic section) Genotoxicity Toxicity Mechanism
Chemical class (alkylated benzene) synonyms | alkylated benzene OR alkylated benzenes | Cancer studies in experimental animals (for the mechanistic section) Genotoxicity Toxicity Mechanism
Exposure scenario (Phenol/ Acetone manufacturing) | (“phenol” and (manufacturing or manufacture or production)) or (acetone and (manufacturing or manufacture or production)) | Human cancer studies

^a^ Search terms for each of these topics were developed in consultation with an informational specialist.

^b^ Note: Searches for cumene synonyms bring up a large number of citations for cumene hydroperoxide. Cumene hydroperoxide is an intermediate in the synthesis of acetone and phenol from cumene and is used in other reactions as an epoxidation reagent for allylic alcohols and fatty acid esters, or as an initiator for radical polymerization. It has not been identified as a metabolite of cumene in any biological system. The term “NOT or AND NOT cumene hydroperoxide” was used to eliminate these citations from the database search results.

Table A-5 Search Terms for Monograph Topics for Cumene

Monograph Topic | Search Terms Used in PubMed, Scopus, and Web of Science | MeSH Terms Used in PubMed
Exposure | exposure OR occurrence OR oral OR dermal OR air OR water OR food OR soil OR environmental pollut* OR environmental exposure* OR occupational exposure* | (“Environmental Pollutants” [MeSH] OR “Environmental Pollution” [MeSH])
ADME/ Toxicokinetics | Toxicokinetic search terms- administration OR absorption OR distribution OR tissue distribution OR bioavailab* OR biological availability OR metaboli* OR biotransform* OR activat* OR bioactivat* OR detoxif* OR excret* OR clearance OR eliminat* OR kinetic* OR pharmacokinetic* OR toxicokinetic* OR cytochrome P450 Combine with AND Animal study search terms- in vivo OR animal* OR mouse OR mice OR rat OR hamster OR guinea pig OR rabbit OR monkey OR dog | Toxicokinetic search terms- “Pharmacokinetics”[Mesh]) OR “Metabolism”[Mesh]) OR “Cytochrome P450 Enzyme System”[Mesh]
Human Cancer | ((cumene OR (“phenol” AND (manufacturing OR manufacture OR production)) OR (acetone AND (manufacturing OR manufacture OR production))) AND (cancer OR mortality OR follow-up OR incidence) AND (epidemiogic* OR workers OR case-control OR cohort OR case-report OR case-series)) | None
Animal Tumors | Cancer search terms- cancer OR neoplasm* OR carcinogen* OR malignan* OR oncogene* OR tumor* OR tumour* Combine with AND Animal study search terms- animal* OR mouse OR mice OR rat OR hamster OR “guinea pig” OR rabbit OR monkey OR dog | Cancer search terms- “Neoplasms”[Mesh]) OR “Carcinogens”[Mesh]
Genotoxicity | genetic toxicology” OR clastogen* OR “DNA strand break*” OR “unscheduled DNA synthesis” OR “UDS” OR aneuploid OR aneuploid* OR polyploid OR polyploid* OR “neoplastic cell transformation” OR “chromosom* aberration*” OR cytogenetic OR cytogenetic* OR “DNA adduct*” OR “DNA damage” OR “DNA repair” OR crosslink* OR “germ-line mutation” OR micronucle* OR mutagen OR mutagen* OR mutation OR mutation* OR oncogen* OR “sister chromatid exchange” OR “SCE” OR “SOS response*” OR “Ames test” OR “gene expression” OR “cell proliferation” OR cytotoxic OR cytotoxic* OR “comet assay” | “DNA Damage”[Mesh] OR “DNA Repair”[Mesh] OR “Mutagens”[Mesh] OR “Mutation”[Mesh] OR “Cytogenetic Analysis”[Mesh] OR “Oncogenes”[Mesh] OR “Mutagenicity Tests”[Mesh]
Toxicity | toxic* OR toxin*OR cytotoxic* OR (nephrotoxic* OR hepatotoxic* OR pneumotoxic* OR thyrotoxic* | “Toxic Actions”[Mesh]) OR “Toxicity Tests”[Mesh]) OR “adverse effects” [Subheading]
Mechanisms of Carcinogenicity | (mode* AND “of action”) OR (mechanism* AND “of action”) OR genetic OR epigenetic OR inhibit* OR promot* OR interact* OR activate* OR detoxific* OR “oxidative damage” OR cytotoxicity OR “alpha 2u globulin” OR (“cyp2f2 protein” AND mouse) | (“Alpha 2u globulin”[Supplementary Concept] OR “Cyp2f2 protein, mouse”[Supplementary Concept])