# 6 Overall Cancer Hazard Evaluation – Synthesis of Animal, Human, and Mechanistic Data

This section synthesizes the information from the animal and mechanistic studies and applies the RoC listing criteria to that body of knowledge to reach a preliminary listing recommendation. No epidemiological studies were identified that evaluated the relationship between human cancer and exposure specifically to 1-bromopropane. As stated in Section 4, cancer studies in experimental animals identified 1-bromopropane-induced tumors in the intestine, skin, and lungs that met the RoC criteria for sufficient evidence of carcinogenicity in experimental animals. That assessment did not consider data on mechanisms of carcinogenesis. This section (1) briefly summarizes the assessment of the cancer studies in experimental animals (as reported in Section 4) and (2) discusses the data on mechanisms of carcinogenesis and metabolism of 1-bromopropane reported in Sections 2 and 5, including a synthesis of the information available from studies in humans. The RoC listing recommendation for 1-bromopropane follows the discussion.

## 6.1 Cancer Studies in Experimental Animals

Inhalation exposure to 1-bromopropane increased the incidences of skin tumors (keratoacanthoma; keratoacanthoma and squamous-cell carcinoma combined; and keratoacanthoma, squamous-cell carcinoma, basal-cell adenoma, and basal-cell carcinoma combined) in male rats, large intestine tumors (adenoma of the colon and rectum) in rats of both sexes, and lung tumors (alveolar/bronchiolar adenoma and carcinoma) in female mice. Increased incidences of skin tumors in male rats, intestinal tumors in female rats, and lung tumors in female mice were statistically significant and dose related. The increased incidence of intestinal tumors in male rats, although not statistically significant, was considered to be of biological significance because of the rarity of this type of tumor (incidence of less than 0.2% in historical controls). The incidence of adenocarcinoma of the large intestine was increased in rats of both sexes after oral exposure to brominated methanes (bromodichloromethane or tribromomethane) and in male rats after exposure to glycidol, a metabolite of 1-bromopropane. Additional tumors that may have been related to 1-bromopropane exposure included malignant mesothelioma of the abdominal cavity and pancreatic islet tumors (adenoma) in male rats and skin tumors (keratoacanthoma, basal-cell adenoma, and basal-cell carcinoma combined) in female rats.

## 6.2 Mechanistic and Other Relevant Data

No studies were found that evaluated mechanisms of carcinogenicity of 1-bromopropane at the tumor sites found in experimental animals (skin, large intestine, and lung). However, 1-bromopropane, either directly or via reactive metabolites, causes molecular alterations related to carcinogenicity, including genotoxicity, oxidative stress, glutathione depletion, immunosuppression, and inflammation (see Section 5.3 for details). These alterations, observed mainly in vitro and in toxicity studies in rodents, are relevant to possible mechanisms of carcinogenicity in humans and support the relevance of the cancer studies in experimental animals to cancer in humans.

The available studies suggest that both direct effects and metabolic activation are important in 1-bromopropane-induced carcinogenesis. There is some evidence that 1-bromopropane is directly genotoxic. It has been shown to bind to macromolecules, forming S-propylcysteine globin adducts in exposed animals and humans. It also caused mutations in bacteria (in the only reported study whose design was appropriate for testing a highly volatile chemical) and cultured mammalian cells with or without exogenous mammalian metabolic activation and DNA damage in cultured human cells without exogenous metabolic activation. In rodents exposed to 1-bromopropane in vivo, negative results were reported for the only two end points measured, micronucleus formation (in bone marrow or peripheral blood erythrocytes) and dominant lethal mutation. However, the dominant lethal mutation assay detects only germ-cell mutations and is generally regarded as relatively insensitive for the detection of mutagenic agents.

There is evidence suggesting that metabolic activation plays a role in the genotoxicity and toxicity of 1-bromopropane. Several potential reactive metabolites or proposed reactive intermediates have been identified in rodents, including glycidol and α-bromohydrin, and propylene oxide has been proposed as a metabolite (see Section 2.2). These compounds cause genotoxic effects in vitro (including DNA adduct formation, mutations, and DNA or chromosome damage). Glycidol and propylene oxide cause chromosome damage in vivo and are carcinogenic in experimental animals. Both chemicals are listed in the Report on Carcinogens as reasonably anticipated to be human carcinogens. These reactive and genotoxic metabolites may be responsible for at least some of the carcinogenic effects of 1-bromopropane. As with 1-bromopropane, oral exposure to glycidol caused rare tumors of the large intestine in rats, as did oral exposure to two halogenated alkane analogues of 1-bromopropane, tribromomethane and bromodichloromethane.

Chronic exposure to 1-bromopropane may produce levels of oxidative metabolites that exceed the capacity for glutathione conjugation or may inhibit enzymes required for glutathione synthesis. The resulting reduction in glutathione levels can lead to oxidative stress, increased toxicity, and carcinogenesis. Numerous studies on mechanisms of toxicity in rodents have shown that 1-bromopropane causes oxidative stress and glutathione depletion. Moreover, studies with Cyp2e1^/^ knockout mice, cytochrome P450 inhibitors, or a glutathione synthesis inhibitor showed that this pathway (metabolic activation leading to oxidative stress from glutathione depletion) is involved in 1-bromopropane-induced toxicity (see Appendix E for details). Although no studies have evaluated the role of oxidative stress in 1-bromopropane-induced carcinogenicity, oxidative stress is a relevant mechanism for carcinogenicity in humans.

Other effects associated with 1-bromopropane that could be relevant to carcinogenesis include immunosuppression and inflammation. Recent studies in rodents have shown that 1-bromopropane causes immunosuppression, increased levels of proinflammatory cytokines, increased macrophage activation, and overproduction of cyclooxygenase 2. In addition, there is some evidence from neurotoxicity studies in rodents that 1-bromopropane causes reduced GABAergic feedback inhibition. Although GABA’s primary role is as an inhibitory neurotransmitter in the adult mammalian nervous system, there is substantial evidence that it is involved in the proliferation, differentiation, and migration of several cell types, including cancer cells.

Although the available data on 1-bromopropane metabolism, genotoxicity, and mechanisms of action in humans are limited, they provide some support for the relevance of the findings in experimental animals to humans. Data on human metabolism of 1-bromopropane suggest that metabolic pathways are similar in humans and experimental animals. Urinary mercapturic conjugates identified from workers exposed to 1-bromopropane were also reported as urinary metabolites in rodents, and CYP2E1, the major cytochrome P450 enzyme involved in 1-bromopropane metabolism, is produced in human lung and other tissues. Although it is likely that humans metabolize 1-bromopropane to reactive metabolites, no studies in humans have explored potential pathways leading to additional metabolites or likely intermediates identified from rodent or in vitro studies, such as propylene oxide, glycidol, and α-bromohydrin. Studies of 1-bromopropane-exposed workers have found S-propylcysteine adducts in globin and limited evidence of DNA damage in leukocytes. Case reports and epidemiological studies suggest that 1-bromopropane causes neurological effects, and studies in experimental animals have shown that glutathione depletion and oxidative stress play a role in this toxicity.

## 6.3 NTP Listing Recommendation

1-Bromopropane is reasonably anticipated to be a human carcinogen based on sufficient evidence of carcinogenicity from studies in experimental animals. These studies found that exposure to 1-bromoproane caused tumors at several tissue sites in rats and mice. 1-Bromopropane, either directly or via reactive metabolites, causes molecular alterations that typically are associated with carcinogenesis, including genotoxicity, oxidative stress, and glutathione depletion. These alterations, observed mainly in vitro and in toxicity studies in rodents, are relevant to possible mechanisms of human carcinogenicity and support the relevance of the cancer studies in experimental animals to cancer in humans.