# 5 Mechanistic Data and Other Relevant Effects

The purpose of this section is to review data that are relevant for identifying and evaluating the potential mechanisms of action for the carcinogenic effects discussed in Section 4. Data reviewed in this section include the following: (1) genetic and related effects (Section 5.1 with data tables in Appendix D), (2) relevant toxicological effects (Section 5.2 and Appendix E), (3) mechanistic considerations (Section 5.3), and (4) carcinogenic effects of metabolites and analogues (Section 5.4).

## 5.1 Genetic and Related Effects

1-Bromopropane has been tested in several short-term assays to evaluate potential induction of mutagenic or other genotoxic effects. The database of genotoxicity studies includes DNA and protein adducts (Section 5.1.1) in vitro studies in bacteria (Section 5.1.2) and in mammalian cells (Section 5.1.3), and in vivo studies in rodents (Section 5.1.4) and in 1-bromopropane-exposed workers (Section 5.1.5). Genotoxicity studies are also available on some metabolites of 1-bromopropane (Section 5.1.6). An overall assessment of the genotoxicity of 1-bromopropane is presented in the final section (Section 5.1.7). Data tables for genotoxicity studies discussed in Section 5.3 are provided in Appendix D.

### 5.1.1 DNA and Protein Adducts

No published data were identified for 1-bromopropane DNA adducts. However, DNA adducts are formed by some 1-bromopropane metabolites (see Section 5.1.5), and the N^7^-guanine DNA adduct was formed when 2-bromopropane was incubated with 2'-deoxyguanosine (Zhao et al. 2002) (see Section 5.4.2).

Although no in vivo studies of 1-bromopropane DNA adducts were identified, 1-bromopropane can form covalent adducts with protein in vivo (binding to sulfhydryl groups). One study measured S-propylcysteine (PrCys) adducts with globin and neurofilaments in rats after inhalation exposure (Valentine et al. 2007). Rats exposed to 1-bromopropane for two weeks at 0 to 800 ppm had a statistically significant linear dose response for PrCys globin and neurofilament adducts; exposure to 50 ppm for 8 hours/day, 5 days/week for 4 weeks produced a linear accumulation of PrCys globin adducts. Although there are very few data, DNA and protein adducts could be involved in 1-bromopropane-induced toxicity and carcinogenicity (see Section 5.3).

Valentine et al. (2007) measured S-propylcysteine globin adducts in 26 female factory workers in China who were exposed to 1-bromopropane by inhalation and possibly by skin contact. Controls were age-matched workers from a Chinese beer factory. Exposure to 1-bromopropane was assessed via individual “passive” (diffusion) samplers, and exposure levels ranged from 0.34 to 49.2 ppm for the workers who gave blood samples and 0 to 170.54 ppm for the workers who gave urine samples. There was a significant increase in the S-propylcysteine adducts measured in the globin of exposed workers (1.52 pmol/mg globin) over controls (0.11 pmol/mg globin). The level of urinary N-acetyl-S-(n-propyl)-L-cysteine (AcPrCys) increased with increasing exposure concentrations.

### 5.1.2 In Vitro Studies in Bacteria

1-Bromopropane has been tested in vitro to evaluate mutagenic effects in bacterial strains of Salmonella typhimurium and Escherichia coli. Results of the mutagenicity studies of 1-bromopropane in bacteria are summarized in Appendix D, Table D-1.

1-Bromopropane was reported to be mutagenic in a dose-dependent manner in two tester strains: TA100 and TA1535, when the S. typhimurium assay was modified by using a closed chamber specifically designed for testing volatile substances (Barber et al. 1981). In this study, the authors compared the mutagenic potency of 10 volatile halogenated alkane solvents in the standard assay versus a closed-chamber assay. They reported that while only 2 of the solvents were positive in the standard assay (1-bromopropane was negative), 7 of the 10 substances, including 1-bromopropane, were positive in the closed system. In the closed-system assay, results were similar both in the absence and presence of metabolic activation (S9), indicating that 1-bromopropane is a direct-acting mutagen.

In standard test assays, in two independent laboratories, 1-bromopropane was reported to be non-mutagenic at doses tested up to 3,333 µg/plate; higher doses (to 10,000 µg/plate) were tested but were too toxic to evaluate (NTP 2011a). In addition, there were no mutagenic effects with S9 (prepared from Aroclor 1254-induced livers of rat or hamster) metabolic activation added to the culture at 10% or 30%. These studies were conducted in an open system, so the volatility of 1-bromopropane could have lowered the amount that the bacteria were exposed to. The observation of toxicity at high treatment doses indicated that exposure to 1-bromopropane did, in fact, occur, but it is unclear what the actual exposure levels were to the bacteria. The Barber study reported mutagenicity at lower doses using a modified closed system protocol; the treatment concentration was determined by using gas chromatography to measure 1-bromopropane in water placed in the chamber rather than by the amount of chemical added to the culture plate. This study also reported mutagenic effects for several other volatile substances that were previously reported as non-mutagenic when tested in the standard protocol bacterial assay. 1-Bromopropane was not mutagenic in S. typhimurium in several strains, both with and without S9, in two unpublished studies reviewed in NTP 2003 (Elf Atochem 1994; Kim et al. 1998). The NTP description of the Elf Atochem study noted that the cultures were incubated in closed stainless steel chambers but other important details, such as protocol modifications for sample preparation and treatment with a volatile substance, were not specified. In addition, other specific details were not provided in the NTP review of these studies (e.g., numbers of revertant colonies in either study, as well as cytotoxicity observations, solvent specification, and incubation conditions in the Kim et al. study), which makes it difficult to evaluate the discrepancy between these and the Barber et al. study results.

In summary, the data indicate that 1-bromopropane is a direct-acting mutagen in S. typhimurium, because similar findings were observed both with and without the addition of metabolic activation, in the only reported study that used appropriate methodology (treatment and incubation in a closed chamber) for testing a volatile substance.

### 5.1.3 In Vitro Studies in Mammalian Cells

Available in vitro studies suggest that 1-bromopropane induces mutations and DNA damage in mammalian cells. Two studies were identified that utilized mammalian cells in vitro to assess DNA damage of 1-bromopropane in human leukocytes and mutagenicity in mouse lymphoma cells (see Appendix D, Table D-2. In vitro Studies of 1-Bromopropane in Mammalian Cells). The comet assay showed that in vitro exposure to the highest dose of 1-bromopropane in human leukocytes induced an increase in DNA damage as measured by comet tail moment but no increase was observed for lower doses (Toraason et al. 2006). In the same study, the temporal response to high-dose 1-bromopropane treatment was assessed using the comet assay, and DNA damage was significantly increased after both 4- and 8-hour exposures; DNA damage was higher after 8 hours compared with 4 hours. Toraason et al. also reported a dose-dependent increase in the percentage of apoptotic cells in 1-bromopropane-treated human leukocytes. 1-Bromopropane induced mutations at the thymidine kinase locus in the L5178Y mouse lymphoma cell assay, both with and without the addition of S9 metabolic activation (Elf Atochem (1996) as cited in NTP (2003a)).

### 5.1.4 In Vivo Studies in Rodents

The micronucleus assay was used to evaluate the potential effects of a three-month exposure of up to 500-ppm 1-bromopropane in male and female B6C3F_1_ mice by inhalation (NTP 2011a). No increases in the frequencies of micronucleated normochromatic erythrocytes were reported for either sex of mice. In addition, two unpublished studies, reviewed by NTP (2003a), also reported that micronuclei were not increased in mice treated by i.p. injection or in rats exposed by inhalation to 1-bromopropane (Kim et al. (1998) and Elf Atochem (1995), both cited in NTP (2003a)). (See Appendix D, Table D-3 for findings from in vivo studies in rodents.)

Dominant lethal mutation assays were negative in ICR mice (Yu et al. 2008) and in Sprague-Dawley rats (Saito-Suzuki et al. 1982) as shown in Appendix D, Table D-3. Male ICR mice were administered 1-bromopropane by i.p. injection while male Sprague-Dawley rats were given five consecutive daily doses in olive oil by oral gavage prior to mating with untreated females. The dominant lethal mutation assay identifies germ-cell mutagens by measuring a chemical’s ability to penetrate gonadal tissue and produce embryonic death via chromosomal breakage in parent germ cells. Limitations for evaluating genotoxicity using this assay are that it does not detect somatic mutations and, because the spontaneous mutation frequency is high, the assay may have limited sensitivity for detection of small increases in induced mutation frequency (Singer et al. 2006). The study in rats also tested four other structurally related halogenated 3-carbon compounds that have a similar structure to a known mutagen, 1,2-dibromo-3-chloropropane (DBCP). Only 1,2,3-tribromopropane and DBCP induced dominant lethal mutations; the authors suggested that in order for propanes to induce dominant lethal mutations, they should have bromine or chlorine on each carbon atom and 2 of the 3 halogen atoms should be bromine.

### 5.1.5 Studies in Exposed Workers

The comet assay was used to assess DNA damage (strand breaks) in peripheral blood leukocytes from 64 workers (18 males and 46 females) exposed occupationally to 1-bromopropane (Toraason et al. 2006) at two facilities (designated as A and B) that utilized spray adhesives containing 1-bromopropane. There was no unexposed population so the workers were divided into higher-exposure (sprayer) and lower-exposure groups (non-sprayers) (see Appendix D, Table D-4).

In analysis by facility (A and B) and job type (sprayer and non-sprayer), no clear exposure-response patterns were observed. DNA damage (as measured by tail moment) in leukocytes from sprayers were numerically higher for both start- and end-of-workweek samples than non-sprayers but none of the increases were statistically significant and sprayers at Facility B (lower-exposure facility) had higher measures of DNA damage than sprayers at Facility A (higher-exposure facility) at the start, but not at the end, of the work week. No exposure-response patterns were observed for DNA damage as assessed by tail moment dispersion coefficient.

Multivariate analyses were also performed that evaluated the association between DNA damage (start-of-workweek and end-of-workweek comet tail moment and dispersion coefficients) and three 1-bromopropane exposure indices—1-bromopropane TWA levels, and serum and urinary bromide concentrations—in models that controlled for gender, age, smoking status, facility, and two DNA polymorphisms (GSTM1 and GSTT1). For each of the three exposure indices, both linear regression models using log-transformed exposure indices and exposure quartiles analyses were performed. Both start-of-workweek and end-of-workweek comet tail moments in leukocytes were significantly associated with serum bromide quartiles; end-of-workweek values were also significantly associated with 1-bromopropane TWA quartiles. Although not statistically significant, all of the other associations between 1-bromopropane exposure indices and DNA damage were positive, with the exception of the end-of-workweek urinary bromide. The strengths of this study are that the assessment of exposure to workers was at the individual level and that these workers were exposed to a wide range of levels of 1-bromopropane, which allowed for the evaluation of exposure-response relationships. Multivariate analyses were considered to be more informative than the analysis by job and facility. Limitations to this study include small numbers of exposed workers, no unexposed controls, and multiple comparisons.

These results provided limited evidence that 1-bromopropane causes DNA damage in vivo.

### 5.1.6 Genotoxic Effects of 1-Bromopropane Metabolites

The genotoxic effects of several known or postulated metabolites of 1-bromopropane have been evaluated in numerous in vitro and in vivo studies. Two reviews by the International Agency for Research on Cancer (IARC) provided most of the information for glycidol (IARC 2000) and propylene oxide (IARC 1994) and primary studies were used to update or supplement this information (see Appendix D, Table D-5).

Both glycidol (known metabolite in rats) and propylene oxide (postulated metabolite) are mutagenic in bacteria, yeast, Drosophila, and mammalian cells; they are direct-acting mutagens, as the addition of metabolic activation did not change the response. Both metabolites have been shown to form DNA adducts, and both induce DNA damage and chromosomal damage in vitro in rodent and human cells. Available in vivo test results for glycidol indicate that it induces micronucleus formation but not chromosomal aberrations (CA) in the mouse. Studies of propylene oxide for chromosomal damage reported positive responses in mouse bone marrow for micronucleus induction and chromosomal aberration tests, as well as DNA damage in the sister chromatid exchange (SCE) assay, but results with monkey lymphocytes for both CA and SCE were negative. In occupationally exposed propylene oxide workers, DNA damage was induced in the SCE assay, and both DNA and hemoglobin (protein) adducts were formed. Propylene oxide has also been shown to bind to DNA in rodents and to hemoglobin in rodents, dogs, and monkeys. Other 1-bromopropane metabolites have been shown to be direct-acting mutagens and to induce DNA damage in bacteria. α-Bromohydrin and 3-bromo-1-propanol were mutagenic in the S. typhimurium reversion assay, and 3-bromo-1-propanol and 1-bromo-2-propanol induced DNA damage in E. coli.

### 5.1.7 Synthesis of Results

Studies in vivo show that 1-bromopropane can covalently bind to protein in exposed rats and occupationally exposed workers. The available data provide some support that 1-bromopropane is genotoxic as it induced mutations in bacterial and mammalian cells and DNA damage in human cells (Table 5-1). There is limited evidence that DNA damage was induced in leukocytes from 1-bromopropane-exposed workers. 1-Bromopropane did not induce chromosomal damage in exposed rodents (micronucleus induction assay) or gene-cell mutations (dominant lethal mutation assay).

Table 5-1 Summary of 1-Bromopropane Genotoxicity Information

Effect | In Vitro | In Vivo
Effect | In Vitro | Rodents | Humans
Mutation
Bacteria | ±^a^
Mammalian cells | + | NT | NT
DNA Damage | + | NT | +
Micronuclei Induction | NT | − | NT
Dominant Lethal Mutation | NT | − | NT

+ = positive, ± = both positive and negative, − = negative.

NT = not tested.

^a^ Positive in the only study whose design was appropriate for testing volatile chemicals.

Several known or postulated metabolites of 1-bromopropane have been identified as mutagens and two, glycidol and propylene oxide (proposed), were shown to cause chromosomal and DNA damage in cultured mammalian cells. Both metabolites caused chromosomal damage in cells from rodents exposed in vivo, and propylene oxide induced DNA damage in cells from exposed workers (Table 5-2). Three other 1-bromopropane metabolites (α-bromohydrin, 3-bromo-1-propanol, and 1-bromo-2-propanol) were mutagenic or caused DNA damage in bacteria (Table 5-2).

Table 5-2 Summary of Genotoxicity Data for 1-Bromopropane Metabolites^a^

Effect Metabolite | In Vitro (Cell Type^b^) | In Vivo (Mammals) | Humans (Epidemiology Studies)
DNA Adducts
Glycidol | + (mammal) | NT | NT
Propylene oxide | + (bacteria, mammal) | + (rodents, dogs) | +
Mutation
Glycidol | +^c^ | NT | NT
Propylene oxide | +^c^ | − (germ cell) | NT
α-Bromohydrin | + (bacteria) | NT | NT
3-Bromo-1-propanol | + (bacteria) | NT | NT
1-Bromo-2-propanol | NT | NT | NT
DNA Damage
Glycidol | +^d^ | NT | NT
Propylene oxide | +^d^ | NT | +
α-Bromohydrin | NT | NT | NT
3-Bromo-1-propanol | + (bacteria) | NT | NT
1-Bromo-2-propanol | + (bacteria) | NT | NT
Chromosomal Damage
Glycidol | + (mammal, human) | ± (rodents) | NT
Propylene oxide | + (mammal, human) | + (rodents); − (monkeys) | Inc

NT = not tested; Inc = inconclusive, + = positive, − = negative, ± = positive and negative results.

^a^ Does not include findings from insect studies or gene conversion studies in yeast.

^b^ Positive in bacteria, yeast, mammalian cells, and human cells.

^c^ Positive in bacteria, yeast, and mammalian cells.

^d^ Positive in bacteria, mammalian cells, and human cells.

## 5.2 Relevant Toxicological Effects

1-Bromopropane has caused neurological, developmental, reproductive, immunological, and hepatotoxic effects in rodents and neurological effects in humans (Lee et al. 2007a; Lee et al. 2010a; Lee et al. 2010b; NTP 2003a; 2011a). Studies on toxic effects were reviewed (see Appendix E) to determine whether they could inform potential mechanisms of carcinogenicity. Several studies indicate that metabolic activation and glutathione depletion are important factors for many of the toxic effects observed in rodents. Appendix E provides a brief review of the toxic effects that have been linked to metabolic activation and/or glutathione depletion and oxidative stress and other alterations and provides background information for Section 5.3, which discusses these mechanisms as they relate to carcinogenicity.

## 5.3 Mechanistic Considerations

The biological events associated with chemically induced cancer are not completely understood even for chemicals that have been extensively studied and are known to cause cancer in humans (e.g., benzene and arsenic) (Guyton et al. 2009). It is important to recognize that chemicals can act through multiple toxicity pathways and mechanisms to induce cancer or other health effects, and the relative importance of the various pathways may vary with life stage, genetic background, and dose. Thus, it is unlikely that for any chemical a single mechanism or mode of action will fully explain the multiple biological alterations and toxicity pathways that can cause normal cells to transform and ultimately form a tumor.

Although no studies were identified that were specifically designed to investigate possible modes of action for 1-bromopropane-induced carcinogenesis, the available data indicate that metabolic activation, genetic damage, and oxidative stress from glutathione depletion are important factors. As discussed in the previous section, these factors were linked to several of the primary non-neoplastic toxic effects of 1-bromopropane, including immunosuppression, neurotoxicity, reproductive toxicity, and hepatotoxicity. Other factors that have been associated with carcinogenesis and may be relevant for 1-bromopropane are discussed and include immune-response modulation, altered cell signaling and gene expression, inflammation, and cytotoxicity and compensatory cell proliferation.

### 5.3.1 Metabolic Activation and Genotoxicity

As mentioned above, there is some evidence that 1-bromopropane and its metabolites are mutagenic and genotoxic (see Section 5.1). Metabolism of many halogenated hydrocarbons results in the formation of highly reactive oxidative intermediates that can alkylate proteins and nucleic acids (Morgan et al. 2011). Reactive metabolites of 1-bromopropane include bromoacetone (1-bromo-2-propanone), glycidol, propylene oxide (proposed), and α-bromohydrin (see Section 5.1.6) (Garner et al. 2007; Garner et al. 2006; Ghanayem and Hoffler 2007; Ishidao et al. 2002; Jones and Walsh 1979; Lee et al. 2010a; Lee et al. 2010b). Bromoacetone and other α-bromoketones have been shown to disrupt enzymatic processes by alkylating trypsin at histidine residues or glutathione-S-transferases at cysteine residues (Beeley and Neurath 1968; Mitchell et al. 1998). Garner et al. (2006) reported that rats pretreated with ABT, a potent inhibitor of CYP, had a 10-fold reduction in hepatic radiochemical content (4.1 to 0.46 μg equivalents per gram of tissue) suggesting that oxidative metabolism leads to more reactive species.

### 5.3.2 Oxidative Stress

Oxidative stress due to cellular glutathione depletion could contribute to the carcinogenicity of 1-bromopropane (Morgan et al. 2011). Although no studies were identified that directly investigated the possible role of glutathione levels and oxidative stress in 1-bromopropane-induced carcinogenicity, several studies have shown evidence that exposure to 1-bromopropane causes toxic effects in the liver and in the reproductive and nervous systems of mice and rats that are associated with glutathione depletion and oxidative stress (Lee et al. 2007a; Lee et al. 2005a; Lee et al. 2005b; Lee et al. 2010a; Lee et al. 2007b; Lee et al. 2010b; Li et al. 2010a; Liu et al. 2009; Liu et al. 2010). A dose-dependent depletion of glutathione by 1-bromopropane was reported in mice (Lee et al. 2007a; Lee et al. 2007b), and a role for Cyp2e1 metabolism in this effect was indicated by a greater depletion of glutathione in wild-type mice than in Cyp2e1 knockout mice (Garner et al. 2007). Oxidative stress in rodents exposed to 1-bromopropane is consistent with dose-dependent increases in oxidative stress markers (ROS, RNS) in rat cerebellum (Subramanian et al. 2012), increased lipid peroxidation in male mice (Liu et al. 2010), and altered expression of oxidative stress genes (NQO1 and HO-1) in mice (Liu et al. 2009; Liu et al. 2010) (for more information, see Appendix E).

Glutathione conjugation is generally regarded as a detoxification mechanism (Morgan et al. 2011). Most of the urinary metabolites of 1-bromopropane are derived from glutathione conjugates, thus, chronic exposure could produce levels of metabolites that exceed the amount of glutathione available for conjugation. Glutathione levels also may be depleted by oxidative metabolites that inhibit enzymes required for glutathione synthesis. Liu et al. (2009) also reported lower hepatocellular glutathione-S-transferase (GST) activity in susceptible mouse strains exposed to 1-bromopropane. Lower GST activity could reduce glutathione conjugation and increase toxicity. Huang et al. (2011) reported differential expression of several proteins in the hippocampus of rats exposed to 1-bromopropane that support the hypothesis that oxidative stress plays a role in 1-bromopropane-induced damage. These proteins included HSP60, GRP78, DJ-1, GSTA3, and GSTP1. The proteins HSP60, GRP78, GSTA3, and GSTP1 were up-regulated after 1-bromopropane exposure. HSP60 is a mitochondrial matrix protein induced by various kinds of stresses and GRP78 is an endoplasmic reticulum-resident molecular chaperone that suppresses oxidative stress. GSTA3 and GSTP1 belong to a family of detoxification enzymes that also protect against oxidative stress. DJ-1 has been shown to prevent oxidative stress in age-related neurodegeneration and was down-regulated after 1 week of exposure. Thus, downregulation of DJ-1 could result in increased oxidative stress.

### 5.3.3 Immunosuppression and Other Factors

Immune-response modulation, cell signaling, altered gene expression, inflammation, and cytotoxicity and compensatory cell proliferation are other key events that have been associated with carcinogenesis. Recent studies have shown that 1-bromopropane causes immunosuppression in rodents (Anderson et al. 2010; Lee et al. 2007a; Lee et al. 2007b). In particular, deleterious effects on T-cell numbers and subpopulations were reported. Since T-cells play an important role in detecting and eliminating tumor cells, a compromised immune system could facilitate tumor progression (Töpfer et al. 2011). Anderson and Rice (1987) demonstrated that athymic nude mice that do not have T-cells were more sensitive to skin tumorigenesis that euthymic mice. In addition, data from genetic, disease, and drug-induced immunosuppression in humans have consistently shown that immunosuppression is associated with an increased risk of skin tumors and certain other cancers (DePry et al. 2011; Kuschal et al. 2012; Weaver 2012). However, a possible role of immunosuppression in 1-bromopropane-induced skin cancer in rodents has not been described.

Chronic inflammation was one of the key events associated with various carcinogenic modes of action (Guyton et al. 2009). In a series of studies, Han et al. (2008; 2012) investigated the effect of 1-bromopropane on nitric oxide and proinflammatory cytokine production and the role of NF-κB in 1-bromopropane-mediated inducible nitric oxide synthases (iNOS) and proinflammatory cytokine expression in mouse macrophages. iNOS catalyzes the formation of nitric oxide and may be an important mediator of carcinogenesis in some circumstances. Overexpression of iNOS has been described in human cancer, and tumor-associated production of nitric oxide by iNOS may elevate tumor progression. 1-Bromopropane caused proinflammatory changes in mouse macrophages including upregulation of iNOS and cytokines (IL-1β, IL-6, and TNF-α), enhanced the production of prostaglandin E_2_ (PGE_2_), and dose-dependently increased cyclooxygenase-2 (COX-2) protein and mRNA levels. Increased PGE_2_ production may contribute to the tumorigenic process through effects on cell proliferation, apoptosis, and vascular growth. Thus, 1-bromopropane exposure induced a variety of effects, including increased levels of proinflammatory cytokines, increased macrophage activation, and over expression of COX-2, that collectively support the assertion that 1-bromopropane induces inflammation.

Exposure-related increased incidences of chronic respiratory tract inflammation (nasal cavity, larynx, and trachea) occurred in rats, and increased incidences of cytoplasmic vacuolization in the nasal cavity, larynx, trachea, and bronchiolar epithelium occurred in mice (NTP 2011a). Bronchiole regeneration also was significantly increased in exposed male and female mice. These lesions are indicative of local irritant effects, but there was no apparent association with carcinogenic effects because lung tumors occurred only in female mice, and upper respiratory tract tumors were not increased in mice or rats.

There is also some evidence from neurotoxicity studies in rodents that 1-bromopropane causes hyperexcitability of the hippocampus due to dysfunction of γ-aminobutyric acid (GABA) feedback inhibition (Fueta et al. 2004; Fueta et al. 2002a; Mohideen et al. 2009) (see Appendix E). Although a primary role of GABA is as an inhibitory neurotransmitter in the adult mammalian nervous system, there is substantial evidence that it is involved in the proliferation, differentiation, and migration of several cell types, including cancer cells (Watanabe et al. 2006). Young and Bordey (2009) reported that GABAergic signaling and its control over proliferation is widespread through peripheral organs containing adult stem cells (e.g., liver, pancreas, kidney, intestine, prostate, testis, and ovary). GABA is a strong inhibitor of cell proliferation; however, it is possible that altered GABAergic signaling in tumors cells leads to abnormal proliferation. Tatsuta et al. (1990) demonstrated that GABA or a GABA_B_ receptor agonist inhibited N-methyl-N'-nitro-N-nitrosoguanidine-induced gastric carcinogenesis in Wistar rats. Maemura et al. (2003) examined the expression of GABA in human intramucosal colonic tumors. Tissue samples included 56 protruded-type colonic tumors that were classified as adenocarcinoma, adenoma with severe atypia, or adenoma with mild to moderate atypia. The level of GABA expression was proportional to the degree of atypia in colonic neoplasms and was proposed as a possible tumor marker. Schuller et al. (2008) reported that GABA may have tumor suppressor function in small airway epithelia and that downregulation of GABA by nicotine-derived carcinogens may contribute to lung cancer in smokers.

### 5.3.4 Sex Differences in Chemical Carcinogenesis

Sex differences were observed for 1-bromopropane-induced tumors in both rats and mice in the NTP experimental animal studies, as described in detail in Section 4. While both sexes of rats developed large intestinal tumors, the incidence was higher in females; skin tumors were induced in male rats, but the findings were only equivocal in females. In mice, lung tumors were observed in females but not in males.

In a recent survey of 278 chemicals identified as carcinogenic in rats in the NTP 2-year bioassay, 201 exhibited statistically significant sex differences (p < 0.05) in at least one non-reproductive organ (Kadekar et al. 2012) with males showing a dominance: tumors were induced in non-reproductive organs in male rats for 130 chemicals and in females for 59. Induction of both skin tumors and tumors of the large intestine were significantly greater in male rats (p < 0.05), which is consistent for the skin tumors but not the large intestinal tumor findings for 1-bromopropane. However, this general pattern of increased incidence in males is based on a review of a large database of multiple chemicals, which may induce tumors via more than one mechanism. Greater male susceptibility to cancer has also been noted in surveys of human cancers (Cook et al. 2009; Edgren et al. 2012); however, no clear explanation for the male dominance in rats or humans was apparent.

As discussed in Section 2.2.4 and Appendix E, CYP2E1 and glutathione S-transferase (GST) are important in 1-bromopropane metabolism and toxicity and thus probably play a role in carcinogenicity. There is some evidence that there are sex differences in enzymatic activity in 1-bromopropane-exposed rats. p-Nitrophenol hydroxylase (pNPH), associated with CYP2E1 expression, and NADPH b_5_ reductase levels increased in a dose-dependent fashion and were consistently higher in male than female rats for the control treatment and all doses tested. GST and lipid peroxide (LPO) levels also increased with increasing dose; in general, GST levels were higher in males, however LPO levels were higher in females (Kim et al. 1999b). It is unclear how these sex differences in enzymatic activity translate to sex differences in tumor incidence in 1-bromopropane-exposed rats; some of the differences would suggest a potential increase in reactive oxygen species or oxidative damage (CYP2E1 in males), while others suggest a decrease (e.g., LPO*). It is also not known if sex differences occur similarly at other tissue sites.

In mice, an evaluation of the NTP 2-year bioassay historical control database indicates that there is a sex difference in the spontaneous incidence of lung tumors: 32% of males had tumors, compared with 8% of females (see NTP database https://ntp.niehs.nih.gov/go/datasearch). No studies looking at gender differences specific for 1-bromopropane exposure in mice were identified; however, normal CYP2E1 expression measured in mice was found to vary by tissue type as well as by sex (Chanas et al. 2003). Expression was significantly greater in the kidneys of males and slightly higher (non-significant) in lungs of females, but no sex difference was observed in the liver.

Overall, 1-bromopropane caused tumors at different sites in male and female rats and mice, and some data from the NTP database for chemical carcinogenesis were consistent with the observed pattern; however, there is limited information on sex differences in 1-bromopropane metabolism or other mechanistic data.

## 5.4 Carcinogenicity of 1-Bromopropane Metabolites and Analogues

While 1-bromopropane and other halogenated hydrocarbons are generally stable compounds, they can undergo metabolism or bioactivation that results in toxic effects, usually subsequent to dehalogenation, i.e., their toxicity is generally associated with the reactive, electrophilic metabolites formed from the carbon skeleton rather than with the halide ion released from the molecule (Anders 1982b).

### 5.4.1 Metabolites

Glycidol is the only urinary metabolite of 1-bromopropane that has been tested for carcinogenicity; it is currently listed as reasonably anticipated to be a human carcinogen by the NTP (2011b). Propylene oxide, a proposed intermediate metabolite of 1-bromopropane, also is currently listed as reasonably anticipated to be a human carcinogen by the NTP (2011c). α-Bromohydrin is another reactive metabolite of 1-bromopropane, but it has not been tested for carcinogenicity.

Oral administration of glycidol caused benign and malignant tumors at multiple tissue sites in rats and mice (NTP 1990). Organs and tissues affected in rats included the oral mucosa, forestomach, glandular stomach, intestines, mammary glands, skin, tunica vaginalis, clitoral gland, thyroid gland, brain, and Zymbal gland. Tissues affected in mice included the mammary glands, forestomach, Harderian gland, lung, liver, skin, uterus, and urinary bladder. The tumor profile for glycidol was more varied than that for 1-bromopropane but there were some similarities. In particular, glycidol and 1-bromopropane induced mesothelioma in the tunica vaginalis covering the epididymis and testes, benign but rare intestinal tumors, and skin tumors in rats. Glycidol also induced lung tumors in male mice, while 1-bromopropane induced lung tumors in female mice. Glycidol also has induced immunosuppressive effects in mice (Guo et al. 2000).

Propylene oxide caused benign and malignant tumors in rats and mice at several tissue sites when administered by inhalation, stomach tube, or s.c. injection (IARC 1994). Rats developed nasal cavity, adrenal gland, forestomach, abdominal cavity, and mammary tumors. Mice developed nasal-cavity and injection-site tumors.

### 5.4.2 Analogues

1-Bromopropane is one member of the large class of halogenated alkanes, and chemical characteristics shared by these related molecules could be informative for the carcinogenicity of 1-bromopropane. In general, the presence of a halogen substituent on a carbon atom has an electron-withdrawing effect making the carbon atom more electrophilic, which increases the reactivity of the carbon atom (van Hylckama Vlieg and Janssen 2001). Among the halogens, bromine is recognized as a better leaving group than the smaller, more electronegative chlorine and fluorine atoms. Thus, halogenated, and particularly brominated, alkanes would be expected to more readily form activated intermediates that could covalently modify biological molecules. Activated intermediates may result from bioactivation by CYP. These bioactive (electrophilic) compounds can also be conjugated by the nucleophile, glutathione, a reaction catalyzed by glutathione-S-transferases (GSTs) (Anders 1982a; 2001). Exposure of mice to 1-bromopropane causes hepatotoxicity and may be related to glutathione depletion associated with conjugate formation and subsequent formation of reactive oxygen species. Since glutathione is an important cellular defense mechanism against reactive oxygen species, reduced levels of glutathione can lead to oxidative stress, enhanced toxicity, and possibly carcinogenicity.

The nearest structural analogue for 1-bromopropane is 2-bromopropane, an isomer that has not been tested for carcinogenicity. However, 2-bromopropane has been studied in a number of genotoxicity assays. Similar to 1-bromopropane, 2-bromopropane caused base-pair mutations in Salmonella strains TA100 and TA1535 (NTP 2003b) and DNA damage in cultures of rat Leydig cells (Wu et al. 2002), but did not induce chromosomal aberrations in Chinese hamster lung cells. In rodents, it induced micronucleus formation in embryos from pregnant mice exposed to 2-bromopropane by i.p. injection but did not cause micronuclei in bone marrow of adult rats exposed by i.p. injection. 2-Bromopropane also formed N^7^-isopropyl guanine adducts (Zhao et al. 2002) and caused massive depurination (Sherchan et al. 2009a; Sherchan et al. 2009b). Unrepaired apurinic sites lead to lethality or base substitution errors. Although 2-bromopropane causes similar types of toxicities (neurological [(Yu et al. 2001)], hematological [(Kim et al. 1999a)], immunological (Anderson et al. 2010), and reproductive (NTP 2003b)), the primary metabolic products are different from those of 1-bromopropane.

Other analogues for 1-bromopropane are monobrominated, short-chain alkanes, such as bromomethane, bromoethane, 1-bromobutane, and 2-bromobutane. Bromomethane (methyl bromide) is classified by NIOSH as a potential occupational carcinogen (CDC 2010) and by IARC as Group 3, not classifiable as to its carcinogenicity in humans, but neither it nor the bromobutane isomers have been tested in 2-year bioassays by NTP or reviewed for the Report on Carcinogens. Bromoethane has been tested in a 2-year bioassay by NTP, and it is listed by IARC as Group 3; it has not been reviewed by NTP for the Report on Carcinogens. Bromoethane is classified by the American Conference of Governmental Industrial Hygienists as A3, confirmed animal carcinogen with unknown relevance to humans.

While the examination of the potential carcinogenicity of all members of the large class of halogenated alkanes is beyond the scope of this document, several halogenated alkanes (bromodichloromethane, carbon tetrachloride, chloroform, 1,2-dibromo-3-chloropropane, 1,2-dibromoethane (ethylene dibromide), 1,2-dichloroethane, dichloromethane, hexachloroethane, and 1,2,3-trichloropropane) are listed in the NTP Report on Carcinogens as reasonably anticipated to be a human carcinogen and classified by IARC as possible or probable carcinogens. In addition to the analogues described above, more than a dozen other halogenated alkanes have been reviewed by IARC and listed as Group 3. No mechanistic data were identified to suggest that these molecules would act by a common mechanism with 1-bromopropane, and they are not discussed further here.

A search of the IARC website (www.iarc.fr) identified 12 additional halogenated alkanes that had been reviewed by IARC and placed in Group 3, i.e., not classifiable as to their carcinogenicity in humans. The majority of these molecules (bromoform [tribromomethane], chlorodibromomethane, chloroethane, chlorofluoromethane, 2-chloro-1,1,1,-trifluoroethane, 1,2-dichloropropane, methyl iodide, pentachloroethane, and 1,1,2-trichloroethane) were reported to have no epidemiological data relevant to their carcinogenicity and limited data in experimental animals. One other molecule (chlorodifluoromethane) also had limited data in experimental animals and data in humans were considered inadequate; the last two molecules (methyl chloride and 1,1,1-trichloroethane) had inadequate data in both humans and experimental animals. Two halogenated alkanes (1,1,1,2-tetrachloroethane and 1,1,2,2-tetrachloroethane) have been recently listed by IARC as Group 2B, possibly carcinogenic to humans, and are pending publication in Volume 106.