# 4 Studies of Cancer in Experimental Animals

This section reviews and assesses the carcinogenicity studies in experimental animals exposed to 1-bromopropane. These studies were identified by searching databases, comprehensive reviews, and citations from studies retrieved from the literature searches as described in Appendix A. Identified citations were reviewed using exclusion and inclusion criteria that limited selection of the studies to those examining neoplastic lesions, non-neoplastic or preneoplastic lesions relevant to carcinogenicity, or subchronic studies that provide information on dose selection. Chronic (2-year) inhalation studies conducted by NTP and the associated subchronic (90-day) studies in mice and rats were the only studies identified that examined tissues for neoplastic or preneoplastic endpoints.

The characteristics, methodology, and relevant non-neoplastic findings from the chronic studies by NTP and the associated subchronic studies are reported in Section 4.1. An assessment of the evidence for carcinogenicity is discussed in Section 4.2 and the recommendation for the level of evidence is provided in Section 4.3.

## 4.1 Studies in Experimental Animals: Characteristics, Methodology, and Relevant Non-Neoplastic Findings

Both the subchronic and chronic studies in rats and mice were conducted in the same facility using 1-bromopropane with purity greater than 99% and the same animal husbandry and testing procedures as in the chronic study under FDA Good Laboratory Practice regulations (NTP 2011a). The subchronic studies in rats and mice were used to determine the exposure groups in the chronic study. B6C3F_1_ mice or F344/N rats were administered 1-bromopropane (99% pure) by whole-body exposure in inhalation chambers for 6 hours and 10 minutes per day, 5 days a week, for either 14 weeks (subchronic studies, 10 males and 10 females per exposure group) or 105 weeks (chronic studies, 50 males and 50 females per exposure group), with controls exposed to filtered air only. (Note: The additional 10 minutes of exposure were based on experimental data for the time required to achieve 90% of the target concentration [T_90_] after the beginning of vapor generation.) Complete necropsies and histopathology were performed on all animals. At necropsy, all organs and tissues were examined for grossly visible lesions, and all major tissues were processed and stained for histopathologic examination.

### 4.1.1 Rats

#### 4.1.1.1 Subchronic Study

The subchronic study did not identify any neoplastic lesions at the exposure levels tested (0, 62.5, 125, 250, 500, or 1,000 ppm). Male rats exposed to 1,000 ppm had reduced body weight compared with controls; rats had evidence of hepatotoxicity at this dose. Sorbitol dehydrogenase activity was increased at 500 ppm (males only) and 1,000 ppm (males and females). Liver weight and cytoplasmic vacuolization were increased at 250 ppm or greater exposures in males. In females, liver weight increased at 125 ppm or greater, liver vacuolization at 500 ppm or greater, and hepatocyte degeneration was observed at 1,000 ppm. During selection of the maximum level of exposure for the chronic study, liver vacuolization was considered a tolerable toxicity and not life threatening, while hepatocyte degeneration was considered intolerable.

#### 4.1.1.2 Chronic Study

Fischer 344/N rats were exposed to 0, 125, 250, and 500 ppm of 1-bromopropane based on decreased body weights and increased incidences of liver lesions at 1,000 ppm reported in the subchronic study. During the chronic study, survival in males was significantly decreased in the group exposed to 500 ppm, and survival decreased with increasing level of exposure (statistically significant negative trend). Survival in females was not significantly decreased in a pairwise analysis for any exposure level, but there was a statistically significant negative trend with the level of exposure. Body weights of exposed males and females were similar to those of controls.

No neoplastic lesions were found in the respiratory tract, but several non-neoplastic lesions, including inflammation, hyperplasia, and metaplasia were found in the upper respiratory tract of both sexes of rats. Hyperplasia of the respiratory epithelium was found at significantly increased incidences in the nasal cavity of females at 125 and 500 ppm and in the trachea of females at 500 ppm. Hyperplasia of glands in the nasal cavity, mostly in level II, was at a significantly increased incidence in both sexes in all exposed groups of rats. Significant increases in the incidences of metaplasia in females were found in the nasal cavity as olfactory epithelium with morphology of respiratory epithelium at 500 ppm and in the larynx as squamous metaplasia at 500 ppm. Chronic suppurative inflammation of the nasal cavity had a significantly increased incidence in males and females at 500 ppm. Despite the high incidence of chronic active inflammation seen in untreated controls, the incidences of this non-neoplastic lesion were significantly increased in the nasal cavity of females at all exposure levels, in the larynx of males at 250 ppm and of females at 250 and 500 ppm, as well as in the trachea of females at 500 ppm. Abscesses on the tail, Harderian gland, head, and salivary gland of five exposed rats were tested for bacterial growth under anaerobic and aerobic conditions. Pseudomonas aeruginosa was the primary isolate (4 out of 5 sites) in all aerobic cultures and Splendore-Hoeppli bodies were later observed microscopically in these lesions (see discussion in Appendix E, Immunotoxicity). Although inflammation and infections were associated with immunosuppression in rats, it was not noted in the Technical Report (NTP 2011a) whether the abscesses were directly associated with tumors. No evidence of suppurative inflammation was reported in the mouse study, although mice were also immunosuppressed after subchronic 1-bromopropane exposure.

### 4.1.2 Mice

#### 4.1.2.1 Subchronic Study

The NTP subchronic study did not identify any neoplastic lesions at the exposure levels tested (0, 62.5, 125, 250, 500 ppm). Survival (number surviving/number at study start) was decreased in the high-dose female (5/10) and male (6/10) groups and one death at 250 ppm in males (9/10). There was an increase in kidney, liver, and lung weights in the 500-ppm female group, and the kidney weights of the 500-ppm male group were decreased.

#### 4.1.2.2 Chronic Study

Based on mortality at the highest exposure concentration, changes in organ weights, and the incidences of various non-neoplastic lesions in the subchronic study, 1-bromopropane exposure concentrations selected for the chronic inhalation study in mice were 62.5, 125, and 250 ppm. During the chronic study, survival and body weights of both sexes in exposed groups were similar to those in control groups.

## 4.2 Assessment of Neoplastic Findings

The chronic inhalation studies in B6C3F_1_ mice and Fischer 344/N rats conducted by NTP were of sufficient duration to adequately assess the carcinogenic potential of 1-bromopropane. Factors considered in study design were the number of animals per exposure group, exposure period, dose selection, monitoring of animal health, and complete necropsies of all animals and histopathologic examination of all major tissues. This study is considered a high-quality study and provides strong evidence to support the cancer assessment. Details of study quality criteria and assessment are found in Appendix C. Important factors taken into account in data assessment are the significance of the effect as compared with the concurrent control (pairwise comparison), whether there is a change in the effect with dose (trend analysis), and the rarity of the event (historical control range). In the NTP assessments of experimental animal data in this report, a Poly-3 trend analysis is employed, which is similar to the Cochran-Armitage trend test but is survival adjusted.

In rats, there was a significantly increased incidence with a positive trend for benign tumors (adenoma) of the large intestine (colon or rectum) in females, but the incidence did not reach significance for male rats (Table 4-1). However, these are rare tumors and the tumor incidence exceeded the historical control range for male and female rats for inhalation studies and studies by all exposure routes and are considered to be of biological significance. (An adenomatous polyp was listed for a male rat exposed to 125-ppm 1-bromopropane [see Appendix Table A1 of the NTP Technical Report 564, NTP 2011a] but was not included in the data analysis conducted by the authors. Addition of this tumor increases the total number of benign tumors of the large intestine in all 1-bromopropane-exposed male rats from 3 to 4 tumors, which provides additional support for an exposure-related effect.) The time to first incidence of tumors of the colon or rectum was lower with increasing dose in male rats (729 days at 250 ppm and 682 days at 500 ppm); but no clear trend was seen with increasing dose for female rats (730 days at 125 ppm, 607 days at 250 ppm, and 719 days at 500 ppm). Spontaneous adenoma of the large intestine is rare in male and female rats, occurring at a rate of less than 0.2%. Increased incidences of adenocarcinoma of the large intestine were observed in both male and female rats after oral treatment with brominated methanes (bromodichloromethane or tribromomethane (NTP 1987; NTP 1989) and in male rats after treatment with glycidol (NTP 1990), a metabolite of 1-bromopropane. Therefore, the findings of intestinal tumors after 1-bromopropane exposure are considered to be exposure related. Although no carcinomas of the large intestine were observed in male or female rats in the current study, adenoma of the large intestine can progress to carcinoma (NTP 2011a).

Table 4-1 Large Intestine Tumors Observed in Fischer 344/N Rats Exposed to 1-Bromopropane by Inhalation for Two Years

Sex | Conc. (ppm) | Number of Rats Surviving to Study Termination | Large Intestine Tumor (Adenoma) (% Incidence)
Sex | Conc. (ppm) | Number of Rats Surviving to Study Termination | Colon | Rectum | Colon or Rectum Combined
Male | 0 | 23 | 0/50 (0) | 0/50 (0) | 0/50 (0.0)^a,b^
Male | 125 | 26 | 0/50 (0) | 0/50 (0)^c^ | 0/50 (0.0)
Male | 250 | 18 | 0/50 (0) | 2/50 (4) | 2/50 (5.3)
Male | 500 | 13* | 1/50 (2) | 0/50 (0) | 1/50 (2.8)
Male | trend^+^ | p = 0.009^d^ | NR | NR | p = 0.197
Female | 0 | 34 | 0/50 (0) | 0/50 (0) | 0/50 (0.0)^a,b^
Female | 125 | 33 | 1/50 (2) | 0/50 (0) | 1/50 (2.3)
Female | 250 | 30 | 1/50 (2) | 1/50 (2) | 2/50 (4.7)
Female | 500 | 24 | 1/50 (2) | 4/50 (8) | 5/50 (13.3)*
Female | trend^+^ | p = 0.028^d^ | NR | NR | p = 0.004

Source: NTP (2011a).

* p ≤ 0.05 (compared with concurrent controls by Poly-3 test for tumor incidence or life-table pairwise comparisons for survival).

^+^ Determined by Poly-3 trend test.

NR = not reported.

^a^ Number of animals with tumors; (Poly-3 estimated tumor incidence percent after adjustment for intercurrent mortality).

^b^ Historical control range: 0% for inhalation studies and 0%–2% for studies by all routes.

^c^ Appendix Table A1 of the NTP Technical Report (TR 564) indicated that an adenomatous polyp was observed at this treatment dose, but the polyp was not included in the data analysis (see TR 569 [NTP 2011a], Table 9).

^d^ Survival analysis performed by life-table trend test.

Male rats had a significant increase in the incidence of malignant or benign skin tumors (keratoacanthoma; keratoacanthoma or squamous-cell carcinoma combined; and keratoacanthoma, squamous-cell carcinoma, basal-cell adenoma, or basal-cell carcinoma combined) as well as significant positive trends for these three groups of skin tumors (Table 4-2). These effects are also considered to be exposure related. Female rats had a significant positive trend for keratoacanthoma, squamous-cell papilloma, basal-cell adenoma, or basal-cell carcinoma combined, with the high-dose group (500 ppm) outside of the historical control range for inhalation studies and studies by all exposure routes, so these combined skin tumors may be exposure related. Keratoacanthomas also occurred in females, but the incidences were not increased compared with the concurrent or historical controls. Keratoacanthomas can progress to squamous-cell carcinoma, a malignant tumor; however, no squamous-cell carcinomas were identified in female rats.

Table 4-2 Skin Tumors Observed in Fischer 344/N Rats Exposed to 1-Bromopropane by Inhalation for Two Years

Sex | Conc. (ppm) | Number of Rats Surviving to Study Termination | Skin Tumors (% Incidence)^a^
Sex | Conc. (ppm) | Number of Rats Surviving to Study Termination | KA | KA or SCC Combined | KA, SCC, BCA, or BCC Combined | KA, SCP, BCA, or BCC Combined
Male | 0 | 23 | 0/50 (0.0)^b^ | 1/50 (2.4)^b^ | 1/50 (2.4)^c^ | NR
Male | 125 | 26 | 3/50 (7.4) | 4/50 (9.8) | 7/50 (17.0)* | NR
Male | 250 | 18 | 6/50 (15.4)* | 6/50 (15.4)* | 9/50 (22.6)** | NR
Male | 500 | 13* | 6/50 (16.2)** | 8/50 (21.4)** | 10/50 (26.7)** | NR
Male | trend^+^ | p = 0.009^d^ | p = 0.008 | p = 0.006 | p = 0.003 | NR
Female | 0 | 34 | 1/50 (2)^e,g^ | 1/50 (2)^g^ | 1/50 (2)^f,g^ | 1/50 (2.2)^f^
Female | 125 | 33 | 0/50 (0) | 0/50 (0) | 1/50 (2) | 1/50 (2.3)
Female | 250 | 30 | 1/50 (2) | 1/50 (2) | 1/50 (2) | 1/50 (2.4)
Female | 500 | 24 | 1/50 (2) | 1/50 (2) | 3/50 (6) | 4/50 (10.6)
Female | trend^+^ | p = 0.028^d^ | NR | NR | NR | p = 0.05

Source: NTP (2011a).

* p ≤ 0.05, **p ≤ 0.01 (compared with concurrent controls by Poly-3 test).

^+^ Determined by Poly-3 trend test.

BCA = basal-cell adenoma, BCC = basal-cell carcinoma, KA = keratoacanthoma, NR = not reported, NS = not significant, SCA = squamous-cell papilloma, SCC = squamous-cell carcinoma.

^a^ Number of animals with tumors (Poly-3 estimated tumor incidence percent after adjustment for intercurrent mortality).

^b^ Historical control range: 0%–8% for inhalation studies and 0%–16% for studies by all routes.

^c^ Historical control range: 0%–10% for inhalation studies and 0%–20% for studies by all routes.

^d^ Survival analysis performed by life-table trend test.

^e^ Historical control range: 0%–2% for inhalation studies and 0%–4% for studies by all routes.

^f^ Historical control range: 0%–2% for inhalation studies and 0%–6% for studies by all routes.

^g^ Percent incidence is overall rate (non-Poly-3 adjusted).

Male rats had a significant positive trend of malignant mesothelioma (tunica vaginalis of the epididymis) with a significant increase in tumor incidence at the high dose that was slightly greater (10.8%) than the historical control range (0% to 6%) for inhalation studies and studies by all exposure routes (Table 4-3). Therefore, these results may be exposure related. A significant increase was also observed in the incidence of malignant or benign pancreatic islet-cell tumors (adenoma and adenoma or carcinoma combined) for all exposure groups for adenoma and for 125 ppm and 250 ppm for adenoma and carcinoma combined in male rats; the incidence of adenoma and carcinoma was increased (but not statistically significant) at the highest exposure level (500 ppm). Although the tumor incidences were within the historical control range for inhalation studies and studies by all exposure routes, there was a significant positive trend for benign pancreatic islet-cell tumors (adenoma) suggesting that the tumors may have been caused by 1-bromopropane exposure. No exposure-related response of pancreatic islet-cell tumors was observed in female rats.

Table 4-3 Malignant Mesotheliomas and Pancreatic Islet-Cell Tumors Observed in Fischer 344/N Rats Exposed to 1-Bromopropane by Inhalation for Two Years

Sex | Conc. (ppm) | Number of Rats Surviving to Study Termination | Malignant Mesothelioma (% Incidence)^a,b^ | Pancreatic Islet-Cell Tumor (% Incidence)^b^
Sex | Conc. (ppm) | Number of Rats Surviving to Study Termination | Malignant Mesothelioma (% Incidence)^a,b^ | Adenoma | Carcinoma | Adenoma or Carcinoma Combined
Male | 0 | 23 | 0/50 (0.0)^c^ | 0/50 (0.0)^d^ | 3/50 (7.2)^e^ | 3/50 (7.2)^f^
Male | 125 | 26 | 2/50 (4.9) | 5/50 (12.2)* | 7/50 (17.0) | 10/50 (24.2)*
Male | 250 | 18 | 2/50 (5.2) | 4/50 (10.4)* | 5/50 (13.0) | 9/50 (23.1)*
Male | 500 | 13* | 4/50 (10.8)* | 5/50 (13.9)* | 3/50 (8.3) | 8/50 (22.2)
Male | trend^+^ | p = 0.009^g^ | p = 0.031 | p = 0.043 | p = 0.0516n | p = 0.093
Female | 0 | 34 | NR | 0/50 (0)^h,i^ | 1/50 (2)^g,h^ | 1/50 (2.2)^f^
Female | 125 | 33 | NR | 2/50 (4) | 1/50 (2) | 3/50 (6.9)
Female | 250 | 30 | NR | 1/50 (2) | 1/50 (2) | 2/50 (4.7)
Female | 500 | 24 | NR | 0/50 (0) | 0/50 (0) | 0/50 (0.0)
Female | trend^+^ | p = 0.028^g^ | NR | NR | NR | p = 0.537N

Source: NTP (2011a).

* p ≤ 0.05 (compared with concurrent controls by Poly-3 test).

^+^ Determined by Poly-3 trend test.

N = negative trend, NR = not reported.

^a^ Epididymis in all affected animals with other tissues variably affected.

^b^ Percentage reported as the adjusted rate, which takes into account the survival rate and is calculated during the Poly-3 test analysis.

^c^ Historical control ranges for inhalation studies and studies by all routes are 0%–6%.

^d^ Historical control range: 0%–12% for inhalation studies and 0%–14% for studies by all routes.

^e^ Historical control range: 2%–10% for inhalation studies and 0%–10% for studies by all routes.

^f^ Historical control range: 6%–18% for inhalation studies and 0%–18% for studies by all routes.

^g^ Survival analysis performed by life-table trend test.

^h^ Historical control range: not reported for inhalation studies and studies by all routes.

^i^ Percentage reported as the overall incidence rate (non-Poly-3 adjusted).

In female mice, there were significantly increased incidences of benign and malignant lung tumors (alveolar/bronchiolar adenoma, alveolar/bronchiolar carcinoma, and combined) with positive dose-response trends for benign lung tumors (alveolar/bronchiolar adenoma) and combined groups. Some females in the 250-ppm group had multiple adenomas and some females in all of the exposed groups had multiple carcinomas. Based on positive pairwise comparisons, positive trend data for adenoma and highly significant trend data for combined, and tumor incidences outside of historical control ranges, these results are considered to be exposure related. There was no evidence of neoplastic lesions in male mice (Table 4-4).

Table 4-4 Lung Tumors Observed in B6C3F_1_ Mice Exposed to 1-Bromopropane by Inhalation for Two Years

Sex | Conc. (ppm) | Number of Mice Surviving to Study Termination | Lung Tumors (% Incidence)^a^
Sex | Conc. (ppm) | Number of Mice Surviving to Study Termination | Alveolar/ Bronchiolar Adenoma | Alveolar/ Bronchiolar Carcinoma | Combined
Male | 0 | 37 | 6/50 (13.3)^c^ | 8/50 (17.8)^c^ | 13/50 (28.3)^c^
Male | 62.5 | 33 | 5/50 (11.5) | 7/50 (15.9)^b^ | 12/50 (27.3)
Male | 125 | 32 | 4/49 (9.0) | 10/49 (22.0)^b^ | 14/49 (30.8)
Male | 250 | 36 | 5/49 (11.9)^b^ | 10/49 (24.3)^b^ | 15/49 (35.7)
Male | trend^+^ | p = 0.934^d^ | p = 0.476N | p = 0.209 | p = 0.225
Female | 0 | 36 | 1/50 (2.2)^e^ | 0/50 (0)^f^ | 1/50 (2.2)^g^
Female | 62.5 | 40 | 6/50 (12.8) | 7/50 (14.9)** | 9/50 (19.2)**
Female | 125 | 37 | 4/50 (8.9) | 5/50 (11.1)* | 8/50 (17.8)*
Female | 250 | 42 | 10/50 (20.8)** | 4/50 (8.5) | 14/50 (29.2)***
Female | trend^+^ | p = 0.363N^d^ | p = 0.007 | p = 0.277 | p < 0.001

Source: NTP (2011a).

* p ≤ 0.05, **p ≤ 0.01, ***p ≤ 0.001 (compared with concurrent controls by Poly-3 test).

^+^ Trend of tumor incidence compared with the overall change in exposure levels by Poly-3 trend test.

N = negative trend.

^a^ Number of animals with tumors (includes multiple) (Poly-3 estimated neoplasm incidence percentage after adjustment for intercurrent mortality).

^b^ Incidence of mice with multiple lung tumors—adenoma: 0/50, 0/50, 0/50, 2/49 and carcinoma: 0/50, 2/50, 1/50, 1/50.

^c^ Historical control range: not reported for inhalation studies and studies by all routes.

^d^ Survival analysis performed by life-table trend test.

^e^ Historical control range: 2%–12% for inhalation studies and 0%–12% for studies by all routes.

^f^ Historical control range: 0%–6% for inhalation studies and 0%–12% for studies by all routes.

^g^ Historical control range: 2%–12% for inhalation studies and 2%–18% for studies by all routes.

As mentioned in Section 4.1.1, an inflammatory response was observed in rats, which could potentially be related to tumor development; however, the inflammatory response did not correlate with tumorigenicity. Chronic active and chronic suppurative inflammation were observed in the respiratory tract of both sexes of rats; however, incidences of lung and nasal tumors were not increased. In contrast, 1-bromopropane did cause lung tumors in male mice, but no chronic suppurative or chronic active inflammation of the respiratory tract was reported for either male or female mice.

## 4.3 NTP Level of Evidence Conclusion

These data meet the Report on Carcinogens criteria for sufficient evidence of carcinogenicity in experimental animals based on an increased incidence of tumors in rats and mice, at multiple tissue sites, and the occurrence of rare tumors. This conclusion is based on exposure-related neoplastic lesions in the skin of male rats, large intestines of male and female rats, and lung of female mice.