# 2 Disposition and Toxicokinetics

This section describes the overall disposition of 1-bromopropane, i.e., how it can enter the body (absorption), what happens to it once it is in the body (distribution and metabolism), how it leaves the body (excretion), and the extent and/or rates of these processes. Section 2.1 discusses the absorption, distribution, and excretion of 1-bromopropane for both humans and experimental animals, and metabolism is discussed in Section 2.2. Toxicokinetics is the mathematical description (toxicokinetic model) of the time course of disposition of a chemical in the body; however, no toxicokinetic models of 1-bromopropane were identified.

Data on disposition of 1-bromopropane are important because they can help identify the various factors that affect the toxicity of the chemical. These factors include routes and rates of absorption, tissue concentrations and their temporal changes, reactive metabolites, toxification and detoxification reactions, routes of elimination, and species differences in these factors. The mechanistic implications of these data are discussed in Section 5.

## 2.1 Absorption, Distribution, and Excretion

### 2.1.1 Absorption

Studies in humans and laboratory animals indicate that 1-bromopropane can be absorbed following inhalation, ingestion, or dermal contact, and both inhalation and dermal exposure are likely to occur in the workplace (Cheever et al. 2009; Hanley et al. 2007). Occupational exposure studies consistently reported a correlation between ambient air levels of 1-bromopropane and levels of 1-bromopropane or metabolites in urine. (See Section 1 for a description of these exposure studies.) An in vitro study of absorption characteristics of 1-bromopropane using heat-separated human epidermal membranes demonstrated that dermal penetration of 1-bromopropane could be substantial but the actual absorption depended on the type and duration of exposure (Frasch et al. 2011).

The most relevant route of exposure for 1-bromopropane based on human exposures is inhalation, and metabolism studies in rats and mice show that 1-bromopropane is absorbed following inhalation (Garner et al. 2007; Garner et al. 2006; Ishidao et al. 2002) or oral exposure (Jones and Walsh 1979; Lee et al. 2010a). In male Wistar rats exposed to 1-bromopropane vapor at either 700 or 1,500 ppm, the concentration of 1-bromopropane in blood decreased linearly with time and was below the detection limit within 0.7 hours following the end of the exposure period (Ishidao et al. 2002). This study also reported that concentrations of bromide ion (a byproduct of 1-bromopropane metabolism) in rat blood decreased much more slowly, with a half-life of 4.7 to 15 days, depending on the exposure scenario (concentration and duration of treatment) while the half-life of bromide ion excreted in the urine was 5 to 7.5 days.

### 2.1.2 Distribution

No data on distribution of 1-bromopropane in humans was identified, and only one study (Garner et al. 2006) was found that reported limited data on distribution of radiolabeled [^14^C]1-bromopropane in rats and mice after exposure by intravenous (i.v.) injection. Exhaled air, urine, and feces were collected at various intervals up to 48 hours, and blood and tissue (reported as carcass) samples were collected 48 hours post-exposure. The total radioactivity recovered ranged from 83% to 103% with the largest percentages represented by volatile organic chemicals (VOCs) (25% to 71%), CO_2_ (10% to 31%) and urine (13% to 23%). Much smaller amounts were recovered from the total carcass (2% to 6%) and feces (<1% to 4%). Limited data were reported for radioactivity in liver, and no recovery data were reported for other individual tissues that might be potential tumor sites (see Section 4). The liver to blood tissue radioactivity ratios were similar (~3) regardless of dose, and dose-normalized 1-bromopropane ng equivalents/g of liver were inversely proportional to dose in both species.

### 2.1.3 Excretion

Once absorbed, the majority of 1-bromopropane is rapidly cleared from the blood by exhalation of the unchanged compound or as either CO_2_ or VOCs, and by urinary excretion of metabolites of 1-bromopropane or the unmetabolized molecule. Only limited information is available for the excretion of 1-bromopropane in humans, but the presence of the unmetabolized molecule in urine has been described in studies of exposed workers (Ichihara et al. 2004a; Kawai et al. 2001). Excretion of unmetabolized 1-bromopropane in urine in these studies of exposed workers was significantly correlated with exposure to 1-bromopropane in air. No studies were identified that reported urinary excretion of unmetabolized 1-bromopropane in rodents. Bromide ion is also excreted, but the specificity of this ion as a biomarker for exposure to 1-bromopropane is limited because of a relatively high background from dietary sources, particularly seafood. As discussed below in the section on metabolism, several mercapturic acid derivatives of 1-bromopropane have been identified in urine from exposed humans and experimental animals. Many more metabolites or potential metabolites have been identified from experimental animal studies using labeled 1-bromopropane and these are discussed below.

Other studies in experimental animals have exposed rats or mice to radiolabeled [^14^C]1-bromopropane by intraperitoneal (i.p.) injection (Jones and Walsh 1979) or i.v. administration through the tail vein or jugular vein (Garner et al. 2006). Jones and Walsh reported that 60% of a single dose of 200 mg/kg 1-bromopropane administered to rats was exhaled unchanged within 4 hours with only trace amounts detected after that time. Only 1.4% of the total dose was exhaled as CO_2_ and about 45% of the metabolized dose was excreted in the urine after 100 hours. A much lower recovery of 3.3% of an i.p. dose of 200 mg/kg as urinary metabolites was reported by Walsh and Jones (1977) after 100 hours.

## 2.2 Metabolism

The metabolites identified in humans are limited to those recovered in the urine of factory workers after exposure to 1-bromopropane. Several studies have investigated 1-bromopropane metabolism in experimental animals, and the different metabolites identified in studies by different routes of exposure indicate that the metabolism is complex.

### 2.2.1 Metabolites Detected in Humans

Several studies have monitored urine samples from humans occupationally exposed to 1-bromopropane in order to establish biomarkers of exposure. The predominant metabolite detected in the urine of workers is N-acetyl-S-propylcysteine (AcPrCys), and levels increased with increasing 1-bromopropane ambient exposure levels (Hanley and Dunn 2006; Hanley et al. 2009; 2010; Valentine et al. 2007). In addition to AcPrCys, several other urinary mercapturic acid conjugates were identified from 1-bromopropane-exposed workers; these included N-acetyl-S-(n-propyl)-L-cysteine-S-oxide, N-acetyl-S-(2-carboxyethyl)-L-cysteine, and N-acetyl-S-(3-hydroxy-n-propyl)-L-cysteine (Cheever et al. 2009; Hanley et al. 2009). The oxidative metabolites that likely lead to the conjugates have not been reported in human studies, however no publications were identified that actually tested for them. Metabolism has been more extensively studied in experimental animals.

### 2.2.2 In Vivo Studies in Experimental Animals

Metabolism studies were conducted in rats and mice exposed by inhalation, oral, subcutaneous (s.c.), i.p., or i.v. administration and in vitro using rat liver microsomes (Barnsley et al. 1966; Garner et al. 2007; Garner et al. 2006; Jones and Walsh 1979). The four urinary mercapturic acid conjugates identified in exposed workers were also identified in experimental animals. AcPrCys was identified in the urine of rats, mice, guinea pigs, and rabbits exposed to 1-bromopropane via s.c. injection. The other metabolites were identified in the urine of rats following oral exposure. Additional urinary metabolites identified from studies in experimental animals are listed in Table 2-1, but the available studies do not agree completely with regard to metabolites detected, which might be due to differences in route of exposure, species tested, and detection methods. Overall, three major categories of metabolites have been identified: (1) brominated metabolites (Phase I), (2) debrominated metabolites (Phase I), and (3) glucuronide or glutathione conjugated metabolites (Phase II).

Table 2-1 1-Bromopropane Metabolites

Metabolite | Humans | Experimental Animals | | | In Vitro
Metabolite | Humans | Inh. | Oral | Inj. | In Vitro
N-acetyl-S-(n-propyl)-L-cysteine (AcPrCys, n-propyl mercapturic acid) | X^a^ | X^b,c^ | X^d^ | X^e,f,g^
N-Acetyl-3-(propylsulfinyl)alanine (N-acetyl-S-(n-propyl)-L-cysteine-S-oxide or n-propylmercapturic acid) | X^a^ | X^b^ | X^d^ | X^f^
N-Acetyl-S-(3-hydroxypropyl)cysteine | X^a^ | | X^d^
N-Acetyl-S-(2-carboxyethyl)cysteine | X^a^ | | X^d^
1-Bromo-2-propanol | | X^b^
Bromoacetone | | X^b^
α-Bromohydrin | | X^b^
Glycidol | | X^h^
N-Acetyl-S-(2-hydroxypropyl)cysteine (2-hydroxypropyl mercapturic acid) | | X^b^ | X^d^ | X^f,g^
N-Acetyl-S-(2-oxopropyl)cysteine | | X^b^
N-Acetyl-3-[(2-hydroxypropyl)sulfinyl]alanine | | X^b^
N-Acetyl-3-[(2-oxopropyl)sulfinyl]alanine | | X^b^
N-Acetyl-3-[(2-propenol)sulfinyl]alanine | | X^b^
2,3-Dihydroxypropylmercapturic acid | | | | X^g^
1-Bromo-2-hydroxypropane-O-glucuronide | | X^b^
3-Bromopropionic acid | | | X^d^ | X^g^ | X^d^
Propene | | | | | X^i^
n-Propanol | | | | | X^j^
1,2-Propanediol | | | | | X^i^
Propionic acid | | | | | X^i^
S-n-Propylglutathione | | | | | X^i^
S-(2-Hydroxypropyl)glutathione | | | | | X^i^
3-Hydroxypropionic acid | | | | | X^d^
S-(2-hydroxypropyl)cysteine | | | | | X^d^

Inh. = inhalation; Inj. = injection.

^a^ Hanley et al. (2009).

^b^ Garner et al. (2006).

^c^ Valentine et al. (2007).

^d^ Jones and Walsh (1979).

^e^ Grenby and Young (1959; 1960).

^f^ Barnsley et al. (1966).

^g^ Walsh and Jones (1977).

^h^ Ishidao et al. (2002).

^i^ Tachizawa et al. (1982).

^j^ Kaneko et al. (1997).

Garner et al. (2006) investigated the metabolism of 1-bromopropane in male F344 rats and B6C3F_1_ mice following inhalation or tail vein injection. These routes were selected because they do not involve first-pass metabolism and the inhalation route, specifically, is more likely to be consistent with occupational or environmental exposures compared with the oral and i.p. routes used by Jones and Walsh (1979). Much of the administered dose (40% to 70%) was exhaled unchanged. Oxidation and glutathione conjugation were the primary metabolic pathways (Figure 2-1). In both rats and mice, hydroxylation at the C_2_ position (forming 1-bromo-2-propanol) was the predominant pathway of oxidation. Although 1-bromo-2-propanol was not detected in the urine, resonances associated with unconjugated 1-bromo-2-propanol were detected in rat liver homogenates, and more than half of the urinary metabolites were derived from this metabolite. Although bromoacetone was not detected in the urine, its mercapturic acid conjugate, N-acetyl-S-(2-oxopropyl)cysteine, was detected in rats at levels approaching that of N-acetyl-S-(2-hydroxypropyl)cysteine, the mercapturic acid of 1-bromo-2-propanol. Another possible metabolite detected in rat liver homogenate was α-bromohydrin.

Figure 2-1

1-Bromopropane Metabolism in Male F344 Rats and B6C3F_1_ Mice Following Inhalation Exposure

Source: Garner et al. (2007); Garner et al. (2006). Structure in brackets is a proposed intermediate and was not isolated. FMO = flavin-containing monooxygenase, GSH = glutathione, P450 = cytochrome P450.

Urinary metabolites in rats exposed to 1-bromopropane by i.v. injection were affected by dose (Garner et al. 2006). At the low dose, AcPrCys was a relatively minor component compared with earlier eluting peaks that included N-acetyl-S-(2-hydroxypropyl)cysteine. However, the relative proportion of AcPrCys increased with dose and accounted for more than 80% of the urinary radioactivity in the high-dose group. AcPrCys is formed by direct conjugation with glutathione without oxidation (Figure 2-1). In contrast, in mice injected i.v. with 1-bromopropane, N-acetyl-S-(2-hydroxypropyl)cysteine was the single predominant metabolite at all dose levels.

A pathway overlapping in part with that described by Garner et al. (2006) was reported by Jones and Walsh (1979), who investigated the metabolism of 1-bromopropane in male Sprague-Dawley rats following five consecutive daily oral doses. Four possible metabolic pathways were identified (Figure 2-2). The first pathway involved direct conjugation with glutathione to produce the urinary metabolites AcPrCys and N-acetyl-S-propylcysteine-S-oxide. The second pathway involved oxidation at C_3_ of 1-bromopropane to 3-bromo-1-propanol. Pathway 3 was based on oxidation of C_1_ of 1-bromopropane to CO_2_ (hydrolysis to n-propanol with rapid oxidation to propionic acid and decarboxylation to CO_2_). Pathway 4 is the proposed mechanism for forming N-acetyl-S-(2-hydroxypropyl)cysteine; however, there was no direct evidence for this pathway in vivo. Several additional metabolites, including 3-bromopropionic acid and n-propanol, were identified by Jones and Walsh that were not described by Garner et al. However, as suggested by Garner et al., the difference in the observed metabolites might be explained by the analytical methods used by Jones and Walsh, which included concentration steps that could have amplified several minor metabolites (see Section 2.2.5).

Figure 2-2

Metabolic Pathways of 1-Bromopropane in Male Sprague-Dawley Rats Following Oral Exposure

Source: Jones and Walsh (1979). Compounds enclosed in brackets were not isolated from the urine.

Pathway 1: direct conjugation with glutathione; Pathway 2: oxidation at C_3_ to 3-bromo-1-propanol; Pathway 3: oxidation at C_1_ to n-propanol and then to CO_2_; Pathway 4: formation of N-acetyl-S-(2-hydroxypropyl)cysteine.

Possible reactive metabolites identified in these studies of 1-bromopropane metabolism include glycidol, α-bromohydrin, and propylene oxide (1,2-epoxypropane). Glycidol was identified in urine samples but not quantified by Ishidao et al. (2002) as a metabolite resulting from exposure of rats to 1-bromopropane by inhalation. Walsh and Jones (1977) did not detect glycidol in rats given an i.p. injection but proposed that it was a likely intermediate in formation of the urinary metabolite 2,3-dihydroxypropylmercapturic acid. Garner et al. (2007) identified α-bromohydrin as a metabolite. Propylene oxide was proposed as a likely metabolite by Ishidao et al. (2002) and by Jones and Walsh (1979), but neither group detected it in their studies. The genotoxicity and potential carcinogenicity of glycidol, α-bromohydrin, and propylene oxide are discussed in Section 5.

### 2.2.3 In Vitro Studies

Several debrominated metabolites of 1-bromopropane were identified only in studies in vitro using rat liver microsomes (see Table 2-1). Three metabolites of 1-bromopropane—propene, 1,2-propanediol, and propionic acid—were identified from the in vitro P450-catalyzed metabolism of 1-bromopropane by phenobarbital-induced rat liver microsomes; when exogenous glutathione was added to the incubation mixture, S-(1'-propyl)glutathione and S-(2'-hydroxy-1'-propyl)glutathione were detected (Tachizawa et al. 1982). In another in vitro metabolism study of 1-bromopropane by rat liver microsomes reported by Kaneko et al. (1997) only n-propyl alcohol was reported as a metabolite, but the authors noted that differences between the rate of substrate disappearance and product formation suggested that there might be other metabolic pathways.

Jones and Walsh (1979) also conducted an in vitro metabolism study of 1-bromopropane. Oxidation of carbons 2 and 3 (C_2_ and C_3_) of 1-bromopropane was demonstrated in vitro. Metabolites oxidized at C_3_ included 3-bromopropionate and 3-hydroxypropionate. Evidence for C_2_ oxidation (i.e., formation of 1-bromo-2-propanol) was provided by the isolation of S-(2-hydroxypropyl)cysteine from the reaction mixture after it was reacted with cysteine in sodium hydroxide.

### 2.2.4 Studies of Metabolizing Enzymes

It is clear from the available studies that most of the metabolites of 1-bromopropane are formed following oxidation reactions and glutathione conjugation. The proportion of 1-bromopropane metabolized via oxidation relative to pathways dependent on direct glutathione conjugation was inversely proportional to dose in rats but independent of dose in mice (Garner et al. 2006). Garner et al. concluded that formation of AcPrCys results from release of a bromide ion without oxidation. Barnsley et al. (1966) also postulated formation of S-n-propylglutathione directly from 1-bromopropane with subsequent formation of S-n-propylcysteine and AcPrCys.

The importance of the cytochromes P450 (CYP) oxidative enzymes in the metabolism of 1-bromopropane has been confirmed by the severe reduction in formation of metabolites when NADPH was eliminated from the incubation mixture with phenobarbital-induced rat liver microsomes, effectively inactivating CYP oxidation (Tachizawa et al. 1982). Pretreatment of rats with 1-aminobenzotriazole (ABT), a general inhibitor of CYP, significantly reduced the number of metabolites from 10 to 1 major metabolite, AcPrCys, which accounted for more than 90% of the total radioactivity (Garner et al. 2006). Results from a study on the induction of liver CYP isozymes in male and female Sprague-Dawley rats exposed to 1-bromopropane indicated that the expression of the CYP2E1 isozyme was enhanced while the signals for the other isozymes (CYP1A/2 and CYP2B1/2) were not, suggesting that CYP2E1 is possibly responsible for 1-bromopropane metabolism (Kim et al. 1999b). Further evidence for the specific contribution of CYP2E1 to metabolism of 1-bromopropane was provided by studies with Cyp2e1^-/-^ knockout and wild-type mice (Garner et al. 2007). Compared with wild-type mice exposed to 1-bromopropane by inhalation for 6 hours, the elimination half-life was more than twice as long in knockout mice (3.2 vs. 1.3 hours) exposed in the same way. In addition, the ratio of glutathione conjugation to 2-hydroxylation increased 5-fold, and the urinary concentration of N-acetyl-S-(2-hydroxypropyl)cysteine was reduced by about 50%. These data indicate that CYP2E1 is responsible for much, but not all, of the oxidative metabolism of 1-bromopropane since hydroxylated metabolites were significantly decreased, but not completely eliminated, in knockout mice.

The role of glutathione conjugation was also investigated using DL-buthionine(S,R)-sulfoximine 1-aminobenzotriazole (BSO), an inhibitor of GSH synthesis (Garner et al. 2006). Pretreatment with BSO did not significantly alter the metabolite profile for 1-bromopropane, although there was a moderate decrease in the level of AcPrCys with a concomitant increase in other metabolites compared with rats that were exposed to 1-bromopropane alone. The authors suggested that direct conjugation of 1-bromopropane might be a relatively minor pathway compared with oxidative metabolism in mammals.

### 2.2.5 Differences in Metabolic Pathways

Differences exist for the metabolites and metabolic pathways identified by various researchers. Possible explanations for these differences include the route of exposure, the location of the radiolabel, and other potential factors as discussed below.

The study by Jones and Walsh (1979) identified two mercapturic acid conjugates derived from metabolites oxidized at the C_3_ position (3-bromo-1-propanol and 3-bromopropionic acid) that were not detected in other studies. Jones and Walsh confirmed formation of these molecules using Udenfriend’s reagent (a mixture of iron, citric acid, EDTA, and oxygen) to oxidize 1-bromopropane in vitro; these conditions might have been too harsh and could reflect more of a chemical reaction than an in vitro metabolism study. In addition, Garner et al. (2006) proposed that Jones and Walsh (1979) might have artificially amplified these metabolites by pooling, acidifying, and concentrating a large volume of urine prior to analysis. Garner et al. (2006) also noted differences with the in vitro study of Tachizawa et al. (1982) (see Section 2.2.3). In vitro metabolism of 1-bromopropane by hepatic microsomes from phenobarbital-induced rats produced propene, 1,2-propanediol, and propionic acid; S-(1'-propyl)glutathione and S-(2'-hydroxy-1'-propyl)glutathione were detected when glutathione was added to the incubation mixture. However, none of these metabolites was detected in rat liver homogenate incubations or in experimental animal models. Garner et al. speculated that the use of phenobarbital as an inducer of CYP by Tachizawa et al. might have produced metabolites that are not normally generated by constitutively expressed CYPs.

The studies discussed here also reported large differences in the amounts of 1-bromopropane exhaled as CO_2_. The reason for this apparent discrepancy is unclear but may be attributed to the particular carbon atom that was radiolabeled. Jones and Walsh (1979) concluded that oxidation of 1-bromopropane at the C_1_ position with subsequent oxidation to propionate and decarboxylation to CO_2_ was insignificant in vivo. However, Garner et al. (2007; 2006) concluded that a large portion of the administered dose was converted to CO_2_ regardless of the exposure route and that 1-bromo-2-propanol was the ultimate source of CO_2_ (via oxidation to bromoacetone, pyruvaldehyde, and pyruvate). This was supported by a significant drop in exhaled CO_2_ in rats pretreated with the CYP inhibitor ABT and by a previous study (Bond et al. 1988) that reported that about 65% of an analogous molecule, 1-chloro-2-propanol, administered to rats was excreted as CO_2_. Bond et al. (1988) demonstrated that about 30% of the CO_2_ originated from C_3_ and about 35% originated from C_2_.

## 2.3 Synthesis and Summary

Studies in humans and laboratory animals indicate that 1-bromopropane can be absorbed following inhalation, ingestion, or dermal exposure. Occupational exposure occurs primarily by inhalation and dermal contact and studies of workers show a good correlation between urinary concentrations of 1-bromopropane, bromide ion, and N-acetyl-S-(n-propyl)-L-cysteine (AcPrCys) with their 1-bromopropane breathing zone air concentrations. Several studies have monitored urine and blood samples in workers to establish biomarkers of exposure. These studies also indicate that unmetabolized 1-bromopropane is excreted in the urine in humans but has not been reported in animal studies. The four urinary mercapturic conjugates identified from 1-bromopropane-exposed workers have also been reported as urinary metabolites from studies in rodents, including AcPrCys, N-acetyl-S-(n-propyl)-L-cysteine-S-oxide, N-acetyl-S-(2-carboxyethyl)-L-cysteine, and N-acetyl-S-(3-hydroxy-n-propyl)-L-cysteine. The oxidative metabolites that likely lead to the conjugates have not been reported in human studies; however, no publications were identified that actually tested for them.

Experimental animal studies have shown that 1-bromopropane is absorbed, rapidly distributed, and predominantly eliminated by exhalation (approximately 40% to 70%) but is also excreted in the urine and feces. In rats and mice, most of the 1-bromopropane administered by i.v. injection was exhaled unchanged or as CO_2_ within 4 hours of exposure. Urinary metabolites accounted for 13% to 23% of the administered dose after 48 hours. The available studies on 1-bromopropane metabolism show that CYP-catalyzed oxidation (primarily via CYP2E1) reactions and glutathione conjugation are the primary metabolic pathways. At least 16 urinary metabolites have been identified in rodent studies (either rats or mice), including several reactive intermediate metabolites (bromoacetone, glycidol, and α-bromohydrin).