# 1 Properties and Human Exposure

1-Bromopropane is a brominated hydrocarbon currently used as a solvent in several industrial sectors including adhesives, dry cleaning, vapor degreasing, and aerosol solvents. In recent years, occupational exposures to 1-bromopropane have increased due to new industrial and commercial applications for 1-bromopropane involving its use as a substitute for ozone-depleting chemicals or suspect carcinogens.

This section describes the chemical and physical properties of 1-bromopropane (Section 1.1); its uses and production (Section 1.2); biological indices of exposure (Section 1.3); characterization of exposure in the workplace (Section 1.4); potential for environmental exposure, including sources of release of 1-bromopropane to the environment, and its fate, occurrence, and exposure (Section 1.5); potential for exposure from other sources such as consumer products (Section 1.6); and exposure levels for people (Section 1.7). Section 1.8 summarizes the information in Sections 1.1 to 1.7. Data tables with occupational exposure to 1-bromopropane are provided in Appendix B, and include individual (e.g., personal breathing zone [PBZ], urinary biomarker, serum bromide, and exhaled breath) and area concentration measurements in various industrial sectors. U.S. regulations and guidelines that potentially limit exposure to 1-bromopropane are also reported in Appendix B.

## 1.1 Chemical Identification and Properties

1-Bromopropane (Figure 1-1) is a bromoalkane or alkyl bromide. Table 1-1 contains some chemical identification information for 1-bromopropane.

Figure 1-1

Chemical Structure of 1-Bromopropane

Table 1-1 Chemical Identification of 1-Bromopropane

Characteristic | Information
Chemical Abstracts index name | 1-Bromopropane^a^
CAS Registry number | 106-94-5^a^
Molecular formula | C_3_H_7_Br^b^
Synonyms | 1-BP^b^; Propyl bromide^b^; n-Propyl bromide^b^; Propane, 1-bromo-^b^; normal propyl bromide^c^; nPB^d^

^a^ NTP (2003a).

^b^ HSDB (2006).

^c^ UNEP (2001).

^d^ US EPA (2007b).

1-Bromopropane exists as a colorless to pale yellow liquid with a strong, characteristic odor (NTP 2011a). It is slightly soluble in water and in most organic solvents including acetone, ethanol, ether, benzene, chloroform, and carbon tetrachloride. It is less flammable than many other halogenated alkanes at room temperature. 1-Bromopropane’s thermal decomposition produces hydrogen bromide. 1-Bromopropane can react with oxidizing agents to form hazardous flammable compounds and with water to produce acids. Some physical and chemical properties for 1-bromopropane are listed in Table 1-2.

Table 1-2 Physical and Chemical Properties of 1-Bromopropane

Property | Information
Molecular weight | 123.0^b^
Melting point | −110°C^b^
Boiling point | 64.7°C^b^
Vapor pressure (mm Hg) | 110.8 at 20°C^b^
Vapor density | 4.25^a^
Specific gravity | 1.353 at 20°C^b^
Solubility in water (20°C) | 2,450 mg/L^a^
Octanol/water partition coefficient (log K_ow_) | 2.10^a^
Henry’s law constant | 0.0073 atm-m^3^/mol at 25°C^a^
Conversion factors (1-bromopropane in air)
parts per million (ppm) to µg/m^3^ | μg/m^3^ = 5,030.7 × (ppm)^c^
µg/m^3^ to parts per million (ppm) | ppm = 1.988 × 10^-4^ × (μg/m^3^)^c^

^a^ HSDB (2006).

^b^ NTP (2003a).

^c^ SMARTe.org (2012).

## 1.2 Uses and Production

1-Bromopropane is used primarily as a solvent cleaner in vapor and immersion degreasing operations to clean optics, electronics, and metals and as a solvent vehicle in industries using aerosol-applied adhesives such as foam cushion manufacturing; however, these uses might be impacted by an EPA proposed rule listing certain uses as unacceptable (see Appendix B, Table B-10). In recent years, 1-bromopropane usage has increased due to new industrial applications involving its use as a substitute for ozone-depleting chemicals or suspect carcinogens. For example, increased use of 1-bromopropane in the dry-cleaning industry has occurred in response to states considering and pursuing actions to ban the use of tetrachloroethylene (perchloroethylene or PERC) (Blando et al. 2010). 1-Bromopropane also has been reported to have other advantages as a replacement for other halogenated solvents, including lower energy costs due to lower boiling point and reduced drying time, low Global Warming Potential (GWP), and reduced water consumption (Craft 2013). 1-Bromopropane also has potential application as a spot remover in the textile industry, but an evaluation of 1-bromopropane as a substitute for trichloroethylene (TCE) concluded that chronic toxicity data were lacking and use of 1-bromopropane was not recommended until more data were available (Mirza et al. 2000). In the past, 1-bromopropane was used primarily as a solvent for fats, waxes, or resins and as an intermediate in the synthesis of pharmaceuticals, insecticides, quaternary ammonium compounds, flavors, or fragrances in generally well-controlled, closed processes (Hanley et al. 2006a; NTP 2003a).

1-Bromopropane is produced by reacting n-propyl alcohol with hydrogen bromide and then removing the water that forms in the process. 1-Bromopropane can also be produced by dehydrating propanol with bromine or hydrogen bromide in the presence of sulfur catalyst (NTP 2003a). In 2012, 1-bromopropane was manufactured by at least 21 companies worldwide, including at least one company in the United States (SRI 2012). Production data for 1-bromopropane are listed in Table 1-3. Production data are based on Internet searches of sources dated as noted; data are subject to change.

Table 1-3 Production Data for 1-Bromopropane

Category | Years Covered | Quantity in Pounds^a^
U.S. EPA Chemical Data Reporting Rule^b^ | 2006 | >1 million to 10 million
U.S. EPA Chemical Data Reporting Rule^b^ | 2002, 1998 | 1 million to <10 million
U.S. EPA Chemical Data Reporting Rule^b^ | 1994 | >500K to 1 million
U.S. EPA Chemical Data Reporting Rule^b^ | 1990, 1986 | 10K to 500K
U.S. imports (recent)^c^ | 2011 | 10.3 million
U.S. imports (historical)^c^ | 2007 | 10.9 million
U.S. exports (recent)^c^ | 2011 | 15.1 million
U.S. exports (historical)^c^ | 2007 | 8.8 million

Sources: U.S. EPA (2012); SRI (2012); USITC (2012).

^a^ From 10/2012 Internet searches; data subject to change.

^b^ Formerly called Inventory Update Rule.

^c^ Reported as brominated derivatives of acyclic hydrocarbons, which includes other chemicals in addition to 1-bromopropane.

## 1.3 Biological Indices of Exposure

Potential biological indices of exposure to 1-bromopropane include measurements of bromide ion (Br^(-)^), N-acetyl-S-(n-propyl)-L-cysteine (AcPrCys) (see Section 2.2 for a description of the metabolism of 1-bromopropane), and 1-bromopropane in urine, and serum bromide levels (Eisenberg and Ramsey 2010; Hanley et al. 2006a; Hanley et al. 2009; Kawai et al. 2001; Valentine et al. 2007). Urinary 3-bromopropionic acid (3-BPA) was not found to be an effective urinary biomarker for occupational exposure to 1-bromopropane from spray adhesives, because it was not detected in heavily exposed workers at foam cushion manufacturers. However, AcPrCys and bromide ion were effective biomarkers (Mathias et al. 2012).

## 1.4 Characterization of Exposure in the Workplace

Occupational exposure to 1-bromopropane may occur through inhalation and dermal contact at workplaces where 1-bromopropane is produced or used (HSDB 2006), and extensive 1-bromopropane occupational exposure-monitoring data are available. Many of the data either were submitted to the EPA under the Significant New Alternatives Policy (SNAP) program or collected during studies conducted under the NIOSH Health Hazard Evaluation (HHE) or Industrywide Studies Branch (IWSB) programs. (See Appendix B, Table B-1 to Table B-8 for personal samples (e.g., personal breathing zone [PBZ], urinary biomarker, serum bromide, and exhaled breath) as well as area samples for 1-bromopropane concentrations in various industrial sectors.)

Based on the available occupational exposure (as described in Table B-1 to Table B-8), 8- to 12-hr time-weighted average (TWA) 1-bromopropane air concentrations across all sectors ranged from not detected to 380 ppm. Jobs requiring workers to spray 1-bromopropane adhesives have the highest exposures and jobs requiring workers to clean and assemble small parts used in radio frequency and microwave communication instruments (vapor degreasing operations) have the lowest exposures. In extreme cases, 1-bromopropane air concentrations during vapor degreasing may be as much as four orders of magnitude lower than during adhesives use. This could be due in part to exposure to 1-bromopropane during only part of the workday. For example, Hanley et al. (2010) reported that parts were cleaned on an as-needed basis in the facilities that they sampled, and use of degreasers was limited to 90 minutes or less for an entire work shift. Figure 1-2 graphically depicts TWA 1-bromopropane air concentrations across industry sectors. The figure does not include all data for occupation exposure; thus, the highest air concentration shown is less than the maximum reported of 380 ppm.

Figure 1-2

TWA 1-Bromopropane Air Concentrations across Industry Sectors

From Eisenberg and Ramsey (2010); Graul (2012); Hanley et al. (2006b); Hanley et al. (2010); Ichihara et al. (2004a); Kawai et al. (2001). Time-weighted average 1-bromopropane exposure levels as geometric means (Adhesives, Other, and Vap. Deg.); arithmetic mean (Dry Cln.); or not reported (Manuf. and Aer. Solv.). Note: the dashed, vertical line represents the ACGIH threshold limit value-time-weighted average (TLV-TWA) of 10 ppm.

The Occupational Safety and Health Administration (OSHA) Chemical Exposure Health Dataset contains OSHA compliance monitoring program industrial hygiene samples. 1-Bromopropane concentration sampling data are available for 1998 to 2011. Of the 164 total sample points for 1-bromopropane, 126 were personal breathing zone (PBZ) samples with detectable values from 18 facilities. PBZ samples with detectable values ranged from 0.0477 to 423 ppm. Sixty-two (62) samples from 9 of the facilities were above the American Conference of Governmental Industrial Hygienists (ACGIH) threshold limit value (TLV) of 10 ppm. Most of those facilities (7 of 9) were in the vapor degreasing or adhesives use sector (OSHA 2011).

### 1.4.1 Adhesives Use

1-Bromopropane-based adhesives are used most widely as spray adhesives for foam cushion manufacturing (e.g., the furniture industry) and to a lesser extent in laminate adhesives (US EPA 2007a); however, no exposure data were identified for laminate adhesives. In furniture foam cushion manufacturing plants, cushions are generally assembled by gluing together pieces of cut flexible foam (Harney et al. 2002; Harney et al. 2003). Once the foam pieces are glued together, workers hand press the pieces to achieve a proper bond. The adhesive is spray-applied using a compressed air spray gun. Data were also identified for one adhesives and coatings manufacturer (Hanley et al. 2007; Hanley et al. 2010).

Personal samples (available data for personal breathing zone and exhaled breath concentrations for 1-bromopropane as well as urinary biomarker and serum bromide concentrations for the adhesives use sector) are provided in Appendix B, Table B-1. Eight- to twelve-hour TWA 1-bromopropane air concentrations for adhesives use ranged from 0.1 to 380 ppm. These data indicate that workers engaged in adhesive spraying are consistently exposed to higher concentrations than non-sprayers, in some cases by as much as three orders of magnitude. The higher exposures are reflected in higher levels of urinary biomarkers for both urinary Br^(-)^ (Hanley et al. 2006a) and urinary AcPrCys concentrations (Hanley et al. 2009).

Pre- and post-shift 1-bromopropane breath concentrations have been measured for adhesives use. Available breath monitoring data indicate that post-shift 1-bromopropane concentrations were consistently higher than pre-shift concentrations, in many cases, more than 10 times higher. For example, Hanley et al. (2005) reported a pre-shift mean breath concentration of 0.96 ppm and a post-shift mean breath concentration of 15.4 ppm for a polyurethane seat cushion manufacturing plant. Further, breath concentrations for sprayers were consistently higher than concentrations for workers performing other jobs.

Serum bromide concentration data indicated that concentrations are highest in the adhesives sector, for which values as high as 1,700 mg/L have been reported (Majersik et al. 2007) (see Appendix B, Table B-1. Adhesives Applications – Personal Samples of 1-Bromopropane in Air, Urinary Biomarkers (AcPrCys and Br), and 1‑Bromopropane in Blood and Exhaled Air). Based on NIOSH HHE data for one facility, the average difference between end-of-week and start-of-week serum bromide concentrations for exposed workers was 23 mg/L compared with 3 mg/L for unexposed workers (Harney et al. 2003).

1-Bromopropane air concentrations differed considerably before and after engineering controls (i.e., ventilation improvements, enclosure of spray tables, etc.) were implemented at two facilities studied in the NIOSH HHE program. Figure 1-3 depicts 1-bromopropane air concentrations for first and second NIOSH facility surveys for the three known facilities in the adhesives use sector at which NIOSH conducted HHE assessments. In two cases (Custom Products and STN Cushion Company), the facilities adopted NIOSH recommendations concerning addition of engineering controls and TWAs decreased by 80% or greater. The results demonstrated reductions of mean TWA 1-bromopropane air concentration from 168.9 ppm (N = 69) to 19.0 ppm (N = 30) for all workers at Custom Products Inc. and from 65.9 ppm (N = 12) to 16.6 ppm (N = 11) for sprayers at STN Cushion Company (Reh et al. 2002).

Figure 1-3

1-Bromopropane Air Concentrations for First and Second NIOSH Facility Surveys in the Adhesives Use Sector

TWA concentrations reported for Custom Products, Inc. and STN Cushion Company are arithmetic means, and those reported for Marx Industries, Inc. are geometric means.

NIOSH also recommended similar controls for the third facility (Marx Industries), but the agency reported that they were unaware of any changes in controls or employee use of personal protective equipment during the time interval between the first and second survey for this facility, and only slight change in exposure for sprayers occurred between the first and second surveys. The mean TWA 1-bromopropane air concentration for all sprayers for the first survey (N = 12) was 107.6 ppm, and the mean for the second survey (N = 8) was 101.4 ppm (Harney et al. 2003).

According to a summary of workplace exposure data for 1-bromopropane submitted to EPA for the SNAP program (Graul 2012), initially, fewer than half the personal breathing zone (PBZ) sample concentrations were below 50 ppm (8-hr TWA); however, after ventilation improvements, 97% of the PBZ samples were less than 50 ppm and 78% were ≤25 ppm. Further, the initial mean concentration was 141.7 ppm; after ventilation improvements, the mean concentration was 18.3 ppm (Graul 2012).

Concentration measurements for the adhesives use sector are shown in Appendix B, Table B-2. Adhesives Applications – Area Samples. Area samples for 1-bromopropane for adhesives use ranged from 0.01 to 176 ppm. The range of area samples reflects variation between facilities; however, differences within a facility appear to vary only minimally for the same task.

### 1.4.2 1-Bromopropane Manufacturing

Personal samples (from the available data for personal breathing zone concentrations of 1-bromopropane) for the manufacturing sector in China are provided in Appendix B, Table B-3. No 1-bromopropane air concentration data were identified for 1-bromopropane manufacturing plants in the United States, but Patent Number 5,773,672 (June 30, 1998), which is assigned to a U.S. manufacturer of 1-bromopropane, contains descriptions of numerous control processes to contain 1-bromopropane in contrast with the more open processes described below. Eight- to twelve-hour TWA 1-bromopropane air concentrations for these facilities ranged from not detected to 170 ppm. Worker exposure was reported to occur from (1) adding chemicals into reaction pots, (2) sitting close to reaction pots when observing and recording the temperature, (3) removing crude product, (4) adding hydrogen carbonate and stirring, and (5) pouring the product into 1,000 L drums (Li et al. 2010c). In one plant, the highest concentrations were measured during the transfer of processed product into containers (Ichihara et al. 2004a).

Area sample concentrations of 1-bromopropane for 1-bromopropane manufacturing ranged from not detected to 90.2 ppm (see Appendix B, Table B-4).

One study also examined biomarkers of 1-bromopropane exposure. Valentine et al. (2007) measured globin S-propylcysteine (PrCys) adducts and urinary N-acetyl-S-propylcysteine (N-acetyl-S-(n-propyl)-L-cysteine or AcPrCys) for workers in a Chinese 1-bromopropane manufacturing facility and reported a significant (p < 0.01) increase in PrCys adducts on 1-bromopropane manufacturing workers’ globin (1.52 pmol/mg globin) compared with control factory workers (0.11 pmol/mg globin) (N = 32 controls, N = 26 exposed). Further, Valentine et al. (2007) determined that urinary AcPrCys levels increased as 1-bromopropane ambient exposure levels increased (N = 47 exposed); the exposure levels ranged from 0 to 170.54 ppm.

### 1.4.3 Dry Cleaning

The increased use of 1-bromopropane in the dry-cleaning industry has occurred in response to states considering and pursuing actions to ban the use of PERC (Blando et al. 2010). 1-Bromopropane has been reported to be the only PERC alternative that can be used in the original PERC machines with alterations; other cleaners would require the purchase of new machines (Eisenberg and Ramsey 2010).

Personal full- and partial-shift samples (available data for personal breathing zone concentrations of 1-bromopropane) for the dry-cleaning sector are provided in Appendix B, Table B-5. Eight- to twelve-hour TWA 1-bromopropane air concentration data identified in these dry-cleaning facilities ranged from <0.004 to 56 ppm. Eisenberg and Ramsey (2010) reported a mean serum bromide concentration of 144 mg/L for a dry-cleaning facility owner who was converting his machine from PERC to 1-bromopropane (value reported as 144 mcg/mL). Worker exposure could occur from introduction of solvent to the cleaning machine, machine maintenance, unloading and handling of recently cleaned clothes, interrupting the machine wash cycle, and “cooking” the solvent (i.e., boiling the solvent to remove impurities) (Blando et al. 2010; Eisenberg and Ramsey 2010). Further, exposure could occur due to leaks resulting from normal machine wear with time, poor maintenance, and incompatibility of 1-bromopropane with system gasket materials and poor ventilation (Blando et al. 2010).

Reduced exposure due to improved ventilation procedures also has been illustrated for dry-cleaning applications. For example, Blando et al. (2010) (see Appendix B, Table B-6) noted that building size, exhaust fan capacity and operation, and natural ventilation (i.e., opening doors and windows) were the determining factors for operator air concentrations in two of the three shops studied differing by as much as 4 orders of magnitude. Other studies have shown that dry cleaning operators often use natural ventilation (i.e., opening doors and windows) to control 1-bromopropane exposures. However, weather conditions may prevent use of natural ventilation (Eisenberg and Ramsey 2010), which typically is not as effective as mechanical ventilation.

Area sample concentrations for 1-bromopropane for dry cleaning ranged from <0.004 to 170 ppm and differences were mainly explained by characteristics of the individual facilities (see Appendix B, Table B-6). Area samples at Facility 1 in Eisenberg and Ramsey (2010) varied between morning and afternoon measurements. Measurements taken in the morning were higher because the facility closed the doors and did not operate the ventilation system at this time; only the front windows were open. However, in the afternoon, the facility operated the ventilation system and opened the back door. Variation in area samples at Facility 4 in Eisenberg and Ramsey (2010) might have been due to machine leaks as the owner converted the machine himself and reported that he had difficulties finding the correct conversion materials. Further, opening the front door and operating the exhaust fan produced a marked decrease in solvent odor at this facility (Eisenberg and Ramsey 2010). Findings reported by Blando et al. (2010) for dry-cleaning Shops A, B, and C were discussed above.

### 1.4.4 Aerosol Solvents

1-Bromopropane has been reported to be used as a solvent in aerosol lubricants, coatings, or cleaning fluids for electrical or electronic equipment or aircraft maintenance, or in spinnerette lubricants and cleaning sprays used in synthetic fiber production (US EPA 2007a). Spray-can aerosol solvents are normally used intermittently and for short periods of time (i.e., 1 to 2 minutes). In some cases, aerosol products are used in confined spaces without ventilation or fans where short-term worker exposure can be high. Although emissions from aerosol solvents typically are not controlled via engineering controls, aerosol users can reduce exposure levels through use of fume hoods and improving ventilation (US EPA 2003). Eight- to twelve-hour TWA 1-bromopropane air concentration data identified for aerosol solvents ranged from 5 to 30.2 ppm (Graul 2012). Fifteen-minute STEL sample data ranged from 45.1 to 254 ppm.

### 1.4.5 Vapor Degreasing

In general, vapor degreasers use a refrigerated cooling coil around the top of the interior of the vapor chamber to condense heated 1-bromopropane vapor into liquid droplets on the cooler surface of parts to remove dirt, grease, and surface contaminants (Hanley and Dunn 2006). Excess 1-bromopropane drips back into the solvent sump and is recycled as the parts ascend from the vapor to condensing zones. Another function of the cooling coil is to control solvent vapor emissions by “capping” the heated vapor zone with a refrigerated air space.

For the vapor degreasing sector, personal samples of 1-bromopropane are provided in Appendix B, Table B-7. Eight- to twelve-hour GM TWA 1-bromopropane air concentration for vapor degreasing ranged from 0.077 to 21 ppm. In Hanley et al. (2010), workers near degreasers had personal breathing zone TWA 1-bromopropane concentrations higher (GM = 2.6 ppm) than workers away from degreasers (GM = 0.31 ppm), and urinary bromide and AcPrCys concentrations showed the same trend.

A NIOSH HHE was conducted at a facility that used 1-bromopropane below its boiling point as a vapor degreaser (Reh and Nemhauser 2001). Eight- to twelve-hour TWA 1-bromopropane air concentration data for this facility ranged from 0.01 to 0.63 ppm. Fifteen-minute sample data identified ranged from 2.3 to 8.4 ppm. This facility’s cleaning system was located in a special, enclosed room with a local exhaust ventilation system (US EPA 2003). The design of most vapor degreasers reduces emissions from equipment because the solvent is boiled and subsequently condensed rather than allowing vapors to be emitted. In general, it is expected to be more difficult to control emissions from cleaning equipment in which the solvent is not boiled and condensed (US EPA 2003). Both cleaning methods could benefit from the installation of well-maintained, effective local exhaust ventilation systems as these are the preferred method of solvent emission control.

A summary of 500 personal samples for vapor degreasing by Graul (2012) reported that >87% of the personal samples were below 25 ppm on an 8-hour TWA basis and approximately 75% of those samples were below 10 ppm on an 8-hour TWA basis.

1-Bromopropane emissions exposure to vapor degreasing workers can be reduced through changes in equipment and operating practices (Hanley and Dunn 2007; US EPA 2003). For example, additional condensation coils can be installed to prevent vapors from leaving the degreaser. Further, workers can tilt pieces to be cleaned to increase solvent drainage inside the vapor degreaser instead of leaving 1-bromopropane on the pieces to evaporate outside the degreaser where workers can inhale the vapors. A mechanical hoist operated at a controlled rate is also advantageous so that workers cannot raise the parts basket too quickly, which may circumvent effective vapor control of the condensing zone.

Area sample concentrations for 1-bromopropane for vapor degreasing ranged from 0.02 to 4.42 ppm (see Appendix B, Table B-8). These measurements indicate that the highest concentrations are found in areas near degreasers and lower concentrations are in areas away from degreasers.

### 1.4.6 Cleaning and Painting Workshops

In a study of 33 workers in a cleaning and painting workshop using 1-bromopropane cleaning solvents in a Japanese factory, Kawai et al. (2001) reported a geometric mean 1-bromopropane concentration of 1.42 ppm and a maximum concentration of 27.8 ppm.

## 1.5 Potential for Environmental Exposure

### 1.5.1 Release of 1-Bromopropane to the Environment

Based on the production and use of 1-bromopropane it may be released to the environment through various waste streams. 1-Bromopropane has also been detected in temperate marine macroalgae tissue and is believed to be transported from these algae to the marine environment. (HSDB 2006).

In a search of the National Response Center database for the time period of January 1, 1990 to the present, “1-bromopropane” identified three chemical spill incidents and “n-propyl bromide” identified one incident (National Response Center 2012). No Toxics Release Inventory (TRI) data for 1-bromopropane were identified, since 1-bromopropane is not included on the TRI list of toxic chemicals (US EPA 2011).

### 1.5.2 Fate, Occurrence, and Exposure

No data have been identified indicating the measurement of 1-bromopropane in ambient air, drinking water, surface water, soil, or food. EPA has estimated 1-bromopropane concentrations in ambient air at a distance of 100 meters from average-adhesive use model facilities via air dispersion modeling to be 0.138 mg/m^3^ [0.0274 ppm] and 1.38 mg/m^3^ [0.274 ppm] for high-adhesive use facilities (Wolf et al. 2003). EPA also has estimated daily uptake from 1-bromopropane in the environment from inhalation for a person living 100 meters from average-adhesive use model facilities to be 0.0537 mg/kg-day and 0.537 mg/kg-day from high-adhesive use facilities.

Investigation of a wastewater tank leak at a Swiss alkyl halide factory that manufactured 1-bromopropane at quantities reported as greater than 5 tons/year did not identify any 1-bromopropane or its alcohol metabolite in groundwater after clean up (Schwarzenbach et al. (1985), as cited by NTP (2003a)).

## 1.6 Potential for Exposure from Other Sources: Consumer Products

No 1-bromopropane concentration measurement data for consumer products have been identified. Knöppel and Schauenburg (1989) analyzed VOC emissions of household wax, liquid pastes, and detergents, and 1-bromopropane was included in the list of analytes; however, 1-bromopropane was used as an internal standard in that study and the authors did not report it as being present in the consumer products (HSDB 2006).

## 1.7 Exposure Levels for People

No data for non-occupational 1-bromopropane exposure levels for people have been identified.

## 1.8 Synthesis and Summary

A significant number of people in the United States are exposed to 1-bromoproane as a result of widespread usage, high-production volume, and exposure to high levels of 1-bromopropane in commercial and industrial settings. The principal uses of 1-bromopropane are as a solvent cleaner in vapor and immersion degreasing operations to clean optics, electronics, and metals, as a solvent vehicle in industries that use aerosol-applied adhesives such as foam cushion manufacturing, and as a textile solvent in the dry-cleaning industry. In recent years, certain 1-bromopropane uses have increased because it is an alternative to ozone-depleting chemicals or suspect carcinogens; e.g., 1-bromoprane has been used as an alternative to PERC (listed as reasonably anticipated to be a human carcinogen in the RoC) in the dry-cleaning industry.

Inhalation is the primary route of human exposure; dermal exposure is also possible. 1-Bromopropane is a high-production-volume chemical with annual production ranging from 1 million to 10 million pounds as reported in 1998, 2002, and 2006. Based on occupational exposure data across several industrial sectors, 8- to 12-hour time-weighted average (TWA) 1-bromopropane air concentrations ranged from not detected to 380 ppm. 1-Bromopropane air concentrations are highest for adhesives use and lowest for vapor degreasing. In extreme cases, vapor degreasing 1-bromopropane air concentrations may be as much as four orders of magnitude lower than adhesives use concentrations.

No data have been identified indicating measurable levels of 1-bromopropane in ambient air, drinking water, surface water, soil, or food. However, the EPA has estimated via air dispersion modeling that 1-bromopropane may be present in ambient air, and daily intake from exposure in the environment may occur, particularly for people who live near industrial and commercial users of 1-bromopropane.