# Abbreviations

  1-BP: 1-bromopropane
  3-BPA: 3-bromopropionic acid
  ABT: 1-aminobenzotriazole
  ACGIH: American Conference of Governmental Industrial Hygienists
  AcPrCys: N-acetyl-S-(n-propyl)-L-cysteine
  ADD: average daily dose
  ALT: serum alanine aminotransferase, alanine aminotransferase
  ANOVA: analysis of variance
  AST: serum aspartate aminotransferase, aspartate aminotransferase
  atm: atmosphere
  BSO: DL-buthionine (S,R)-sulfoximine
  CDC: Centers for Disease Control and Prevention
  CERHR: Center for the Evaluation of Risks to Human Reproduction
  cm^2^: square centimeter
  COX-2: cyclooxygenase-2
  DBCP: 1,2-dibromo-3-chloropropane
  DLMI: dominant lethal mutation index
  DLMR: dominant lethal mutation rate
  EQ: exposure quartiles model
  FDA: Food and Drug Administration
  FR: Federal Register
  ft: feet
  GC/MS: gas chromatography/mass spectrometry
  GSH: glutathione
  GSSH: oxidized glutathione
  GST: glutathione-S-transferase
  HHE: Health Hazard Evaluation
  HHS: Department of Health and Human Services
  HIC: highest ineffective concentration
  HID: highest ineffective dose
  HO-1: heme oxygenase-1
  hr: hour
  in: inch
  i.s.: internal standard
  iNOS: inducible nitric oxide synthases
  L: liter
  LEC: lowest effective concentration
  LED: lowest effective dose
  m^3^: cubic meter
  mg: milligram
  MMWR: Morbidity and Mortality Weekly Report
  MN: micronuclei
  mol: mole
  NCE: normochromatic erythrocyte
  NCTR: National Center for Toxicological Research
  ND: not done
  NIC: Notices of Intended Changes
  NIEHS: National Institute of Environmental Health Sciences
  NIH: National Institutes of Health
  NIOSH: National Institute for Occupational Safety and Health
  nPB: normal propyl bromide
  NQO1: NAD(P)H:quinone oxidoreductase
  NR: not reported
  NS: non-sprayer
  NTP: National Toxicology Program
  OHAT: Office of Health Assessment and Translation
  OSHA: Occupational Safety and Health Administration
  PBZ: personal breathing zone
  PCE: polychromatic erythrocyte
  PEL: permissible exposure limit
  PERC: tetrachloroethylene (perchloroethylene)
  PGE_2_: prostaglandin E_2_
  ppm: parts per million
  PrCys: S-propylcysteine
  r: correlation coefficient
  RoC: Report on Carcinogens
  RTG: relative total growth
  s.c.: subcutaneous
  SD: standard deviation
  SNAP: Significant New Alternatives Policy
  Solv.: aerosol solvents use
  SP: sprayer
  TBARS: thiobarbituric acid-reactive substance
  TLV: threshold limit value
  TM: tail moment
  TMD: tail moment dispersion coefficient
  TWA: time-weighted average
  VOC: volatile organic compound
  µg: microgram