# References

Anders MW. 1982 a. Mechanisms of haloalkane and haloalkene biotransformation. Trends Pharmacol Sci. 3(C):356–357. 10.1016/0165-6147(82)91182-8
Anders MW. 1982 b. Bioactivation of halogenated hydrocarbons. J Toxicol Clin Toxicol. 19(6-7):699–706. 10.3109/15563658208990399 7161850
Anders MW. 2001. Formation and fate of reactive intermediates of haloalkanes, haloalkenes, and alpha-haloacids. Adv Exp Med Biol. 500:113–120. 10.1007/978-1-4615-0667-6_12 11764921
Anderson LM, Rice JM. 1987. Tumorigenesis in athymic nude mouse skin by chemical carcinogens and ultraviolet light. J Natl Cancer Inst. 78(1):125–134. 10.1093/jnci/78.1.125 3099050
Anderson SE, Munson AE, Butterworth LF, Germolec D, Morgan DL, Roycroft JA, Dill J, Meade BJ. 2010. Whole-body inhalation exposure to 1-bromopropane suppresses the IgM response to sheep red blood cells in female B6C3F1 mice and Fisher 344/N rats. Inhal Toxicol. 22(2):125–132. 10.3109/08958370902953910 20041805
Barber ED, Donish WH, Mueller KR. 1981. A procedure for the quantitative measurement of the mutagenicity of volatile liquids in the Ames salmonella/microsome assay. Mutat Res. 90(1):31–48. 10.1016/0165-1218(81)90048-3 7029269
Barnsley EA, Grenby TH, Young L. 1966. Biochemical studies of toxic agents. The metabolism of 1- and 2-bromopropane in rats. Biochem J. 100(1):282–288. 10.1042/bj1000282 5965256
Beeley JG, Neurath H. 1968. The reaction of trypsin with bromoacetone. Biochemistry. 7(3):1239–1251. 10.1021/bi00843a047 5690563
Blando JD, Schill DP, De La Cruz MP, Zhang L, Zhang J. 2010. Preliminary study of propyl bromide exposure among New Jersey dry cleaners as a result of a pending ban on perchloroethylene. J Air Waste Manag Assoc. 60(9):1049–1056. 10.3155/1047-3289.60.9.1049 20863050
Bond JA, Birnbaum LS, Dahl AR, Medinsky MA, Sabourin PJ, Henderson RF. 1988. Disposition of inhaled 1-chloro-2-propanol in F344/N rats. Toxicol Appl Pharmacol. 95(3):444–455. 10.1016/0041-008X(88)90362-6 3142098
Centers for Disease Control and Prevention (CDC). 2008. 1-BP: A Potential Occupational Hazard. Atlanta, GA: Centers for Disease Control and Prevention. https://blogs.cdc.gov/niosh-science-blog/2008/12/1bp/. [Accessed: February 8, 2012]
Centers for Disease Control and Prevention (CDC). 2010. Pocket guide: Methyl bromide. Atlanta, GA: Centers for Disease Control and Prevention. https://www.cdc.gov/niosh/npg/npgd0400.html. [Accessed: December 6, 2012]
Chanas B, Wang H, Ghanayem BI. 2003. Differential metabolism of acrylonitrile to cyanide is responsible for the greater sensitivity of male vs female mice: Role of CYP2E1 and epoxide hydrolases. Toxicol Appl Pharmacol. 193(2):293–302. 10.1016/j.taap.2003.08.006 14644629
Cheever KL, Marlow KL, B'Hymer C, Hanley KW, Lynch DW. 2009. Development of an HPLC-MS procedure for the quantification of N-acetyl-S-(n-propyl)-l-cysteine, the major urinary metabolite of 1-bromopropane in human urine. J Chromatogr B Analyt Technol Biomed Life Sci. 877(8-9):827–832. 10.1016/j.jchromb.2009.02.010
Chovanec M, Cedervall B, Kolman A. 2001. DNA damage induced by gamma-radiation in combination with ethylene oxide or propylene oxide in human fibroblasts. Chem Biol Interact. 137(3):259–268. 10.1016/S0009-2797(01)00258-7 11566293
Cook MB, Dawsey SM, Freedman ND, Inskip PD, Wichner SM, Quraishi SM, Devesa SS, McGlynn KA. 2009. Sex disparities in cancer incidence by period and age. Cancer Epidemiol Biomarkers Prev. 18(4):1174–1182. 10.1158/1055-9965.EPI-08-1118 19293308
Couch R, Ehrenberg L, Magnusson AL, Nilsson R, de la Rosa ME, Törnqvist M. 1996. In vivo dosimetry of ethylene oxide and propylene oxide in the cynomolgus monkey. Mutat Res. 357(1-2):17–23. 10.1016/0027-5107(96)00066-8 8876676
Craft TD. 2013. Letter to R. Linn, National Toxicology Program, Research Triangle Park, NC from T.D. Craft, Albemarle Corporation, Baton Rouge, LA, March 7, 2013.
Czene K, Osterman-Golkar S, Yun X, Li G, Zhao F, Pérez HL, Li M, Natarajan AT, Segerbäck D. 2002. Analysis of DNA and hemoglobin adducts and sister chromatid exchanges in a human population occupationally exposed to propylene oxide: A pilot study. Cancer Epidemiol Biomarkers Prev. 11(3):315–318. 11895884
DePry JL, Reed KB, Cook-Norris RH, Brewer JD. 2011. Iatrogenic immunosuppression and cutaneous malignancy. Clin Dermatol. 29(6):602–613. 10.1016/j.clindermatol.2011.08.009 22014982
Dröge W, Breitkreutz R. 2000. Glutathione and immune function. Proc Nutr Soc. 59(4):595–600. 10.1017/S0029665100000847 11115795
Dröge W, Schulze-Osthoff K, Mihm S, Galter D, Schenk H, Eck HP, Roth S, Gmünder H. 1994. Functions of glutathione and glutathione disulfide in immunology and immunopathology. FASEB J. 8(14):1131–1138. 10.1096/fasebj.8.14.7958618 7958618
Edgren G, Liang L, Adami HO, Chang ET. 2012. Enigmatic sex disparities in cancer incidence. Eur J Epidemiol. 27(3):187–196. 10.1007/s10654-011-9647-5 22212865
Eisenberg J, Ramsey J. 2010. Evaluation of 1-bromopropane use in four New Jersey commercial dry cleaning facilities. Washington, DC: National Institute for Occupational Safety and Health. Health Hazard Evaluation Report HETA 2008-0175-3111.
El Ramy R, Ould Elhkim M, Lezmi S, Poul JM. 2007. Evaluation of the genotoxic potential of 3-monochloropropane-1,2-diol (3-MCPD) and its metabolites, glycidol and β-chlorolactic acid, using the single cell gel/comet assay. Food Chem Toxicol. 45(1):41–48. 10.1016/j.fct.2006.07.014 16971032
Elf Atochem. 1994. Ames test--reverse mutation assay on Salmonella typhimurium. N-propyl bromide. Study performed by Sanofi Recherche. Service de Toxicologie. HIS1005/1005A.
Elf Atochem. 1995. Acute dermal toxicity in rats. N-propyl bromide. Miserey, France: Study Director, Stephane de Jouffrey. Centre International de Toxicologie. Study No. 13113 Tar.
Elf Atochem. 1996. In vitro mammalian cell gene mutation test in L5178Y TK+/- mouse lymphoma cells of n-propyl bromide. Miserey, France: Study Director, B. Molinier. Centre International de Toxicologie. Study No. 13293.
ESIS Environmental Health Lab (EHL). 2012. 2012 ACGIH TLV updates: March 2012 newsletter. Cromwell, CT: ESIS Environmental Health Lab.
Fabiani R, Rosignoli P, De Bartolomeo A, Fuccelli R, Morozzi G. 2012. Genotoxicity of alkene epoxides in human peripheral blood mononuclear cells and HL60 leukaemia cells evaluated with the comet assay. Mutat Res. 747(1):1–6. 10.1016/j.mrgentox.2012.01.004 22285587
Frasch HF, Dotson GS, Barbero AM. 2011. In vitro human epidermal penetration of 1-bromopropane. J Toxicol Environ Health A. 74(19):1249–1260. 10.1080/15287394.2011.595666 21830855
Fueta Y, Fukuda T, Ishidao T, Hori H. 2004. Electrophysiology and immunohistochemistry in the hippocampal CA1 and the dentate gyrus of rats chronically exposed to 1-bromopropane, a substitute for specific chlorofluorocarbons. Neuroscience. 124(3):593–603. 10.1016/j.neuroscience.2003.12.025 14980730
Fueta Y, Fukunaga K, Ishidao T, Hori H. 2002 a. Hyperexcitability and changes in activities of Ca^2+^/calmodulin-dependent kinase II and mitogen-activated protein kinase in the hippocampus of rats exposed to 1-bromopropane. Life Sci. 72(4-5):521–529. 10.1016/S0024-3205(02)02247-6 12467892
Fueta Y, Ishidao T, Arashidani K, Endo Y, Hori H. 2002 b. Hyperexcitability of the hippocampal CA1 and the dentate gyrus in rats subchronically exposed to a substitute for chlorofluorocarbons, 1-bromopropane vapor. J Occup Health. 44(3):156–165. 10.1539/joh.44.156
Fueta Y, Ishidao T, Ueno S, Yoshida Y, Kunugita N, Hori H. 2007. New approach to risk assessment of central neurotoxicity induced by 1-bromopropane using animal models. Neurotoxicology. 28(2):270–273. 10.1016/j.neuro.2006.05.003 16782201
Garner CE, Sloan C, Sumner SC, Burgess J, Davis J, Etheridge A, Parham A, Ghanayem BI. 2007. CYP2E1-catalyzed oxidation contributes to the sperm toxicity of 1-bromopropane in mice. Biol Reprod. 76(3):496–505. 10.1095/biolreprod.106.055004 17093198
Garner CE, Sumner SC, Davis JG, Burgess JP, Yueh Y, Demeter J, Zhan Q, Valentine J, Jeffcoat AR, Burka LT, et al. 2006. Metabolism and disposition of 1-bromopropane in rats and mice following inhalation or intravenous administration. Toxicol Appl Pharmacol. 215(1):23–36. 10.1016/j.taap.2006.01.010 16513153
Ghanayem BI, Hoffler U. 2007. Investigation of xenobiotics metabolism, genotoxicity, and carcinogenicity using Cyp2e1(-/-) mice. Curr Drug Metab. 8(7):728–749. 10.2174/138920007782109760 17979661
Golomb BA. 1999. Does accumulation of the bromide from PB produce bromism? In: A Review of the Scientific Literature as it Pertains to Gulf War Illness: Volume 2: Pyridostigmine Bromide. Santa Monica, CA: RAND Corporation. p. 131.
Graul F. 2012. Summary of data on workplace exposure to n-propyl bromide.
Grenby TH, Young L. 1959. Isolation of n-propylmercapturic acid from the urine of animals dosed with 1-bromopropane. Biochem J. 71:25.
Grenby TH, Young L. 1960. Biochemical studies on toxic agents. 12. The biosynthesis of n-propylmercapturic acid from n-propyl halides. Biochem J. 75:28–33. 10.1042/bj0750028 13829194
Guo TL, McCay JA, Brown RD, Musgrove DL, Butterworth L, Munson AE, Germolec DR, White KL Jr. 2000. Glycidol modulation of the immune responses in female B6C3F1 mice. Drug Chem Toxicol. 23(3):433–457. 10.1081/DCT-100100127 10959546
Guyton KZ, Kyle AD, Aubrecht J, Cogliano VJ, Eastmond DA, Jackson M, Keshava N, Sandy MS, Sonawane B, Zhang L, et al. 2009. Improving prediction of chemical carcinogenicity by considering multiple mechanisms and applying toxicogenomic approaches. Mutat Res. 681(2-3):230–240. 10.1016/j.mrrev.2008.10.001 19010444
Han EH, Hwang YP, Lee KJ, Jeong TC, Jeong HG. 2008. 1-Bromopropane induces macrophage activation via extracellular signal-regulated kinase 1/2 MAPK and NF-κB pathways. Cancer Lett. 262(1):28–36. 10.1016/j.canlet.2007.11.024 18164123
Han EH, Yang JH, Kim HK, Choi JH, Khanal T, Do MT, Chung YC, Lee KY, Jeong TC, Jeong HG. 2012. 1-Bromopropane up-regulates cyclooxygenase-2 expression via NF-κB and C/EBP activation in murine macrophages. Food Chem Toxicol. 50(5):1616–1622. 10.1016/j.fct.2012.02.006 22353212
Hanley K, Curwin B, Sanderson W, Johnson B. 2005. Workers’ exposures to n-propyl bromide in two foam fabricating plants manufacturing furniture polyurethane seat cushions in North Carolina. Washington, DC: National Institute for Occupational Safety and Health. IWSB 232.10.
Hanley KW, Dunn K. 2006. Workers’ exposures to n-propyl bromide at a helicopter transmission factory. Washington, DC: National Institute for Occupational Safety and Health. IWSB 232.11.
Hanley KW, Dunn K, Sollberger R. 2006b. Workers’ exposures to n-propyl bromide at an aerospace components manufacturer. Washington, DC: National Institute for Occupational Safety and Health. IWSB 232.12.
Hanley KW, Dunn KL. 2007. Workers’ exposures to n-propyl bromide at an optical prism and optical assemblies manufacturer. Washington, DC: National Institute for Occupational Safety and Health. IWSB 232.15.
Hanley KW, Dunn KL, Johnson B. 2007. Workers’ exposures to n-propyl bromide at an adhesives and coatings manufacturer. Washington, DC: National Institute for Occupational Safety and Health. IWSB 232.16.
Hanley KW, Johnson B. 2007a. Workers’ exposures to n-propyl bromide at a printed electronics circuit assembly manufacturer. Washington, DC: National Institute for Occupational Safety and Health. IWSB 232.14.
Hanley KW, Johnson B. 2007b. Workers’ exposures to n-propyl bromide at a hydraulic power control component manufacturer. Washington, DC: National Institute for Occupational Safety and Health. IWSB 232.13.
Hanley KW, Petersen M, Curwin BD, Sanderson WT. 2006 a. Urinary bromide and breathing zone concentrations of 1-bromopropane from workers exposed to flexible foam spray adhesives. Ann Occup Hyg. 50(6):599–607. 16698849
Hanley KW, Petersen MR, Cheever KL, Luo L. 2009. N-acetyl-S-(n-propyl)-l-cysteine in urine from workers exposed to 1-bromopropane in foam cushion spray adhesives. Ann Occup Hyg. 53(7):759–769. 19706636
Hanley KW, Petersen MR, Cheever KL, Luo L. 2010. Bromide and N-acetyl-S-(n-propyl)-L-cysteine in urine from workers exposed to 1-bromopropane solvents from vapor degreasing or adhesive manufacturing. Int Arch Occup Environ Health. 83(5):571–584. 10.1007/s00420-010-0524-4 20229238
Harney JM, Hess J, Reh CM, Trout D. 2002. NIOSH Health Hazard Evaluation Report. STN Cushion Company, Thomasville, North Carolina. Cincinnati, OH: National Institute for Occupational Safety and Health. HETA 2000-0410-2891.
Harney JM, Nemhauser JB, Reh CM, Trout D. 2003. NIOSH Health Hazard Evaluation Report. Marx Industries, Inc., Sawmills, North Carolina. Cincinnati, OH: National Institute for Occupational Safety and Health. HETA 99-0260-2906.
HSDB. 2006. Hazardous Substances Data Bank. National Library of Medicine. http://toxnet.nlm.nih.gov/cgi-bin/sis/htmlgen?HSDB and search on CAS number or compound name. [Accessed: February 7, 2012]
Huang Z, Ichihara S, Oikawa S, Chang J, Zhang L, Takahashi M, Subramanian K, Mohideen SS, Wang Y, Ichihara G. 2011. Proteomic analysis of hippocampal proteins of F344 rats exposed to 1-bromopropane. Toxicol Appl Pharmacol. 257(1):93–101. 10.1016/j.taap.2011.08.023 21925529
Hyman J, Leifer Z, Rosenkranz HS. 1980. The E. coli Pol A-1 assay: A quantitative procedure for diffusible and non-diffusible chemicals. Mutat Res. 74(2):107–111. 10.1016/0165-1161(80)90236-8 6990232
Ichihara G, Kitoh J, Li W, Ding X, Ichihara S, Takeuchi Y. 2012. Neurotoxicity of 1-bromopropane: Evidence from animal experiments and human studies. J Adv Res. 3(2):91–98. 10.1016/j.jare.2011.04.005
Ichihara G, Li W, Ding X, Peng S, Yu X, Shibata E, Yamada T, Wang H, Itohara S, Kanno S, et al. 2004 a. A survey on exposure level, health status, and biomarkers in workers exposed to 1-bromopropane. Am J Ind Med. 45(1):63–75. 10.1002/ajim.10320 14691970
Ichihara G, Li W, Shibata E, Ding X, Wang H, Li J, Huang F, Peng S, Gu B, Ichihara S, et al. 2006. Exposure to 1-bromopropane adversely affects vibration sense and nerve conduction velocity of lower limbs and central nervous system in workers. Clin Toxicol (Phila). 44(5):668.
Ichihara G, Li W, Shibata E, Ding X, Wang H, Liang Y, Peng S, Itohara S, Kamijima M, Fan Q, et al. 2004 b. Neurologic abnormalities in workers of a 1-bromopropane factory. Environ Health Perspect. 112(13):1319–1325. 10.1289/ehp.6995 15345346
Ichihara G, Miller JK, Ziolkowska A, Itohara S, Takeuchi Y. 2002. Neurological disorders in three workers exposed to 1-bromopropane. J Occup Health. 44(1):1–7. 10.1539/joh.44.1
International Agency for Research on Cancer (IARC). 1994. In Some Industrial Chemicals. IARC Monographs on the Evaluation of Carcinogenic Risks to Humans, vol. 60. Lyon, France: International Agency for Research on Cancer; Propylene oxide. p. 181–213.
International Agency for Research on Cancer (IARC). 2000. In Some Industrial Chemicals. IARC Monographs on the Evaluation of Carcinogenic Risks to Humans, vol. 77. Lyon, France: International Agency for Research on Cancer; Glycidol. p. 469–486.
Ishidao T, Kunugita N, Fueta Y, Arashidani K, Hori H. 2002. Effects of inhaled 1-bromopropane vapor on rat metabolism. Toxicol Lett. 134(1-3):237–243. 10.1016/S0378-4274(02)00171-6 12191883
Johnson CW, Williams WC, Copeland CB, DeVito MJ, Smialowicz RJ. 2000. Sensitivity of the SRBC PFC assay versus ELISA for detection of immunosuppression by TCDD and TCDD-like congeners. Toxicology. 156(1):1–11. 10.1016/S0300-483X(00)00330-9 11162871
Jones AR, Walsh DA. 1979. The oxidative metabolism of 1-bromopropane in the rat. Xenobiotica. 9(12):763–772. 10.3109/00498257909042344 532220
Kadekar S, Peddada S, Silins I, French JE, Högberg J, Stenius U. 2012. Gender differences in chemical carcinogenesis in National Toxicology Program 2-year bioassays. Toxicol Pathol. 40(8):1160–1168. 10.1177/0192623312446527 22585941
Kaneko T, Kim HY, Wang PY, Sato A. 1997. Partition coefficients and hepatic metabolism in vitro of 1- and 2- Bromopropanes. J Occup Health. 39(4):341–342. 10.1539/joh.39.341
Kawai T, Takeuchi A, Miyama Y, Sakamto K, Zhang ZW, Higashikawa K, Ikeda M. 2001. Biological monitoring of occupational exposure to I-bromopropane by means of urinalysis for I-bromopropane and bromide ion. Biomarkers. 6(5):303–312. 10.1080/13547500110034817 23889306
Kim H, Chung J, Chung Y, et al. 1998. Toxicological studies on inhalation of 1-bromopropane using rats. Report submitted to the Industrial Health Research Institute – Korea Industrial Safety Corporation.
Kim KW, Kim HY, Park SS, Jeong HS, Park SH, Lee JY, Jeong JH, Moon YH. 1999 b. Gender differences in activity and induction of hepatic microsomal cytochrome P-450 by 1-bromopropane in Sprague-Dawley rats. J Biochem Mol Biol. 32(3):232–238.
Kim Y, Park J, Moon Y. 1999 a. Hematopoietic and reproductive toxicity of 2-bromopropane, a recently introduced substitute for chlorofluorocarbons. Toxicol Lett. 108(2-3):309–313. 10.1016/S0378-4274(99)00103-4 10511276
Knöppel H, Schauenburg H. 1989. Sceening of household product for the emission of volatile organic compounds. Environ Int. 15:413–418. 10.1016/0160-4120(89)90056-1
Kolman A, Spivak I, Näslund M, Dušinská M, Cedervall B. 1997. Propylene oxide and epichlorohydrin induce DNA strand breaks in human diploid fibroblasts. Environ Mol Mutagen. 30(1):40-46. 10.1002/(SICI)1098-2280(1997)30:1<40::AID-EM6>3.0.CO;2-G 9258328
Kuschal C, Thoms KM, Schubert S, Schafer A, Boeckmann L, Schon MP, Emmert S. 2012. Skin cancer in organ transplant recipients: Effects of immunosuppressive medications on DNA repair. Exp Dermatol. 21(1):2–6. 10.1111/j.1600-0625.2011.01413.x 22151386
Lee SK, Jeon TW, Kim YB, Lee ES, Jeong HG, Jeong TC. 2007 a. Role of glutathione conjugation in the hepatotoxicity and immunotoxicity induced by 1-bromopropane in female BALB/c mice. J Appl Toxicol. 27(4):358–367. 10.1002/jat.1214 17265426
Lee SK, Jin CH, Hyun SH, Lee DW, Kim GH, Jeon TW, Lee J, Kim DH, Jeong HG, Lee ES, et al. 2005 a. Identification of glutathione conjugates and mercapturic acids of 1,2-dibromopropane in female BALB/c mice by liquid chromatography-electrospray ionization tandem mass spectrometry. Xenobiotica. 35(1):97–105. 10.1080/00498250400021937 15788371
Lee SK, Jo SW, Jeon TW, Jun IH, Jin CH, Kim GH, Lee DJ, Kim TO, Lee ES, Jeong TC. 2005 b. Hepatotoxic effect of 1-bromopropane and its conjugation with glutathione in male ICR mice. Arch Pharm Res. 28(10):1177–1182. 10.1007/BF02972983 16276976
Lee SK, Kang MJ, Jeon TW, Ha HW, Yoo JW, Ko GS, Kang W, Jeong HG, Lyoo WS, Jeong TC. 2010 a. Role of metabolism in 1-bromopropane-induced hepatotoxicity in mice. J Toxicol Environ Health A. 73(21-22):1431–1440. 10.1080/15287394.2010.511546 20954070
Lee SK, Lee DJ, Jeong H, Bista SR, Kang MJ, Lee ES, Son JK, Nam DH, Chang HW, Lee SH, et al. 2007 b. Hepatotoxic and immunotoxic effects produced by 1,3-dibromopropane and its conjugation with glutathione in female BALB/c mice. J Toxicol Environ Health A. 70(15-16):1381–1390. 10.1080/15287390701434489 17654258
Lee SK, Lee DJ, Ko GS, Yoo SH, Ha HW, Kang MJ, Jeong TC. 2010 b. Role of glutathione conjugation in 1-bromobutane-induced hepatotoxicity in mice. Food Chem Toxicol. 48(10):2707–2711. 10.1016/j.fct.2010.06.044 20600521
Li W, Shibata E, Zhou Z, Ichihara S, Wang H, Wang Q, Li J, Zhang L, Wakai K, Takeuchi Y, et al. 2010 c. Dose-dependent neurologic abnormalities in workers exposed to 1-bromopropane. J Occup Environ Med. 52(8):769–777. 10.1097/JOM.0b013e3181eaded7 20657306
Li WH, Wang QY, Ichihara G, Takeuchi Y, Ding XC, Zhou ZJ. 2010 b. [ Exposure to 1-bromopropane causes dose-dependent neurological abnormalities in workers ]. Chin J Ind Hyg Occup Dis. 28(7):488–493.
Li WH, Zhou ZJ, Wang QY, Ichihara G, Takeuchi Y, Ding XC. 2010 a. [ Effects of 1-bromopropane on neurological and hematological changes of female exposed workers ]. Chin J Ind Hyg Occup Dis. 28(5):339–344.
Liu F, Ichihara S, Mohideen SS, Sai U, Kitoh J, Ichihara G. 2009. Comparative study on susceptibility to 1-bromopropane in three mice strains. Toxicol Sci. 112(1):100–110. 10.1093/toxsci/kfp173 19638432
Liu F, Ichihara S, Valentine WM, Itoh K, Yamamoto M, Sheik Mohideen S, Kitoh J, Ichihara G. 2010. Increased susceptibility of Nrf2-null mice to 1-bromopropane-induced hepatotoxicity. Toxicol Sci. 115(2):596–606. 10.1093/toxsci/kfq075 20211940
Maemura K, Yamauchi H, Hayasaki H, Kanbara K, Tamayama T, Hirata I, Watanabe M. 2003. γ-Amino-butyric acid immunoreactivity in intramucosal colonic tumors. J Gastroenterol Hepatol. 18(9):1089–1094. 10.1046/j.1440-1746.2003.03131.x 12911668
Majersik JJ, Caravati EM, Steffens JD. 2007. Severe neurotoxicity associated with exposure to the solvent 1-bromopropane (n-propyl bromide). Clin Toxicol (Phila). 45(3):270–276. 10.1080/15563650701226218 17453879
Mathias PI, Cheever KL, Hanley KW, Marlow KL, Johnson BC, B'Hymer C. 2012. Comparison and evaluation of urinary biomarkers for occupational exposure to spray adhesives containing 1-bromopropane. Toxicol Mech Methods. 22(7):526-532. 10.3109/15376516.2012.686536
Mazon G, Philippin G, Cadet J, Gasparutto D, Fuchs RP. 2009. The alkyltransferase-like ybaZ gene product enhances nucleotide excision repair of O(6)-alkylguanine adducts in E. coli. DNA Repair (Amst). 8(6):697–703. 10.1016/j.dnarep.2009.01.022 19269902
Meyer-Baron M, Kim EA, Nuwayhid I, Ichihara G, Kang SK. 2012. Occupational exposure to neurotoxic substances in Asian countries - Challenges and approaches. Neurotoxicology. 33(4):853–861. 10.1016/j.neuro.2011.12.012 22202747
Mirza T, Gérin M, Bégin D, Drolet D. 2000. A study on the substitution of trichloroethylene as a spot remover in the textile industry. AIHAJ. 61(3):431–438. 10885896
Mitchell AE, Zheng J, Hammock BD, Lo Bello M, Jones AD. 1998. Structural and functional consequences of haloenol lactone inactivation of murine and human glutathione S-transferase. Biochemistry. 37(19):6752–6759. 10.1021/bi971846r 9578559
MMWR . 2008. Neurologic illness associated with occupational exposure to the solvent 1-bromopropane - New Jersey and Pennsylvania, 2007-2008. MMWR Morb Mortal Wkly Rep. 57(48):1300–1302. 19052528
Mohideen SS, Ichihara G, Ichihara S, Nakamura S. 2011. Exposure to 1-bromopropane causes degeneration of noradrenergic axons in the rat brain. Toxicology. 285(1-2):67–71. 10.1016/j.tox.2011.04.005 21527306
Mohideen SS, Ichihara S, Banu S, Liu F, Kitoh J, Ichihara G. 2009. Changes in neurotransmitter receptor expression levels in rat brain after 4-week exposure to 1-bromopropane. Neurotoxicology. 30(6):1078–1083. 10.1016/j.neuro.2009.06.007 19576243
Morgan DL, Nyska A, Harbo SJ, Grumbein SL, Dill JA, Roycroft JH, Kissling GE, Cesta MF. 2011. Multisite carcinogenicity and respiratory toxicity of inhaled 1-bromopropane in rats and mice. Toxicol Pathol. 39(6):938–948. 10.1177/0192623311416374 21859883
National Response Center. 2012. National Response Center database. Washington, DC: United States Coast Guard. http://www.nrc.uscg.mil/foia.html. [Accessed: May 14, 2012]
National Toxicology Program (NTP). 1987. Toxicology and carcinogenesis studies of bromodichloromethane (CAS No. 75-27-4) in F344/N rats and B6C3F_1_ mice (gavage studies). Research Triangle Park, NC: National Toxicology Program. NTP TR 321, NIH Publication No. 88-2537.
National Toxicology Program (NTP). 1989. Toxicology and carcinogenesis studies of tribromomethane (bromoform) (CAS No. 75-25-2) in F344/N rats and B6C3F_1_ mice (gavage studies). Research Triangle Park, NC: National Toxicology Program. NTP TR 350, NIH Publication No. 89-2805.
National Toxicology Program (NTP). 1990. Toxicology and carcinogenesis studies of glycidol (CAS No. 556-52-5) in F344/N rats and B6C3F_1_ mice (gavage studies). Research Triangle Park, NC: National Toxicology Program. NTP TR 374, NIH Publication No. 90-2829.
National Toxicology Program (NTP). 2003 a. NTP-CERHR monograph on the potential human reproductive and developmental effects of 1-bromopropane. Research Triangle Park, NC: National Toxicology Program, Center for the Evaluation of Risks to Human Reproduction.
National Toxicology Program (NTP). 2003b. NTP-CERHR monograph on the potential human reproductive and developmental effects of 2-bromopropane (2-BP). Research Triangle Park, NC: National Toxicology Program. NIH Publication No. 04-4480.
National Toxicology Program (NTP). 2011a. NTP technical report on the toxicology and carcinogenesis studies of 1-bromopropane (CAS No. 106-94-5) in F344/N rats and B6C3F1 mice (inhalation studies). Research Triangle Park, NC: National Toxicology Program. NTP TR 564, NIH Publication No. 11-5906.
National Toxicology Program (NTP). 2011 b. In Report on Carcinogens. 12th ed. Research Triangle Park, NC: National Toxicology Program; Glycidol. p. 215–216.
National Toxicology Program (NTP). 2011 c. In Report on Carcinogens. 12th ed. Research Triangle Park, NC: National Toxicology Program; Propylene oxide. p. 367–368.
Nivard MJ, Czene K, Segerbäck D, Vogel EW. 2003. Mutagenic activity of ethylene oxide and propylene oxide under XPG proficient and deficient conditions in relation to N-7-(2-hydroxyalkyl)guanine levels in Drosophila. Mutat Res. 529(1-2):95–107. 10.1016/S0027-5107(03)00111-8 12943923
Occupational Safety and Health Administration (OSHA). 2011. Chemical exposure health data. Washington, DC: Occupational Safety and Health Administration. https://www.osha.gov/opengov/healthsamples.html. [Accessed: April 17, 2013]
Plna K, Nilsson R, Koskinen M, Segerback D. 1999. ^32^P-postlabelling of propylene oxide 1- and N^6^-substituted adenine and 3-substituted cytosine/uracil: Formation and persistence in vitro and in vivo. Carcinogenesis. 20(10):2025–2032. 10.1093/carcin/20.10.2025 10506120
Raymond LW, Ford MD. 2007. Severe illness in furniture makers using a new glue: 1-bromopropane toxicity confounded by arsenic. J Occup Environ Med. 49(9):1009–1019. 10.1097/JOM.0b013e318145b616 17848857
Reh CM, Mortimer V, Nemhauser JB, Trout D. 2002. NIOSH Health Hazard Evaluation Report. Custom Products, Inc. Mooresville, NC. Cincinnati, OH: National Institute for Occupational Safety and Health. HETA 98-0153-2883.
Reh CM, Nemhauser JB. 2001. NIOSH Health Hazard Evaluation Report. Trilithic, Inc., Indianapolis, Indiana. Cincinnati, OH: National Institute for Occupational Safety and Health. HETA 2000-0233-2845.
Ríos-Blanco MN, Faller TH, Nakamura J, Kessler W, Kreuzer PE, Ranasinghe A, Filser JG, Swenberg JA. 2000. Quantitation of DNA and hemoglobin adducts and apurinic/apyrimidinic sites in tissues of F344 rats exposed to propylene oxide by inhalation. Carcinogenesis. 21(11):2011–2018. 10.1093/carcin/21.11.2011 11062162
Ríos-Blanco MN, Ranasinghe A, Lee MS, Faller T, Filser JG, Swenberg JA. 2003. Molecular dosimetry of N7-(2-hydroxypropyl)guanine in tissues of F344 rats after inhalation exposure to propylene oxide. Carcinogenesis. 24(7):1233–1238. 10.1093/carcin/bgg087 12807731
Saito-Suzuki R, Teramoto S, Shirasu Y. 1982. Dominant lethal studies in rats with 1,2-dibromo-3-chloropropane and its structurally related compounds. Mutat Res. 101(4):321–327. 10.1016/0165-1218(82)90125-2 7110159
Schuller HM, Al-Wadei HA, Majidi M. 2008. Gamma-aminobutyric acid, a potential tumor suppressor for small airway-derived lung adenocarcinoma. Carcinogenesis. 29(10):1979–1985. 10.1093/carcin/bgn041 18310090
Schwarzenbach RP, Giger W, Schaffner C, Wanner O. 1985. Groundwater contamination by volatile halogenated alkanes: Abiotic formation of volatile sulfur compounds under anaerobic conditions. Environ Sci Technol. 19(4):322–327. 10.1021/es00134a003 22283343
Segerbäck D, Plná K, Faller T, Kreuzer PE, Håkansson K, Filser JG, Nilsson R. 1998. Tissue distribution of DNA adducts in male Fischer rats exposed to 500 ppm of propylene oxide: Quantitative analysis of 7-(2-hydroxypropyl)guanine by ^32^P-postlabelling. Chem Biol Interact. 115(3):229–246. 10.1016/S0009-2797(98)00076-3 9851292
Sherchan J, Choi H, Lee ES. 2009 a. Depurination of nucleosides and calf thymus DNA induced by 2-bromopropane at the physiological condition. Bull Korean Chem Soc. 30(10):2309–2317. 10.5012/bkcs.2009.30.10.2309
Sherchan J, Yun M, Lee ES. 2009 b. Deadenylation of adenine based-nucleosides and calf thymus DNA induced by halogenated alkanes at the physiological condition. Bull Korean Chem Soc. 30(10):2318–2328. 10.5012/bkcs.2009.30.10.2318
Singer TM, Lambert IB, Williams A, Douglas GR, Yauk CL. 2006. Detection of induced male germline mutation: Correlations and comparisons between traditional germline mutation assays, transgenic rodent assays and expanded simple tandem repeat instability assays. Mutat Res. 598(1-2):164–193. 10.1016/j.mrfmmm.2006.01.017 16542687
SMARTe.org. 2012. Understanding units of measurement. SMARTe.org. http://www.smarte.org. [Accessed: September 19, 2012]
Snow ET, Singh J, Koenig KL, Solomon JJ. 1994. Propylene oxide mutagenesis at template cytosine residues. Environ Mol Mutagen. 23(4):274–280. 10.1002/em.2850230403 8013473
SRI. 2012. Directory of chemical producers. Menlo Park, CA: SRI Consulting. Database edition. [Accessed: February 13, 2012]
Stolzenberg SJ, Hine CH. 1979. Mutagenicity of halogenated and oxygenated three-carbon compounds. J Toxicol Environ Health. 5(6):1149–1158. 10.1080/15287397909529820 393836
Stolzenberg SJ, Hine CH. 1980. Mutagenicity of 2- and 3-carbon halogenated compounds in the Salmonella/mammalian-microsome test. Environ Mutagen. 2(1):59–66. 10.1002/em.2860020109 7035158
Subramanian K, Mohideen SS, Suzumura A, Asai N, Murakumo Y, Takahashi M, Jin S, Zhang L, Huang Z, Ichihara S, et al. 2012. Exposure to 1-bromopropane induces microglial changes and oxidative stress in the rat cerebellum. Toxicology. 302(1):18–24. 10.1016/j.tox.2012.07.006 22824114
Tachizawa H, MacDonald TL, Neal RA. 1982. Rat liver microsomal metabolism of propyl halides. Mol Pharmacol. 22(3):745–751. 7155131
Tatsuta M, Iishi H, Baba M, Nakaizumi A, Ichii M, Taniguchi H. 1990. Inhibition by γ-amino-n-butyric acid and baclofen of gastric carcinogenesis induced by N-methyl-N'-nitro-N-nitrosoguanidine in Wistar rats. Cancer Res. 50(16):4931–4934. 2379157
Temple L, Kawabata TT, Munson AE, White KL Jr. 1993. Comparison of ELISA and plaque-forming cell assays for measuring the humoral immune response to SRBC in rats and mice treated with benzo[a]pyrene or cyclophosphamide. Fundam Appl Toxicol. 21(4):412–419. 10.1006/faat.1993.1116 8253294
Töpfer K, Kempe S, Müller N, Schmitz M, Bachmann M, Cartellieri M, Schackert G, Temme A. 2011. Tumor evasion from T cell surveillance. J Biomed Biotechnol. 2011:918471. 10.1155/2011/918471
Toraason M, Lynch DW, DeBord DG, Singh N, Krieg E, Butler MA, Toennis CA, Nemhauser JB. 2006. DNA damage in leukocytes of workers occupationally exposed to 1-bromopropane. Mutat Res. 603(1):1–14. 10.1016/j.mrgentox.2005.08.015 16412685
Ueno S, Yoshida Y, Fueta Y, Ishidao T, Liu J, Kunugita N, Yanagihara N, Hori H. 2007. Changes in the function of the inhibitory neurotransmitter system in the rat brain following subchronic inhalation exposure to 1-bromopropane. Neurotoxicology. 28(2):415–420. 10.1016/j.neuro.2006.03.006 16647755
United Nations Environment Programme (UNEP). 2001. Montreal Protocol on Substances that Deplete the Ozone Layer. Report of the Technology and Economic Assessment Panel. Nairobi, Kenya: United Nations Environment Programme.
United States International Trade Commission (USITC). 2012. USITC interactive tariff and trade dataweb. United States International Trade Commission. https://dataweb.usitc.gov/scripts/user_set.asp and search on HTS no. 2903391550. [Accessed: October 11, 2012]
U.S. Environmental Protection Agency (US EPA). 2003. Protection of stratospheric ozone: Listing of substitutes for ozone-depleting substances - n-propyl bromide. Fed Regist. 68(106):33284–33316.
U.S. Environmental Protection Agency (US EPA). 2007a. Protection of stratospheric ozone: Listing of substitutes for ozone-depleting substances - n-propyl bromide in adhesives, coatings and aerosols. Fed Regist. 72(103):30168–30207.
U.S. Environmental Protection Agency (US EPA). 2007b. Protection of stratospheric ozone: Listing of substitutes for ozone-depleting substances n-propyl bromide in solvent cleaning. Fed Reg. 72(103):30142-30167.
U.S. Environmental Protection Agency (US EPA). 2011. List of lists: Consolidated list of chemicals subject to the Emergency Planning and Community Right-To-Know Act (EPCRA), Comprehensive Environmental Response, Compensation and Liability Act (CERCLA) and section 112(r) of the Clean Air Act. Washington, DC: U.S. Environmental Protection Agency. EPA 550-B-10-001.
U.S. Environmental Protection Agency (US EPA). 2012. Non-confidential IUR Production volume information. Washington, DC: U.S. Environmental Protection Agency. https://cfpub.epa.gov/iursearch/index.cfm and search by CAS no.
Valentine H, Amarnath K, Amarnath V, Li W, Ding X, Valentine WM, Ichihara G. 2007. Globin s-propyl cysteine and urinary N-acetyl-S-propylcysteine as internal biomarkers of 1-bromopropane exposure. Toxicol Sci. 98(2):427–435. 10.1093/toxsci/kfm126 17517825
van Hylckama Vlieg JE, Janssen DB. 2001. Formation and detoxification of reactive intermediates in the metabolism of chlorinated ethenes. J Biotechnol. 85(2):81–102. 10.1016/S0168-1656(00)00364-3 11165358
Vogel EW, Nivard MJ. 1997. The response of germ cells to ethylene oxide, propylene oxide, propylene imine and methyl methanesulfonate is a matter of cell stage-related DNA repair. Environ Mol Mutagen. 29(2):124-135. 10.1002/(SICI)1098-2280(1997)29:2<124::AID-EM3>3.0.CO;2-E
Walsh DA, Jones AR. 1977. Metabolism of bromopropane in the rat. Proc Aust Biochem Soc. 10:49–49.
Wang H, Ichihara G, Ito H, Kato K, Kitoh J, Yamada T, Yu X, Tsuboi S, Moriyama Y, Sakatani R, et al. 2002. Biochemical changes in the central nervous system of rats exposed to 1-bromopropane for seven days. Toxicol Sci. 67(1):114–120. 10.1093/toxsci/67.1.114 11961224
Wang H, Ichihara G, Ito H, Kato K, Kitoh J, Yamada T, Yu X, Tsuboi S, Moriyama Y, Takeuchi Y. 2003. Dose-dependent biochemical changes in rat central nervous system after 12-week exposure to 1-bromopropane. Neurotoxicology. 24(2):199–206. 10.1016/S0161-813X(02)00195-X 12606292
Watanabe M, Maemura K, Oki K, Shiraishi N, Shibayama Y, Katsu K. 2006. Gamma-aminobutyric acid (GABA) and cell proliferation: Focus on cancer cells. Histol Histopathol. 21(10):1135–1141. 16835836
Weaver JL. 2012. Establishing the carcinogenic risk of immunomodulatory drugs. Toxicol Pathol. 40(2):267–271. 10.1177/0192623311427711 22105649
Wolf K, Morris M, Swanson MB, Geibig JR, Kelly KE. 2003. Alternative adhesive technologies: Foam furniture and bedding industries. Washington, DC: U.S. Environmental Protection Agency.
Wu X, Faqi AS, Yang J, Pang BP, Ding X, Jiang X, Chahoud I. 2002. 2-Bromopropane induces DNA damage, impairs functional antioxidant cellular defenses, and enhances the lipid peroxidation process in primary cultures of rat Leydig cells. Reprod Toxicol. 16(4):379–384. 10.1016/S0890-6238(02)00039-4 12220598
Young SZ, Bordey A. 2009. GABA’s control of stem and cancer cell proliferation in adult neural and peripheral niches. Physiology (Bethesda). 24:171–185. 10.1152/physiol.00002.2009 19509127
Yu WJ, Kim JC, Chung MK. 2008. Lack of dominant lethality in mice following 1-bromopropane treatment. Mutat Res. 652(1):81–87. 10.1016/j.mrgentox.2008.01.001 18291709
Yu X, Ichihara G, Kitoh J, Xie Z, Shibata E, Kamijima M, Takeuchi Y. 2001. Neurotoxicity of 2-bromopropane and 1-bromopropane, alternative solvents for chlorofluorocarbons. Environ Res. 85(1):48–52. 10.1006/enrs.2000.4226 11161652
Zhao LX, Kim EK, Lim HT, Moon YS, Kim NH, Kim TH, Choi H, Chae W, Jeong TC, Lee ES. 2002. Synthesis, characterization and in vtro identification of N^7^-guanine adduct of 2-bromopropane. Arch Pharm Res. 25(1):39–44. 10.1007/BF02975258 11885689