# Glossary

Aerosol solvent: A cleaning agent stored in a metal container (i.e., a handheld can) under pressure and then released through a push-button valve or nozzle as a suspension of particles in air.
Apoptosis: Cell deletion by fragmentation into membrane-bound particles, which are phagocytosed by other cells.
Aroclor 1254-induced liver: Liver tissue treated with the polychlorinated biphenyl mixture Aroclor 1254 used as a source of S9 fraction for mutagenic and genotoxic effects testing.
Assembly worker: A foam seat cushion manufacturing facility employee who sprays adhesive on foam pieces and presses them together by hand to form the cushion. Assembly department workers are either sprayers or assemblers.
Ataxia: Loss of the ability to coordinate muscular movement.
Axial exhaust fan: An air-moving device in which the air flow is parallel (or axial) to the shaft on which the propeller is mounted; also called a propeller fan.
Boiling point: The boiling point of the anhydrous substance at atmospheric pressure (101.3 kPa) unless a different pressure is stated. If the substance decomposes below or at the boiling point, this is noted (dec). The temperature is rounded off to the nearest °C.
Cauda epididymis: The tail of the epididymis; part of the reservoir for spermatozoa.
CD8^+^ T-cell blast: An immature, undifferentiated lymphocyte that expresses the CD8 transmembrane glycoprotein.
Chemical Data Reporting Rule: Chemical Data Reporting (CDR) is the new name for Inventory Update Reporting (IUR). The purpose of Chemical Data Reporting is to collect quality screening-level, exposure-related information on chemical substances and to make that information available for use by the U.S. Environmental Protection Agency (EPA) and, to the extent possible, to the public. The IUR/CDR data are used to support risk screening, assessment, priority setting and management activities and constitute the most comprehensive source of basic screening-level, exposure-related information on chemicals available to EPA. The required frequency of reporting currently is once every four years.
Comet assay: A genotoxicological technique for measuring DNA damage in an individual cell using single-cell gel electrophoresis. Cell DNA fragments assume a “comet with tail” formation on electrophoresis and are detected with an image analysis system. Alkaline assay conditions facilitate sensitive detection of single-strand damage.
Conversion factor: A numerical factor used to multiply or divide a quantity when converting from one system of units to another.
Cooking: In dry cleaning, boiling the solvent cleaner to remove impurities.
Cover worker: A foam seat cushion manufacturing facility employee who places covers around the assembled cushions and seals the cover around the cushion with adhesive. All workers in the Covers department are sprayers.
Dehydrodehalogenation: An elimination reaction in which a halogen is removed from one carbon and a hydrogen is removed from an adjacent carbon.
Disposition: The description of absorption, distribution, metabolism, and excretion of a chemical in the body.
Distal latency: The interval between the stimulation of a compound muscle and the observed response. Normal nerve conduction velocity is above 40 m/sec in the lower extremities and above 50 m/sec in the upper extremities, but age, muscle disease, temperature, and other factors can influence the velocity.
Dominant lethal mutation assay: The dominant lethal assay identifies germ cell mutagens by measuring the ability of a chemical to penetrate gonadal tissue and produce embryonic death due to chromosomal breakage in parent germ cells.
ELISA assay: Enzyme-linked immunosorbent assay; a sensitive immunoassay that uses an enzyme linked to an antibody or antigen as a marker for the detection of a specific protein, especially an antigen or antibody.
EPA SNAP program: The U.S. Environmental Protection Agency Significant New Alternatives Policy program reviews alternatives to ozone-depleting substances and approves the use of alternatives that do not present substantially greater risk to the public health and environment than the substance they replace or other substitutes available.
F_0_ generation: F_0_ generation is the initial parent generation in a multi-generation reproduction study.
F_1_ and F_2_ offspring: F_1_ offspring is the first filial generation, which comprises offspring resulting from a cross between strains of distinct genotypes. The F_1_ generation is the generation resulting immediately from a cross of the first set of parents (parental generation, i.e., F_0_ generation). F_2_ offspring is the second filial generation, which comprises offspring resulting from a cross of the members of F_1_ generation. The F_2_ generation is the result of a cross between two F_1_ individuals (from F_1_ generation).
FDA Good Laboratory Practice Regulations: A quality system codified by the U.S. Food and Drug Administration that prescribes operating procedures for conducting nonclinical laboratory studies that support or are intended to support applications for research or marketing permits for products regulated by the Food and Drug Administration.
Heat-separated human epidermal membrane: A skin sample used for dermal absorption testing. The method of preparation of epidermal membranes varies across species due to the inherent differences in skin morphology and follicle depth. Commonly, heat separation (60°C for one to two minutes) is used for human and pig skin; the epidermal membrane is peeled from the dermis using forceps.
Helminthes: Eukaryotic animals with worm-like appearance (i.e., small animals with long, slender bodies and without appendages) and mostly parasitic.
Henry’s Law constant at 25°C: The ratio of the aqueous-phase concentration of a chemical to its equilibrium partial pressure in the gas phase. The larger the Henry’s law constant the less soluble it is (greater tendency for vapor phase).
Immersion cleaning: A process in which a tank containing cleaning solvent at a temperature below its boiling point is used for metal parts cleaning. To use the vapor degreaser, the operator places the parts to be cleaned in a metal wire basket, removes the cover, and lowers the basket of parts by hand into the cleaning solvent. After a brief period of time, the operator raises the basket and allows the parts to drip-dry inside the degreaser.
Karmen unit: A formerly used enzyme unit for aminotransferase activity; a change of 0.001 in the absorbance of reduced nicotinamide adenine dinucleotide (NADH) per minute.
Lymphokine-activated killer cell: Killer cell lymphocytes activated in the presence of interleukin-2 (IL-2). Lymphokine-activated killer cells (LAKs) are cytotoxic effector cells with an exceptionally wide target cell spectrum including normal and malignant cells of different origins. LAKs exhibit a profound heterogeneity with regard to phenotype surface marker expression; it remains to be determined whether they represent a unique cell lineage.
Melting point: The melting point of the substance at atmospheric pressure (101.3 kPa). When there is a significant difference between the melting point and the freezing point, a range is given. In case of hydrated substances (i.e., those with crystal water), the apparent melting point is given. If the substance decomposes at or below its melting point, this is noted (dec). The temperature is rounded off to the nearest °C.
Molecular chaperone: Any of a diverse group of proteins that oversee the correct intracellular folding and assembly of polypeptides without being components of the final structure.
Molecular weight: The molecular weight of a substance is the weight in atomic mass units of all the atoms in a given formula. The value is rounded to the nearest tenth.
Natural killer cells: A type of white blood cell that contains granules with enzymes that can kill tumor cells or microbial cells. Also called large granular lymphocytes.
Octanol/water partition coefficient (log K_ow_): A measure of the equilibrium concentration of a compound between octanol and water.
Ozone-depleting substance: A family of man-made compounds that includes, but are not limited to, chlorofluorocarbons (CFCs), bromofluorocarbons (halons), methyl chloroform, carbon tetrachloride, methyl bromide, and hydrochlorofluorocarbons (HCFCs). These compounds have been shown to deplete stratospheric ozone.
Personal breathing zone: A sampling area as close as practical to an employee’s nose and mouth, (i.e., in a hemisphere forward of the shoulders within a radius of approximately nine inches) so that it does not interfere with work performance or safety of the employee.
Phase I metabolism: Metabolism of drugs or other xenobiotic molecules, usually by oxidation or hydrolysis and involving a cytochrome P450 monooxygenase.
Phase II metabolism: A conjugation reaction that forms a covalent linkage between a functional group on a xenobiotic molecule and glucuronic acid, sulfate, glutathione, amino acid, or acetate.
Plaque assay: An assay for antibody production by single lymphocytes using cells isolated from the spleen or lymph nodes of animals injected with sheep red blood cells as an antigen. Incubation of the antibody-forming cells together with sheep red cells in an agar layer with exposure to guinea pig serum as complement results in formation of microscopic plaques (i.e., circular areas of hemolytic clearance around a lymphoid cell) due to release of hemolysin.
Plate incorporation: A commonly used procedure for performing a bacterial reverse mutation test. Suspensions of bacterial cells are exposed to the test substance in the presence and in the absence of an exogenous metabolic activation system. In the plate-incorporation method, these suspensions are mixed with an overlay agar and plated immediately onto minimal medium. After two or three days of incubation, revertant colonies are counted and compared with the number of spontaneous revertant colonies on solvent control plates.
Poly-3 test: A survival-adjusted statistical test that takes survival differences into account by modifying the denominator in the numerical (quantal) estimate of lesion incidence to reflect more closely the total number of animal years at risk.
Pyknotic shrinkage: A thickening, especially the degeneration of a cell in which the nucleus shrinks in size and the chromatin condenses to a solid, structureless mass or masses.
S9 metabolic activation: Addition of the supernatant fraction obtained from an organ (usually liver) homogenate by centrifuging at 9000 g-force for 20 minutes in a suitable medium to a biological assay (e.g., genetic toxicology) to provide metabolic enzymes.
Saw worker: A foam seat cushion manufacturing facility employee who cuts bulk foam with various saws.
SKF-525A: An inhibitor of drug metabolism and cytochrome P-450 activity.
Solubility: The ability of a substance to dissolve in another substance and form a solution.
Specific gravity: The ratio of the density of a material to the density of a standard material, such as water at a specific temperature; when two temperatures are specified, the first is the temperature of the material and the second is the temperature of water.
Sperm motility: Movement characteristics of spermatozoa in a fresh specimen. It is measured as the percentage of sperms that are moving, and as the percentage of sperms with productive flagellar motion such as rapid, linear, and forward progression.
Spinnerette: A small, thimble-shaped, metal nozzle having fine holes through which a spinning solution is forced to form a filament.
Splendore-Hoeppli reaction material: Homogeneous, eosinophilic material that coats the grains that are characteristic of the exudate in lesions of botryomycosis.
Sprayer: Any cushion manufacturing facility employee who works directly with adhesive formulations via spray application using a compressed air spray gun.
Static diffusion cell: A diffusion cell consists of a donor chamber and a receptor chamber between which the skin is positioned. The cell should provide a good seal around the skin, enable easy sampling and good mixing of the receptor solution in contact with the underside of the skin, and provide good temperature control of the cell and its contents. In a static diffusion cell, the receptor fluid is sampled at intervals and replaced with equal volumes of fresh receptor fluid.
Temperate marine macroalgae: Algae growing in the ocean in large seaweed form, generally visible to the naked eye (e.g., kelp), in regions where the climate undergoes seasonal change in temperature and moisture. Temperate regions of the earth lie primarily between 30 and 60 degrees latitude in both hemispheres.
Time-weighted average: The average exposure concentration of a chemical measured over a period of time (not an instantaneous concentration).
Toxicokinetics: The mathematical description (toxicokinetic models) of the time course of disposition of a chemical in the body.
Vapor degreasing: A type of cleaning procedure using a refrigerated cooling coil around the top of the interior of a vapor chamber to condense solvent vapor into liquid droplets on the surface of parts to remove surface impurities. Excess solvent drips back into the solvent sump and is recycled as the parts ascend from the vapor to condensing zones.
Vapor density, relative: A value that indicates how many times a gas (or vapor) is heavier than air at the same temperature. If the substance is a liquid or solid, the value applies only to the vapor formed from the boiling liquid.
Vapor pressure: The pressure of the vapor over a liquid (and some solids) at equilibrium, usually expressed as mm Hg at a specific temperature (°C).