# Introduction and Methods

1-Bromopropane (n-propyl bromide, CASRN 106-94-5) is a brominated hydrocarbon that is currently used as a solvent in a variety of industrial and commercial applications. Exposure to workers has been increasing in the past few years due to several new applications in which 1-bromopropane has been substituted for substances identified as suspect carcinogens or ozone-depleting chemicals. The available occupational exposure data indicate that workers can be exposed to high levels of 1-bromopropane.

1-Bromopropane was selected as a candidate substance for the Report on Carcinogens (RoC) due to the potential for substantial human exposure to 1-bromopropane in the United States, and an adequate database to evaluate its potential carcinogenicity. 1-Bromopropane has been tested for carcinogenicity in rodents in a 2-year inhalation study (NTP 2011a). In addition, 1-bromopropane causes toxicity in people and experimental animals. Structurally related haloalkanes are carcinogenic in experimental animals.

## Monograph Contents

This RoC monograph on 1-bromopropane reviewed the relevant scientific information, assessed its quality, applied the RoC listing criteria to the scientific information, and recommended an RoC listing status for 1-bromopropane.

The monograph for 1-bromopropane provides information on the following topics: human exposure and properties (Section 1), disposition and toxicokinetics (Section 2), cancer studies in experimental animals (Section 4), and studies of mechanisms and other related effects (Section 5), including relevant toxicological effects, genetic toxicology, and mechanisms of carcinogenicity. When human cancer studies are reviewed, they are discussed in Section 3; however, no cancer studies in humans with exposure specifically to 1-bromopropane were identified. The information in Sections 2 through 5 is synthesized in Section 6.

The information reviewed in Sections 2 through 5 (and synthesized in Section 6) came from publicly available, peer-reviewed sources. Information in Section 1, including chemical and physical properties, analytical methods, production, use, and occurrence came from publicly available, published or unpublished sources.

The cancer hazard evaluation for 1-bromopropane focuses on the evaluation of the cancer studies in experimental animals and mechanistic data, and also whether there is any evidence that the potential modes of action by which 1-bromopropane might cause cancer are not relevant to humans.

## Process for Preparation of the Cancer Hazard Evaluation

The process for preparing the monograph included approaches for obtaining public and scientific input and using systematic methods (e.g., standardized methods for identifying the literature, inclusion/exclusion criteria, extraction of data and evaluation of study quality using specific guidelines (see Appendix A), and assessment of the level of evidence for carcinogenicity using established criteria).

The Office of the Report on Carcinogens (ORoC) followed the approaches outlined in the concept document, which discusses the scientific issues and questions relevant to the evaluation of 1-bromopropane carcinogenicity, the scope and focus of the monograph, and the approaches to obtain scientific and public input to address the key scientific questions and issues, for preparing the cancer hazard evaluation. The ORoC presented the draft concept document on 1-bromopropane to the NTP Board of Scientific Counselors (BSC) at the June 21–22, 2012 meeting that provided opportunity for written and oral public comments; the concept document is available on the RoC website (https://ntp.niehs.nih.gov/go/37896). The draft monograph was peer reviewed in a public forum in March 2013 (see “Peer Review of the Draft RoC Monograph on 1-Bromopropane” above), revised accordingly, and presented to the BSC at a June 2013 meeting.

### Key Scientific Questions and Issues Relevant for the Cancer Hazard Evaluation

The cancer hazard evaluation focuses on studies of 1-bromopropane in experimental animals and mechanistic data. It also identifies and discusses human and animal studies of non-cancer endpoints, such as neurological or reproductive/developmental toxicity, immunosuppression, and studies of structurally related compounds and metabolites, to determine whether this information can inform mechanisms of carcinogenicity of 1-bromopropane.

The key scientific questions identified in the concept, which concern the results in experimental animals and mechanisms of carcinogenicity are:

- What is the level of evidence (sufficient or not sufficient) for the carcinogenicity of 1-bromopropane from studies in experimental animals? What are the tissue sites?
- What are potential mechanisms by which 1-bromopropane may cause cancer?
- Do the mechanistic data in experimental animals support the cancer findings in humans?
- Are there mechanistic data to suggest that the cancer findings in experimental animals are not relevant to humans?
- Does immunomodulation play a role in 1-bromopropane carcinogenicity?

### Approach for Obtaining Scientific and Public Input

Additional scientific input was obtained for exposure and disposition and toxicokinetics of 1-bromopropane. (Technical advisors are identified on the “CONTRIBUTORS” page.)

Public comments on scientific issues were requested on 1-bromopropane by Federal Register notices at several times prior to and during the development of the final RoC monograph, including a request for information on the nomination, and for comment on the draft concept document (which outlined the rationale and approach for conducting the scientific review) and comment on the draft RoC monograph. In addition, NTP posted its preliminary literature search strategy and list of references for public input on the RoC web page for 1-bromopropane (https://ntp.niehs.nih.gov/go/37896) several months prior to the release of the draft monograph. Four public comments were received in response to the Federal Register notices and are available at https://ntp.niehs.nih.gov/go/37663.

### Methods for Writing the Monograph

The procedures by which relevant literature were identified, data were systematically extracted and summarized, and the monograph was written, together with the processes for scientific review, quality assurance, and assessment and synthesis of data, are described below.

The preparation of the RoC Monograph on 1-Bromopropane began with development of a literature search strategy for 1-bromopropane to obtain information relevant to the topics for monograph sections, as discussed above, using search terms developed in collaboration with a reference librarian (see Appendix A for a detailed description of the literature search strategy). The citations (N = 1,689) identified from these searches were uploaded to a web-based systematic review system for evaluation by two reviewers using inclusion/exclusion criteria, and 158 references were selected for final inclusion in the monograph using these criteria.

Information for the exposure, relevant cancer, and mechanistic sections was systematically extracted in tabular format and/or summarized in the text, following specific procedures developed by ORoC, from studies selected for inclusion in the monograph. All sections of the monograph underwent scientific review and quality assurance (QA) (i.e., assuring that all the relevant data and factual information extracted from the publications have been reported accurately) by a separate reviewer. Any discrepancies between the writer and the reviewer were resolved by mutual discussion in reference to the original data source.

Strengths, weaknesses, and data quality of the cancer studies for 1-bromopropane in experimental animals were assessed based on a series of questions related to characterization of the substance tested, the features of animal husbandry, the design of the study, the methods for clinical observations and necropsy, and the manner in which the data were reported (see Appendix C). Relevant genotoxicity and mechanistic studies were also assessed for their strengths and weaknesses.

Human exposure information was assessed to determine whether the evidence indicates that a significant number of persons residing in the United States are exposed to 1-bromopropane (see Foreword for information regarding the congressional mandate for the RoC). However, for many substances, this information is not available, and typically, U.S. exposure can be inferred from data on use, production volume, occupational monitoring, environmental (occurrence), estimated daily intake, and biomonitoring. Because cancer has a long latency period, past exposure is also considered in the assessment.

RoC listing criteria (see text box) were applied to the available database of carcinogenicity data to assess the level of evidence (sufficient or not sufficient) for the carcinogenicity of 1-bromopropane from studies in experimental animals. This initial conclusion does not integrate the experimental animal and mechanism data. The evaluation of the mechanistic data included a discussion and assessment of the strength of evidence for potential modes of action of 1-bromopropane-induced neoplasia, including metabolic activation, cytotoxicity, and genetic effects and immunosuppression. In addition, human and animal studies of non-cancerous endpoints, such as neurological or reproductive/developmental toxicity, as well as studies of structurally related compounds and metabolites, may be informative. The RoC listing criteria were then applied to the available body of knowledge for 1-bromopropane to reach a listing recommendation.

RoC Listing Criteria

##### Known to Be Human Carcinogen:

There is sufficient evidence of carcinogenicity from studies in humans*, which indicates a causal relationship between exposure to the agent, substance, or mixture, and human cancer.

##### Reasonably Anticipated to Be Human Carcinogen:

There is limited evidence of carcinogenicity from studies in humans*, which indicates that causal interpretation is credible, but that alternative explanations, such as chance, bias, or confounding factors, could not adequately be excluded, OR

There is sufficient evidence of carcinogenicity from studies in experimental animals, which indicates there is an increased incidence of malignant and/or a combination of malignant and benign tumors (1) in multiple species or at multiple tissue sites, or (2) by multiple routes of exposure, or (3) to an unusual degree with regard to incidence, site, or type of tumor, or age at onset, OR

there is less than sufficient evidence of carcinogenicity in humans or laboratory animals; however, the agent, substance, or mixture belongs to a well-defined, structurally related class of substances whose members are listed in a previous Report on Carcinogens as either known to be a human carcinogen or reasonably anticipated to be a human carcinogen, or there is convincing relevant information that the agent acts through mechanisms indicating it would likely cause cancer in humans.

Conclusions regarding carcinogenicity in humans or experimental animals are based on scientific judgment, with consideration given to all relevant information. Relevant information includes, but is not limited to, dose response, route of exposure, chemical structure, metabolism, pharmacokinetics, sensitive sub-populations, genetic effects, or other data relating to mechanism of action or factors that may be unique to a given substance. For example, there may be substances for which there is evidence of carcinogenicity in laboratory animals, but there are compelling data indicating that the agent acts through mechanisms which do not operate in humans and would therefore not reasonably be anticipated to cause cancer in humans.

*This evidence can include traditional cancer epidemiology studies, data from clinical studies, and/or data derived from the study of tissues or cells from humans exposed to the substance in question that can be useful for evaluating whether a relevant cancer mechanism is operating in people.