# Appendix E Relevant Toxicological Effects

Studies on neurological, developmental, reproductive, immunological, and hepatotoxic effects were identified to determine whether they could inform potential mechanisms of carcinogenicity. Several studies indicate that metabolic activation and glutathione depletion are important factors for many of the toxic effects observed in rodents. Appendix E provides a brief review of the toxic effects that have been linked to metabolic activation and/or glutathione depletion and oxidative stress and other alterations and provides background information for Section 5.3, which discusses these mechanisms as they related to carcinogenicity.

## E.1 Reproductive Toxicity

NTP (2003a) evaluated the reproductive toxicity of 1-bromopropane. There was convincing evidence that 1-bromopropane caused reproductive effects in experimental animals but the evidence in humans was limited to a health hazard survey conducted by NIOSH at a plant that used a spray adhesive that contained 1-bromopropane. Three of 42 workers reported fertility problems (2 males and 1 female). Ichihara et al. (2002) presented case reports for three female workers who used a spray gun with 1-bromopropane as a solvent. Most of the symptoms and signs were neurological in nature but two of the women reported irregular periods and decreased sexual desire.

NTP (2003a) also reviewed a two-generation reproductive toxicity study that reported significant effects in males, females, and offspring. Reproductive capabilities were examined in the F_0_ and F_1_ generations, and neonatal survival, growth, and development were evaluated in the F_1_ and F_2_ offspring. Whole-body inhalation exposures (6 hours/day, 7 days/week at nominal concentrations of 100, 250, 500, or 750 ppm) began at 7 weeks of age for the F_0_ parents and at weaning for the F_1_ generation. Exposures began at least 70 days prior to mating. Prior to weaning on postnatal day 22, the F_1_ offspring were indirectly exposed to the test chemical in utero and through nursing. Effects in F_0_ parents included reduced sperm motility and prostate weight, abnormal sperm, increased estrous cycle length and ovarian follicular cysts, decreased numbers of implantation sites and litter size, and complete infertility in the high-dose group (750 ppm). Reproductive effects in F_1_ offspring were similar. The only significant effect reported in the F_2_ rats was reduced postnatal weight gain. Other studies reported that Wistar rats exposed to 1-bromopropane for 12 weeks had decreased sperm count and sperm motility, irregular estrous cycles, and a decrease in the number of normal growing follicles (National Toxicology Program (NTP) 2003a; 2011a).

Some of the reproductive effects have been linked to metabolic activation. Garner et al. (2007) investigated the relationship between 1-bromopropane oxidative metabolism and sperm toxicity in mice. Wild-type and Cyp2e1^−/−^ (knockout) mice (4 per group) were exposed to [1,2,3-^13^C]-1-bromopropane at 800 ppm for 6 hours in an inhalation chamber. In addition, ex vivo experiments were conducted using caudal sperm (collected from the cauda epididymis) from unexposed wild-type and knockout mice incubated with either 1-bromopropane or its metabolite 1-bromo-2-hydroxypropane (1-bromo-2-propanol) in a sealed test tube. Exposed wild-type mice had a 37% reduction in the percentage of motile sperm compared with unexposed controls (Table E-1). In contrast, the percentage of motile sperm in exposed knockout mice was not significantly different from unexposed controls. In addition, liver glutathione levels were reduced by 76% in exposed wild-type mice compared with 47% in exposed knockout mice (Table E-1). Epididymal sperm were isolated from unexposed wild-type and knockout mice and were incubated with 0.05 mM 1-bromopropane or 1-bromo-2-hydroxypropane for 2 hours (Table E-2). Sperm isolated from wild-type mice had significantly reduced motility when incubated with either test compound. In contrast, sperm from knockout mice did not show a significant change in motility when incubated with 1-bromopropane but motility was significantly reduced when incubated with 1-bromo-2-hydroxypropane. The authors did not address the apparent differences in sperm motility between wild-type and knockout mice in the control groups for the ex vivo experiment. Although the sample sizes used in these experiments were small, these data suggest that products of CYP2E1-mediated oxidation of 1-bromopropane (specifically 1-bromo-2-hydroxypropane) contribute to male reproductive toxicity.

Table E-1 1-Bromopropane Effects on Sperm Motility and Glutathione Levels in Wild-type or Cyp2e1^−/−^ Mice

Genotype | Dose (ppm) | % Motile Sperm (N = 8) | GSH (mM ± SE) (N = 3 to 4)
Wild-type | 0 | 63 | 10.6 ± 1.7
Wild-type | 800 | 40* | 2.6 ± 2.5**
Wild-type | % change | −37 | −76
Cyp2e1^−/−^ | 0 | 57 | 13.8 ± 1.4
Cyp2e1^−/−^ | 800 | 48 | 7.36 ± 1.0*
Cyp2e1^−/−^ | % change | −16 | −47

Source: (Garner et al. 2007).

* p < 0.05 (compared with unexposed controls).

** p < 0.01 (compared with unexposed controls).

Table E-2 Sperm Motility Following Two-hour Incubations with 1-Bromopropane or 1-Bromo-2-hydroxypropane

Genotype | % Motile Sperm (N = 3)
Genotype | Control | 1-Bromopropane | 1-Bromo-2-hydroxypropane
Wild-type | 73 | 39* | 26*
Cyp2e1^−/−^ | 57 | 43 | 23*

Source: (Garner et al. 2007).

* p < 0.05 (compared with unexposed controls, 3 animals/group).

These authors believed that reduction of sperm motility might be mediated by disruption of energetic pathways by metabolites (bromoacetone and α-bromohydrin) derived from CYP-mediated oxidation of 1-bromo-2-hydroxypropane. Studies with α-bromohydrin and its chlorinated analogue have shown that these compounds are converted in situ by spermatozoa into halolacetates. Halolacetates are metabolic inhibitors that can cause reduced sperm motility. Bromoacetone also may be further metabolized either to 1-hydroxy-1-bromoacetone, ultimately forming pyruvate and CO_2_, or 3-bromo-1-hydroxypropanone. 3-Bromo-1-hydroxypropanone can inhibit sperm motility by conversion to bromolactaldehyde and bromopyruvaldehyde, and ultimately yielding the metabolic poison bromopyruvate.

## E.2 Neurotoxicity

Neurotoxic effects of 1-bromopropane were first described in rats and were later used to identify and analyze the initial human cases (Ichihara et al. 2012; Li et al. 2010c; Meyer-Baron et al. 2012). Although the molecular mechanisms of neurotoxicity are not completely understood, recent studies show that the hippocampus is especially susceptible to 1-bromopropane-induced effects and involves oxidative stress, loss of ATP production, altered GABA metabolism and reduced GABAergic feedback inhibition, inhibition of the ubiquitination-proteosome system, changes in neurotransmitter receptor expression, and modifications of intracellular signaling cascades (Fueta et al. 2004; Fueta et al. 2002b; Huang et al. 2011; Mohideen et al. 2009). Other studies indicate that the neurotoxic effects of 1-bromopropane involve glutathione depletion, protein adducts, and degeneration of noradrenergic axons (Mohideen et al. 2011; Valentine et al. 2007; Wang et al. 2002; Wang et al. 2003).

Studies in humans include more than a dozen case reports from the United States and an epidemiologic study of 1-bromopropane production factory workers in China (Ichihara et al. 2012; Li et al. 2010c). Signs and symptoms from the case reports were similar and included numbness, diminished vibration sense in the lower extremities, distal latency, and ataxia suggesting that sensory nerves were affected. Other effects included hyperreflexia, suggesting damage to the central nervous system, and neurobehavioral effects (memory disturbances and depressive or unstable mood). Li et al. (2010b) evaluated neurologic abnormalities in 60 women factory workers compared with age-, sex-, and region-matched controls. Significant neurological effects included dose-dependent increase in the distal latency of tibial nerves, increased threshold for vibration sense in the toes, and decreased sensory nerve conduction velocity of the sural nerve. However, the exposure assessment was based on recent exposure measurement, which may not accurately reflect past exposure.

Reported effects in rats include prolongation of motor distal latency, reduction of motor nerve conduction velocity, myelin sheath degeneration, decrease in cerebral weight, pyknotic shrinkage and degeneration of Purkinje cells in the cerebellum, ataxia, and decreased limb muscle strength (Ichihara et al. 2012). Wang et al. (2002; 2003) investigated the biochemical changes in the central nervous system of rats exposed to 1-bromopropane vapors for 7 days or 12 weeks. Groups of 9 male Wistar rats were exposed to 0, 200, 400, or 800 ppm 8 hours/day, 7 days/week. Both studies reported a dose-dependent decrease in neurospecific γ-enolase in the cerebrum and cerebellum (suggesting functional or cellular loss of neurons) with concomitant decreases in nonprotein sulfhydryl bases, total glutathione, and creatine kinase activity. Creatine kinase also has a critical active-site sulfhydryl group and may be representative of other proteins with a functional sulfhydryl group. Therefore, the mechanisms of 1-bromopropane neurotoxicity may involve glutathione depletion and modification of functional proteins containing a sulfhydryl base. A study by Valentine et al. (2007) demonstrated that 1-bromopropane produces S-propyl cysteine adducts on globin and neurofilaments in rats and globin adducts in humans and provides further support for this mechanism proposed by Wang et al. (2002; 2003), which is discussed below.

Valentine et al. (2007) investigated the dose responses for urinary N-acetyl-S-(n-propyl)-L-cysteine (AcPrCys) and S-propylcysteine adducts on globin and neurofilaments as a function of 1-bromopropane exposure in male Wistar rats and humans. Two experiments were conducted in rats. In the first experiment, rats were divided into four groups (8 per group) and exposed to 1-bromopropane vapor at 0, 50, 200, or 800 ppm for 8 hours/day for 2 weeks. The second experiment included 2 groups of rats (12 per group) exposed to 0 or 50 ppm for 8 hours/day, 5 days/week for 4 weeks. Globin adducts were measured in both experiments, but neurofilament adducts were measured only in the first experiment. In humans, urinary AcPrCys and globin S-propylcysteine adducts were determined in workers at a 1-bromopropane production factory. Both globin and neurofilament adducts showed a linear dose-dependent increase, and a significant increase in globin adducts was observed in exposed workers compared with control workers. The authors concluded that the formation of S-propylcysteine adducts on rat spinal cord protein represents a potential mechanism to explain the observed decrease in sulfhydryl groups reported by Wang et al. (2002; 2003). Thus, the neurotoxic effects of 1-bromopropane may be explained in part by its ability to covalently bind to sulfhydryl groups in the nervous system either by direct addition or from reactive metabolites.

Subramanian et al. (2012) reported that several oxidative stress markers (e.g., thiobarbituric acid-reactive substances, protein carbonyl, ROS, and reactive nitrogen species [RNS]) were increased in a dose-dependent manner in the rat cerebellum following exposure to 1-bromopropane vapor for 28 days. In addition, morphological changes in microglia were reported. Microglia activation in response to pathological stimuli in the CNS is a major source of ROS and RNS. Imbalance in the formation and removal of ROS and RNS results in disturbances of cellular homeostasis and cytotoxicity.

Huang et al. (2011) analyzed the differential protein expression in the hippocampus of F344 rats exposed to 1-bromopropane at 0, 400, or 1,000 ppm, 8 hours/day, for 1 to 4 weeks. 1-Bromopropane was shown to modify the hippocampal proteome in both a dose- and time-dependent manner. Twenty-six protein spots were identified with significant changes (increase or decrease) in their levels of expression compared with controls. From these 26 protein spots, 19 proteins were successfully identified. The altered proteins were classified into six groups according to their functional properties and included nucleocytoplasmic transport, immunity and defense, energy metabolism, purine metabolism, neurotransmitter metabolism, and ubiquitination-proteosome pathway. These data suggest that 1-bromopropane-induced damage to the hippocampus involves oxidative stress, loss of ATP production, dysfunction of GABAergic feedback inhibition, and inhibition of ubiquitination-proteosome system. Several studies have reported an association between 1-bromopropane exposure and GABA inhibition (Fueta et al. 2004; Fueta et al. 2007; Ueno et al. 2007). Fueta et al. (2004; 2007) reported that excitability and convulsive behavior in rats following inhalation exposure to 700 or 1,500 ppm 1-bromopropane was related to dysfunction of GABA-mediated feedback inhibition in the hippocampus. Ueno et al. (2007) also reported dysfunction of the hippocampal GABAergic system in male Wistar rats following subchronic inhalation exposure to 1-bromopropane. Reduced function was related to decreased levels in the expression and function of GABA receptors. Although the relevance of GABA inhibition to the carcinogenicity of 1-bromopropane is unknown, several studies have reported that GABA is involved in the proliferation, differentiation, and migration of various cell types and that increased expression of GABA and GABA receptors have been reported in some tumor cells (Maemura et al. 2003; Schuller et al. 2008; Watanabe et al. 2006; Young and Bordey 2009). These data are briefly reviewed in Section 5.3.3.

## E.3 Hepatotoxicity

Several studies have investigated the mechanisms underlying the hepatotoxic effects of 1-bromopropane in mice (Lee et al. 2007a; Lee et al. 2005b; Li et al. 2010a; Liu et al. 2009; Liu et al. 2010) and rats (Ishidao et al. 2002). Lee et al. focused on the role of metabolism following single oral doses while Liu et al. focused on the role of oxidative stress and biological factors that determine susceptibility in different mouse strains following inhalation exposure. The findings from these studies are summarized below.

The role of glutathione conjugation in the hepatotoxic effects of 1-bromopropane was investigated in male ICR mice (Lee et al. 2005a; Lee et al. 2005b) and female BALB/c mice (Lee et al. 2007a). These studies used similar protocols to investigate the dose response and the time course of effects and reported similar results. Two studies were conducted with male ICR mice. In the first study, male ICR mice (5 per group) received a single oral dose of 0, 200, 500, or 1,000 mg/kg of 1-bromopropane in corn oil and were sacrificed 12 or 24 hours later (Lee et al. 2005b). For the time-course study, groups of mice were administered a single oral dose of 1,000 mg/kg and sacrificed at 6, 12, or 24 hours. The second study was similar to the first but also included groups pretreated with phenobarbital or SKF-525A, a general CYP inhibitor (Lee et al. 2010a). Female BALB/c mice were divided into the same treatment groups as reported above but all mice were sacrificed after 12 hours in the dose-response study and at 6, 12, 24, or 48 hours in the time-course study (Lee et al. 2007a). Hepatotoxicity parameters measured in these three studies included serum alanine aminotransferase (ALT), aspartate aminotransferase (AST), or malondialdehyde. Also, liver homogenates were analyzed for glutathione (GSH), 1-bromopropane glutathione conjugate, or S-propyl GSH.

Body and liver weights were not affected by 1-bromopropane exposure in male ICR mice; however, the activities of serum ALT and AST were significantly increased at the high dose 24 hours after treatment (Table E-3) (Lee et al. 2005b). Hepatic GSH levels decreased and S-propyl GSH levels increased with dose 12 hours after treatment but returned to near normal levels after 24 hours. Levels of malondialdehyde, a marker of lipid peroxidation, also increased with dose and were significantly elevated in groups exposed to 500 or 1,000 mg/kg.

Table E-3 1-Bromopropane Effects on Serum Enzymes in Male ICR Mice

Group (N = 5) | ALT (Karmen Unit/mL ± SE) | AST (Karmen Unit/mL ± SE)
Dose-response study (mg/kg)^a^
0 | 46 ± 10 | 58 ± 6
200 | 33 ± 6 | 70 ± 9
500 | 34 ± 2 | 76 ± 7
1,000 | 1,972 ± 1,648** | 653 ± 478**
Time-course study (hr)^b^
0 | 46 ± 10 | 58 ± 6
6 | 38 ± 3 | 106 ± 12
12 | 1,031 ± 613 | 293 ± 120
24 | 1,972 ± 1,648** | 653 ± 478**

Source: (Lee et al. 2005b).

** p < 0.01.

ALT = serum alanine aminotransferase, AST = serum aspartate aminotransferase.

^a^ Measured at 24 hours.

^b^ 1,000 mg/kg treatment dose.

Lee et al. (2010a) reported similar results. Serum ALT and AST were significantly increased by a single treatment of 1,000 mg/kg 1-bromopropane. Mice pretreated with phenobarbital to induce metabolic enzymes had significantly increased serum ALT and AST in groups treated with 750 mg/kg and above; however, groups of mice pretreated with the CYP inhibitor (SKF-525A) had significantly lower serum ALT and AST levels than mice treated with 1-bromopropane alone. In addition, thiobarbituric acid-reactive substance (TBARS), a byproduct of lipid peroxidation, also was significantly increased by 1,000 mg/kg 1-bromopropane. TBARS was not increased in animals pretreated with SKF-525A. Hepatotoxicity was associated with glutathione depletion by formation of GSH conjugates. Specifically, S-propyl and 2-hydroxypropyl GSH conjugates were identified in the liver, and hepatic GSH levels were significantly decreased 6 hours after treatment with 750 or 1,000 mg/kg. Pretreatment with phenobarbital resulted in significantly decreased hepatic GSH levels 6 hours after treatment with 500 or 1,000 mg/kg compared with mice exposed to 1-bromopropane alone. Mice pretreated with SKF-525A showed decreased GSH only at 500 mg/kg compared with 1-bromopropane alone. GSH levels were restored to control levels 24 hours after 1-bromopropane treatment in all groups except the high-dose groups pretreated with either phenobarbital or SKF-525A.

Effects of 1-bromopropane exposure in female BALB/c mice were consistent with those reported for male ICR mice (Lee et al. 2007a). Glutathione levels in the liver and spleen were significantly decreased in a dose-dependent manner (Table E-4). S-Propyl glutathione conjugate showed dose-related increases in the liver, spleen, and serum. Maximum amounts were detected at 6 to 12 hours after dosing.

Table E-4 1-Bromopropane Effects on Hepatic GSH and GSH Conjugate (S-propyl GSH) Levels in Female BALB/c Mice

Group (N = 5) | ALT (Karmen Unit/mL ± SE) | GSH (nmol/mg Protein ± SE) | | S-propyl GSH (nmol/mg Protein ± SE)
Group (N = 5) | ALT (Karmen Unit/mL ± SE) | Liver | Spleen | Liver | Spleen | Serum
Dose-response study (mg/kg)^a^
0 | 28.4 ± 4.1 | 576.6 ± 23.8 | 161.5 ± 3.6 | ND | ND | ND
200 | 35.2 ± 6.4 | 102.6 ± 34.9** | 117.6 ± 8.5 | 3.2 ± 1.0 | ND | 0.04 ± 0.02
500 | 151.2 ± 100.7 | 102.2 ± 38.0** | 126.2 ± 6.9 | 25.8 ± 3.2 | 1.4 ± 0.5 | 0.11 ± 0.02
1,000 | 3,367 ± 3,111** | 24.2 ± 4.9** | 86.3 ± 8.7* | 315.6 ± 162.7 | 10.3 ± 1.3 | 5.98 ± 1.54
Time-course study (hr)^b^
0 | 28.4 ± 4.1 | 576.5 ± 23.8 | 161.5 ± 3.6 | ND | ND | ND
6 | 18.3 ± 8.9 | 29.6 ± 10.8** | 93.8 ± 10.0* | 409.4 ± 72.2 | 6.3 ± 2.8 | 7.20 ± 1.52
12 | 3,367 ± 3,111** | 24.2 ± 4.9** | 86.3 ± 8.7* | 315.6 ± 162.7 | 10.3 ± 1.3 | 5.98 ± 1.54
24 | 10,641 ± 3,592** | 28.8 ± 10.2** | 110.6 ± 10.2 | 33.1 ± 9.2 | 1.9 ± 0.7 | 0.38 ± 0.15
48 | 2,209 ± 849** | 114.8 ± 28.0 | 135.2 ± 7.9 | 1.2 ± 0.6 | 1.3 ± 0.9 | 0.01 ± 0.01

Source: (Lee et al. 2007a).

* p < 0.05.

** p < 0.01.

ALT = serum alanine aminotransferase, GSH = glutathione, ND = not detected.

^a^ Measured at 12 hr.

^b^ 1,000 mg/kg treatment dose.

Hepatotoxic effects occurred in parallel with changes in glutathione and glutathione conjugate levels and were prevented by pretreatment with a general CYP inhibitor (SKF-525A) (Lee et al. 2007a; Lee et al. 2005b; Lee et al. 2010a). Increases in ALT levels were proportional to glutathione depletion and formation of S-propyl glutathione. Hepatotoxic effects included centrilobular cellular swelling and vacuolization of hepatocytes, congestion, hemorrhage, and centrilobular necrosis. In addition, lipid peroxidation was significantly increased and liver catalase activity was decreased in mice treated with 1-bromopropane. These data suggest that the hepatotoxic effects, including lipid peroxidation, could be related to two different metabolic pathways. First, hepatotoxicity may be closely related with glutathione depletion associated with GSH conjugate formation and subsequent formation of reactive oxygen species. Further, metabolism of 1-bromopropane by CYP enzymes to toxic metabolites that are not associated with GSH conjugation might be an additional factor.

Liu et al. (2009) compared the susceptibility of male mice in three strains (C57BL/6J, DBA/2J, and BALB/cA) to 1-bromopropane-induced hepatotoxicity. Male mice (6 per group) were exposed to 0, 50, 110, or 250 ppm for 8 hours/day for 28 days. Hepatic CYP2E1 levels, glutathione-S-transferase (GST) activity, total GSH, oxidized GSH (GSSH), and NAD(P)H:quinone oxidoreductase (NQO1) and heme oxygenase-1 (HO-1) mRNA levels were measured. All three strains exposed to 250 ppm developed focal necrosis and hepatocellular degeneration, and both parameters showed a significant correlation between response and dose as measured by Pearson’s coefficient (Table E-5). However, BALB/cA mice were the most susceptible based on liver histopathology and DBA/2J mice were the most resistant strain. Baseline CYP2E1 protein levels were higher while total GSH content and GST activity in the liver were lower in BALB/cA than DBA/2J mice. NQO1 and HO-1 mRNA levels were increased at 250 ppm in BALB/cA but not in DBA/2J mice. NQO1 protects cells against redox cycling chemicals and HO-1 defends against oxidant-induced injury during inflammation. Increased expression of NQO1 and HO-1 in the susceptible strain indicates increased oxidative stress compared with the resistant strain. These data indicate that CYP2E1 activity, GSH levels, and GST activity might explain the differences in susceptibility among the three mouse strains to 1-bromopropane-induced hepatotoxicity.

Table E-5 Comparison of Liver Histopathology among Three Mouse Strains Exposed to 1-Bromopropane

Strain | N | Dose (ppm) | % Necrotic Area (Mean ± SD)^a^ | % Lobule Degeneration (Mean ± SD)^a^
DBA/2J | 6 | 0 | 0.00 ± 0.00 | 0.00 ± 0.00
DBA/2J | 6 | 50 | 0.15 ± 0.02 | 15.44 ± 9.45
DBA/2J | 6 | 110 | 0.23 ± 0.09 | 14.32 ± 13.18
DBA/2J | 6 | 250 | 0.46 ± 0.27* | 52.60 ± 21.88*
DBA/2J | | Pearson’s coefficient | 0.780* | 0.807*
C57BL/6J | 6 | 0 | 0.00 ± 0.00 | 0.00 ± 0.00
C57BL/6J | 6 | 50 | 0.28 ± 0.11* | 24.27 ± 11.12*
C57BL/6J | 6 | 110 | 0.49 ± 0.25* | 35.78 ± 22.00*
C57BL/6J | 5 | 250 | 0.88 ± 0.24* | 73.03 ± 21.07*
C57BL/6J | | Pearson’s coefficient | 0.879* | 0.819*
BALB/cA | 6 | 0 | 0.00 ± 0.00 | 0.00 ± 0.00
BALB/cA | 6 | 50 | 0.55 ± 0.21^b^* | 43.76 ± 15.16^b^*
BALB/cA | 6 | 110 | 1.69 ± 0.53^b^* | 62.30 ± 8.18^b^*
BALB/cA | 4 | 250 | 3.80 ± 2.19^b^* | 91.42 ± 9.93^c^*
BALB/cA | | Pearson’s coefficient | 0.841* | 0.920*

Source: (Liu et al. 2009).

* p < 0.05 (compared with strain-matched controls).

^a^ Percent values were converted by arcsine transformation before statistical analysis.

^b^ Significantly different (p < 0.05) from either DBA/2J or C57BL/6J strain at same dose.

^c^ Significantly different (p < 0.05) from DBA/2J strain at same dose.

Liu et al. (2010) investigated the role of oxidative stress in 1-bromopropane-induced hepatotoxicity using nuclear factor erythroid 2-related factor 2 (Nrf2)-null mice. Nrf2 is a transcription factor involved in the cellular defense against oxidative stress. Male Nrf2-null and wild-type mice (8 per group) were exposed to 0, 100, or 300 ppm 1-bromopropane for 8 hours/day for 28 days. At the high dose, diffuse hepatocellular degeneration, focal and widespread necrosis, and focal inflammatory cell infiltration were observed in both genotypes. However, significantly larger areas of liver necrosis occurred in Nrf2-null mice compared with wild-type mice (Table E-6). Nrf2-null mice also had a higher prevalence of fatty degeneration, greater malondialdehyde levels, higher ratio of oxidized glutathione/reduced form of glutathione (GSSH/GSH), and lower total GSH content. GST activity was significantly increased in wild-type mice at 300 ppm but was unchanged in Nrf2-null mice where the basal expression levels were low. Significant changes in the mRNA levels of several oxidative stress-related genes (including NQO1 and HO-1) occurred in exposed wild-type mice compared with controls. Only GST Yc2 mRNA levels were significantly increased in the high-dose Nrf2-null mice. Thus, these data demonstrated that Nrf2-null mice were more susceptible to 1-bromopropane-induced liver injury and had a reduced antioxidant response compared with wild-type mice. The compromised antioxidant response and higher level of lipid peroxidation (as indicated by higher malondialdehyde levels) in Nrf2-null mice suggest that liver injury is related to oxidative stress. However, since liver necrosis also may contribute to lipid peroxidation, further studies are needed to clarify the role of oxidative stress in liver injury.

Table E-6 Comparison of Liver Necrotic Area in Wild-type and Nrf2-Null Mice Exposed to 1-Bromopropane

Genotype | Dose (ppm)^a^
Genotype | 0 | 100 | 300
Wild-type | 0.00 ± 0.00 | 0.43 ± 0.20* | 1.08 ± 0.36*
Nrf2-null | 0.00 ± 0.00 | 0.99 ± 0.28* | 1.94 ± 0.60*

Source: (Liu et al. 2010).

* p < 0.05 (compared with strain-matched controls).

^a^ Percent values (± SD) were converted by arcsine transformation before statistical analysis; N = 8 except for high-dose Nrf2-null mice where N = 6.

In contrast with the studies in mice, Ishidao et al. (2002) reported that male Wistar rats exposed to 1-bromopropane vapor 6 hours/day, 5 days/week for 3 and 4 weeks at 1,500 ppm or 4 to 12 weeks at 700 ppm showed significantly decreased plasma ALT levels (Table E-7). Plasma AST levels were not significantly affected. Although the reason for the decreased ALT levels was not clear, the data indicated that plasma ALT activity was affected by 1-bromopropane. Another surprising finding was that the levels of P450 in hepatic microsomes were significantly decreased after 1-day and 1-month exposures to 700 ppm. There is some experimental evidence that exposure to ethylene oxide may decrease hepatic P450 levels by attacking the heme moiety and altering heme balance in the liver. Propylene oxide, a structural analogue of ethylene oxide, is a possible intermediate metabolite of 1-bromopropane that might affect hepatic P450 levels.

Table E-7 1-Bromopropane Effects on Plasma Enzymes in Male Wistar Rats

Treatment (ppm) | N | Duration (Weeks) | AST (U/L ± SD) | ALT (U/L ± SD)
0 | 30 | 4 | 77.4 ± 16.3 | 44.8 ± 11.5
700 | 15 | 4 | 80.2 ± 11.0 | 23.6 ± 3.6**
0 | 30 | 12 | 110.0 ± 35.2 | 60.6 ± 14.0
700 | 10 | 12 | 90.4 ± 21.6 | 31.0 ± 5.3**
0 | 10 | 3 | 119.7 ± 24.3 | 56.8 ± 18.8
1,500 | 10 | 3 | 141 ± 58.5 | 30.2 ± 9.5*

Source: (Ishidao et al. 2002).

* p < 0.05 (compared with group controls).

** p < 0.01 (compared with group controls).

AST = aspartate aminotransferase, ALT = alanine aminotransferase.

## E.4 Immunotoxicity

1-Bromopropane has induced immunotoxic effects in mice (Lee et al. 2007a). T-dependent antibody response to sheep red blood cells, intracellular IL-2 production, and the absolute numbers of splenocyte subpopulations (total T-cells, CD4^+^ cells, CD8^+^ cells, macrophages, and B-cells) were all reduced in a dose-dependent manner. Thus, dose levels that resulted in decreased cellular glutathione and increased production of glutathione conjugate in spleen cells (see Table E-4) also suppressed immune function. These findings are consistent with studies that have shown immune function to be affected by intracellular glutathione (Dröge and Breitkreutz 2000). Studies in humans indicate that the immune system requires an optimal level of glutathione. Individuals with intermediate levels of glutathione generally have a higher number of CD4^+^ T-cells than individuals with lower or higher intracellular glutathione levels. Some immune functions, such as DNA synthesis in lymphocytes, are very sensitive to reactive oxygen intermediates and are favored by high levels of glutathione while certain signal pathways are enhanced by oxidative conditions that are favored by low intracellular glutathione levels. IL-2-dependent functions (including T-cell proliferation, generation of CD8^+^ T-cell blasts, cytotoxic T-cell activity, lymphokine-activated killer cells, and natural killer cells) are particularly sensitive and are inhibited by a partial depletion of intracellular glutathione levels (Dröge et al. 1994). Thus, the immunotoxicity of 1-bromopropane could be related to glutathione depletion from formation of glutathione conjugates and increased oxidative stress.

Anderson et al. (2010) also reported immunotoxic effects of inhaled 1-bromopropane in female B6C3F_1_ mice and F344/N rats. Animals (8 per group) were placed in inhalation chambers and exposed to 0, 125, 250, or 500 ppm (mice) or 0, 250, 500, or 1,000 ppm (rats) for 6 hours/day, 5 days/week, for 4 or 10 weeks. Spleen immunoglobulin (IgM) responses to sheep red blood cells (plaque-forming cell assay) were significantly decreased in mice (all exposed groups) and in rats (high-dose group only) after exposure for 10 weeks (see Table E-8); however, the serum IgM response (ELISA assay) was not affected. Although the mechanism underlying these contradictory results is unknown, it has been observed following exposure to other chemicals (Johnson et al. 2000; Temple et al. 1993). The sensitivities of these assays can vary depending on the compound being tested.

Table E-8 Suppression of Splenic IgM Response to Sheep RBC in Rodents after Inhalation Exposure to 1-Bromopropane for 10 Weeks

Exposure (ppm) | B6C3F_1_ Mouse | | Fisher 344 Rat
Exposure (ppm) | PFC/ 10^6^ Splenocytes | PFC/ Spleen | PFC/ 10^6^ Splenocytes | PFC/ Spleen
0 | 1,752 | 449 | 309 | 142
125 | 1,124* | 263* | ND | ND
250 | 859* | 181* | 211 | 105
500 | 681* | 144* | 209 | 102
1,000 | ND | ND | 164* | 79*

Source: (Ishidao et al. 2002) (mean values from graphs in paper; actual data provided by authors).

* p < 0.05 (compared with air control).

IgM = immunoglobulin M; RBC = red blood cells; PFC = plaque-forming cell; ND = not done.

Total spleen cells and total T-cells (CD3^+^) were significantly reduced in mice (all exposed groups) and in high-dose rats after 4-weeks exposure (Anderson et al. 2010). This trend was not observed after 10-weeks exposure, with the exception of a decrease in total T-cells in high-dose rats. The apparent recovery of splenocyte numbers by the end of the 10-week exposure period might be due to the ability of 1-bromopropane to induce its own metabolism to increase production of CO_2_ and other nontoxic metabolites. However, rats exposed to 500 or 1,000 ppm for 10 weeks also had a significant decrease in the CD4^+^/CD8^−^ T-cell subpopulation. There were no consistent changes in natural killer cell activity or biological alterations in B-cell or macrophage numbers in either species. These data suggest that T-cells are a possible target for 1-bromopropane immunotoxicity, which could increase the risk of infection.

An unusual non-neoplastic finding in rats in the 2-year carcinogenicity study was the presence of inflammatory lesions with Splendore-Hoeppli reaction material (Morgan et al. 2011; National Toxicology Program (NTP) 2011a). These lesions were exposure related and were more common in males than females. Although these lesions occurred primarily in the nose and skin, other sites were affected. Swabs were collected from abscesses on the tail, Harderian gland, head, and salivary glands from five rats and cultured under aerobic and anaerobic conditions and Splendore-Hoeppli bodies were later observed microscopically in these lesions. No bacterial growth occurred under anaerobic conditions, but Pseudomonas aeruginosa was observed in four of five aerobic cultures. Splendore-Hoeppli bodies may be formed by deposition of antigen-antibody complexes and debris from host inflammatory cells, or from glycoproteins, lipid, and calcium derived from host leukocytes. Infections from fungi, helminths, or bacteria are the typical causative agents. Although immunosuppression might have contributed to the development of Splendore-Hoeppli bodies, it is not clear why these lesions occurred only in rats since mice were also immunosuppressed by exposure to 1-bromopropane in subchronic studies (Anderson et al. 2010).