# Appendix D Genotoxicity Studies

The five tables in this appendix contain data discussed in the “Mechanisms and Other Relevant Effects” section (Section 5) for genetic and related effects (Section 5.1).

Data are reported for in vitro studies of 1-bromopropane mutagenicity in bacteria (Table D-1), in vitro genotoxicity studies of 1-bromopropane in mammalian cells (Table D-2), in vivo studies of cytogenetic effects of 1-bromopropane in rodents (Table D-3), in vivo studies of cytogenetic effects of 1-bromopropane in humans (Table D-4), and a summary of in vitro and in vivo studies of genotoxicity of 1-bromopropane metabolites (Table D-5).

Table D-1 In Vitro Studies of 1-Bromopropane Mutagenicity in Bacteria

Reference | Strain | Method | LED/HID | | Results | | Cytotoxicity | | Evaluation: Limitations and Conclusions^a^
Reference | Strain | Method | −S9 | +S9 | −S9 | +S9 | −S9 | +S9 | Evaluation: Limitations and Conclusions^a^
Barber et al. (1981) | S. typhimurium TA98, TA100 TA1535 | Plate incorporation; closed-system incubation | TA98 (HID) 2,497 µg/plate^b^ | TA98 (HID) 2,497 µg/plate^b^ | − | − | NR | NR | No toxicity was observed up to and including the highest dose tested (2,497 µg/plate^b^) for each strain. For strains showing mutagenicity, positive effects were observed at the same doses for with or without S9. Test results with other strains, TA1537 and TA1538, reported as negative (data not provided by study authors).
Barber et al. (1981) | S. typhimurium TA98, TA100 TA1535 | Plate incorporation; closed-system incubation | TA100 (LED) 1,107 µg/plate^b^ | TA100 (LED) 1,107 µg/plate^b^ | + | + | NR | NR
Barber et al. (1981) | S. typhimurium TA98, TA100 TA1535 | Plate incorporation; closed-system incubation | TA1535 (LED) 603 µg/plate^b^ | TA1535 (LED) 603 µg/plate^b^ | + | + | NR | NR
Elf Atochem (1994), as cited in NTP (2003a) | S. typhimurium TA98, TA100, TA1535, TA1537, TA1538 | Protocol (plate incorporation or preincubation) not specified; closed-system incubation | 10,000 µg/plate | 10,000 µg/plate | − | − | 10,000 µg/plate | 10,000 µg/plate | A brief description of this study was presented in the NTP (2003a) review, but protocol not specified, and number of replicate plates and resultant data (i.e., numbers of revertants/plate for each dose of the tested strains) were not provided. Insufficient information to evaluate because protocol not specified.
Kim et al. (1998), as cited in NTP (2003a) | S. typhimurium TA98, TA100 TA1535, TA1537 and | Protocol not specified and no indication if closed system was used | 5,000 µg/ plate | 5,000 µg/ plate | − | − | NR | NR | A brief description of this study was presented in the NTP (2003a) review, but the protocol was not specified and details on methods (e.g., solvent) and observations regarding cytotoxicity were not given. Also, the number of replicate plates and resultant data (i.e., numbers of revertants/plate for each dose of the tested strains) were not provided. Insufficient information to evaluate because protocol not specified.
Kim et al. (1998), as cited in NTP (2003a) | E. coli WP2uvrA | | 5,000 µg/ plate | 5,000 µg/ plate | − | − | NR | NR
NTP (2011a) (two studies, independent contract labs) | Study 1
NTP (2011a) (two studies, independent contract labs) | S. typhimurium TA97, TA98, TA100, TA1535 | Preincubation | All strains: 10,000 µg/ plate, but ≥3,333 μg/plate was too toxic to evaluate | All strains: 10,000 µg/ plate, but ≥3,333 μg/ plate was too toxic to evaluate | − | − | ≥3,333 μg/plate | ≥3,333 μg/plate | All strains were tested to 10,000 µg/plate; unable to adequately evaluate mutagenicity at doses ≥3,333 µg/plate due to high toxicity. Not mutagenic at nontoxic doses. +S9: 10% and 30% rat or hamster. Study 2 used same chemical lot as 2-year NTP bioassay. Not mutagenic.
NTP (2011a) (two studies, independent contract labs) | Study 2
NTP (2011a) (two studies, independent contract labs) | S. typhimurium TA98, TA100 | Preincubation | Both strains: 5,000 µg/ plate | Both strains: 10,000 µg/plate | − | − | ≥3,500 µg/plate | TA98: 10,000 µg/plate | +S9: 10% rat. TA100: not toxic at highest dose (10,000 µg/plate) tested. Not mutagenic.
NTP (2011a) (two studies, independent contract labs) | E. coli WP2uvrA/ pKM101 | Standard protocol | 5,000 µg/ plate | 10,000 µg/plate | − | − | ≥5,000 µg/plate | | +S9: Not toxic at highest dose (10,000 µg/plate) tested. Not mutagenic.

LED/HID = lowest effective dose/highest ineffective dose, NR = not reported, + = positive, − = negative.

^a^ Evaluations of some studies (as indicated) presented in this table are limited by the information provided in the cited review paper.

^b^ Reported dose levels of 1-bromopropane were determined by using gas liquid chromatography to analyze samples of distilled water that were in the test chambers during treatment. To facilitate comparison with other studies, data reported by these authors as µmoles per plate were converted to µg/plate.

Table D-2 In Vitro Studies of 1-Bromopropane in Mammalian Cells

Reference | Effect | Test System | Concentration (LEC or HIC) | Cytotoxicity | Results | | | Evaluation: Limitations and Conclusions^a^
Reference | Effect | Test System | Concentration (LEC or HIC) | Cytotoxicity | −S9 | | +S9 | Evaluation: Limitations and Conclusions^a^
Elf Atochem (1994), cited in NTP (2003a) | Mutation | L5178Y mouse lymphoma cells (2 experiments) | −S9: 1,000 mg/L +S9: 1,500 mg/L | ≥2,000 mg/L (10%–60% RTG) | + | | + | Adequate information provided in NTP review on methodology; reproducible two-fold increase in mutation frequency and evidence of dose response, but actual numbers of revertant colonies not available. Evidence of mutagenicity.
Toraason et al. (2006) | DNA damage (dose response) | Comet assay, using human leukocytes from venous blood from unexposed adult males. | LEC = 1 mM 8-hr exposure | | [underlined: Dose (mM)] | [underlined: Comet tail moment^a^] | ND | Did not perform assays in presence of S9 since Barber et al. 1981 had previously shown 1-bromopropane to be mutagenic with or without added metabolic activation in the S. typhimurium assay. Evidence of DNA damage.
Toraason et al. (2006) | DNA damage (dose response) | Comet assay, using human leukocytes from venous blood from unexposed adult males. | LEC = 1 mM 8-hr exposure | | 0 | 1,000 | ND
Toraason et al. (2006) | DNA damage (dose response) | Comet assay, using human leukocytes from venous blood from unexposed adult males. | LEC = 1 mM 8-hr exposure | | 0.01 | 1,000 | ND
Toraason et al. (2006) | DNA damage (dose response) | Comet assay, using human leukocytes from venous blood from unexposed adult males. | LEC = 1 mM 8-hr exposure | | 0.1 | 1,250 | ND
Toraason et al. (2006) | DNA damage (dose response) | Comet assay, using human leukocytes from venous blood from unexposed adult males. | LEC = 1 mM 8-hr exposure | | 1.0 | 3,500* | ND
Toraason et al. (2006) | DNA damage (temporal response) | Comet assay, using human leukocytes from venous blood from unexposed adult males. | LEC = 1 mM 4-hr exposure | | [underlined: Exp (hr)] | [underlined: Comet tail moment^a^] | ND
Toraason et al. (2006) | DNA damage (temporal response) | Comet assay, using human leukocytes from venous blood from unexposed adult males. | LEC = 1 mM 4-hr exposure | | 1 | 750 | ND
Toraason et al. (2006) | DNA damage (temporal response) | Comet assay, using human leukocytes from venous blood from unexposed adult males. | LEC = 1 mM 4-hr exposure | | 2 | 750 | ND
Toraason et al. (2006) | DNA damage (temporal response) | Comet assay, using human leukocytes from venous blood from unexposed adult males. | LEC = 1 mM 4-hr exposure | | 4 | 1,250* | ND
Toraason et al. (2006) | DNA damage (temporal response) | Comet assay, using human leukocytes from venous blood from unexposed adult males. | LEC = 1 mM 4-hr exposure | | 8 | 3,250* | ND
Toraason et al. (2006) | Apoptosis | DNA diffusion assay using human leukocytes | LEC = 0.1 mM | | [underlined: Dose (mM)] | [underlined: Apoptotic cells (%)^a^] | ND
Toraason et al. (2006) | Apoptosis | DNA diffusion assay using human leukocytes | LEC = 0.1 mM | | 0 | 2.75 | ND
Toraason et al. (2006) | Apoptosis | DNA diffusion assay using human leukocytes | LEC = 0.1 mM | | 0.01 | 2.50 | ND
Toraason et al. (2006) | Apoptosis | DNA diffusion assay using human leukocytes | LEC = 0.1 mM | | 0.1 | 3.25* | ND
Toraason et al. (2006) | Apoptosis | DNA diffusion assay using human leukocytes | LEC = 0.1 mM | | 1.0 | 4.75* | ND

* p < 0.05 (ANOVA).

Exp = exposure, LEC/HIC = lowest effective concentration/highest ineffective concentration, ND = not done, RTG = relative total growth.

^a^ Data estimated from graph.

Table D-3 In Vivo Studies of Cytogenetic Effects of 1-Bromopropane in Rodents

Reference | Endpoint | Species/Sex/# | Exposure | Results | | | | Comments and Evaluation^a^
Kim et al. (1998), cited in NTP (2003a) | Micronuclei | Rat (Sprague-Dawley) bone marrow males and females 10 animals/sex/group | Inhalation 0, 50, 300, 1,800 ppm 6 hr/day for 5 days/week for 8 weeks | No increases in bone marrow micronucleated polychromatic erythrocytes | | | | Information limited to that provided in summary of study in review; values for micronuclei were not provided. NTP (2003a) stated that animals exposed to 1,800 ppm had decreased bodyweight and ataxia. Treatment doses differed by a factor of 6; intermediate doses might have been informative. Negative.
Elf Atochem (1994), cited in NTP (2003a) | Micronuclei | Mouse (Swiss mice) bone marrow males and females 5 animals/sex/group | Intraperitoneal injection M: 0, 100, 400, 600, 800 mg/kg F: 0, 100, 400, 800 mg/kg Two injections; animals sacrificed 24 hr after last injection. | Bone marrow micronucleated erythrocytes M: 600 mg/kg – no increases F: 800 mg/kg – no increases | | | | Information limited to that provided in summary of study in review; values for micronuclei were not provided. Only 800 mg/kg for females and 600 mg/kg for males were evaluated for micronuclei because the PCE/NCE ratio in controls from other doses (100, 400) were outside the historical control range Negative.
NTP (2011a) | Micronuclei | Mouse (B6C3F_1_) peripheral blood erythrocytes males and females 5 animals/sex/group | Inhalation: 3 mo | NCE^b^ | | | | Percent of polychromatic erythrocytes (reticulocytes) was unaltered indicating a lack of bone marrow toxicity. Negative.
NTP (2011a) | Micronuclei | Mouse (B6C3F_1_) peripheral blood erythrocytes males and females 5 animals/sex/group | Inhalation: 3 mo | Males | | Females | | Percent of polychromatic erythrocytes (reticulocytes) was unaltered indicating a lack of bone marrow toxicity. Negative.
NTP (2011a) | Micronuclei | Mouse (B6C3F_1_) peripheral blood erythrocytes males and females 5 animals/sex/group | 0 ppm | 2.00 ± 0.61 | | 1.80 ± 0.25 | | Percent of polychromatic erythrocytes (reticulocytes) was unaltered indicating a lack of bone marrow toxicity. Negative.
NTP (2011a) | Micronuclei | Mouse (B6C3F_1_) peripheral blood erythrocytes males and females 5 animals/sex/group | 62.5 | 3.10 ± 0.81 | | 1.70 ± 0.25 | | Percent of polychromatic erythrocytes (reticulocytes) was unaltered indicating a lack of bone marrow toxicity. Negative.
NTP (2011a) | Micronuclei | Mouse (B6C3F_1_) peripheral blood erythrocytes males and females 5 animals/sex/group | 125 | 2.70 ± 0.64 | | 1.60 ± 0.19 | | Percent of polychromatic erythrocytes (reticulocytes) was unaltered indicating a lack of bone marrow toxicity. Negative.
NTP (2011a) | Micronuclei | Mouse (B6C3F_1_) peripheral blood erythrocytes males and females 5 animals/sex/group | 250 | 1.30 ± 0.41 | | 1.40 ± 0.33 | | Percent of polychromatic erythrocytes (reticulocytes) was unaltered indicating a lack of bone marrow toxicity. Negative.
NTP (2011a) | Micronuclei | Mouse (B6C3F_1_) peripheral blood erythrocytes males and females 5 animals/sex/group | 500 | 2.30 ± 0.46 | | 1.80 ± 0.20 | | Percent of polychromatic erythrocytes (reticulocytes) was unaltered indicating a lack of bone marrow toxicity. Negative.
Saito-Suzuki et al. (1982) | Dominant lethal mutation assay | Rat (Sprague-Dawley) 15 exposed males mated with females (1 female/week/male) for 8 weeks, examined vital status of fetuses 13-14 days after mating | Gavage 400 mg/kg 5 days | Week | | DLMI^c^ | | An increase in the number of dead implants in fetuses from rats mated 8 weeks after 1-bromopropane exposure compared with controls was observed but the mutational index was not increased. Negative.
Saito-Suzuki et al. (1982) | Dominant lethal mutation assay | Rat (Sprague-Dawley) 15 exposed males mated with females (1 female/week/male) for 8 weeks, examined vital status of fetuses 13-14 days after mating | Gavage 400 mg/kg 5 days | 1 | | −2.1 | | An increase in the number of dead implants in fetuses from rats mated 8 weeks after 1-bromopropane exposure compared with controls was observed but the mutational index was not increased. Negative.
Saito-Suzuki et al. (1982) | Dominant lethal mutation assay | Rat (Sprague-Dawley) 15 exposed males mated with females (1 female/week/male) for 8 weeks, examined vital status of fetuses 13-14 days after mating | Gavage 400 mg/kg 5 days | 2 | | 1.8 | | An increase in the number of dead implants in fetuses from rats mated 8 weeks after 1-bromopropane exposure compared with controls was observed but the mutational index was not increased. Negative.
Saito-Suzuki et al. (1982) | Dominant lethal mutation assay | Rat (Sprague-Dawley) 15 exposed males mated with females (1 female/week/male) for 8 weeks, examined vital status of fetuses 13-14 days after mating | Gavage 400 mg/kg 5 days | 3 | | 0.4 | | An increase in the number of dead implants in fetuses from rats mated 8 weeks after 1-bromopropane exposure compared with controls was observed but the mutational index was not increased. Negative.
Saito-Suzuki et al. (1982) | Dominant lethal mutation assay | Rat (Sprague-Dawley) 15 exposed males mated with females (1 female/week/male) for 8 weeks, examined vital status of fetuses 13-14 days after mating | Gavage 400 mg/kg 5 days | 4 | | 1.3 | | An increase in the number of dead implants in fetuses from rats mated 8 weeks after 1-bromopropane exposure compared with controls was observed but the mutational index was not increased. Negative.
Saito-Suzuki et al. (1982) | Dominant lethal mutation assay | Rat (Sprague-Dawley) 15 exposed males mated with females (1 female/week/male) for 8 weeks, examined vital status of fetuses 13-14 days after mating | Gavage 400 mg/kg 5 days | 5 | | 3.3 | | An increase in the number of dead implants in fetuses from rats mated 8 weeks after 1-bromopropane exposure compared with controls was observed but the mutational index was not increased. Negative.
Saito-Suzuki et al. (1982) | Dominant lethal mutation assay | Rat (Sprague-Dawley) 15 exposed males mated with females (1 female/week/male) for 8 weeks, examined vital status of fetuses 13-14 days after mating | Gavage 400 mg/kg 5 days | 6 | | 8.0 | | An increase in the number of dead implants in fetuses from rats mated 8 weeks after 1-bromopropane exposure compared with controls was observed but the mutational index was not increased. Negative.
Saito-Suzuki et al. (1982) | Dominant lethal mutation assay | Rat (Sprague-Dawley) 15 exposed males mated with females (1 female/week/male) for 8 weeks, examined vital status of fetuses 13-14 days after mating | Gavage 400 mg/kg 5 days | 7 | | 0.9 | | An increase in the number of dead implants in fetuses from rats mated 8 weeks after 1-bromopropane exposure compared with controls was observed but the mutational index was not increased. Negative.
Saito-Suzuki et al. (1982) | Dominant lethal mutation assay | Rat (Sprague-Dawley) 15 exposed males mated with females (1 female/week/male) for 8 weeks, examined vital status of fetuses 13-14 days after mating | Gavage 400 mg/kg 5 days | 8 | | 9.3 | | An increase in the number of dead implants in fetuses from rats mated 8 weeks after 1-bromopropane exposure compared with controls was observed but the mutational index was not increased. Negative.
Yu et al. (2008) | Dominant lethal mutation assay | Mouse (ICR) 20 males/exposure group, mated with 40 unexposed females (2 females/week/male) for 6 weeks; examined vital status of fetuses at 15 to 17 days gestation | Gavage Males exposed to 300 or 600 mg/kg/day 10 days | Week | DLMR^d^ | | | Negative.
Yu et al. (2008) | Dominant lethal mutation assay | Mouse (ICR) 20 males/exposure group, mated with 40 unexposed females (2 females/week/male) for 6 weeks; examined vital status of fetuses at 15 to 17 days gestation | Gavage Males exposed to 300 or 600 mg/kg/day 10 days | Week | [underlined: 300] | | [underlined: 600] | Negative.
Yu et al. (2008) | Dominant lethal mutation assay | Mouse (ICR) 20 males/exposure group, mated with 40 unexposed females (2 females/week/male) for 6 weeks; examined vital status of fetuses at 15 to 17 days gestation | Gavage Males exposed to 300 or 600 mg/kg/day 10 days | 1 | 0.17 | | −0.26 | Negative.
Yu et al. (2008) | Dominant lethal mutation assay | Mouse (ICR) 20 males/exposure group, mated with 40 unexposed females (2 females/week/male) for 6 weeks; examined vital status of fetuses at 15 to 17 days gestation | Gavage Males exposed to 300 or 600 mg/kg/day 10 days | 2 | 2.17 | | 0.88 | Negative.
Yu et al. (2008) | Dominant lethal mutation assay | Mouse (ICR) 20 males/exposure group, mated with 40 unexposed females (2 females/week/male) for 6 weeks; examined vital status of fetuses at 15 to 17 days gestation | Gavage Males exposed to 300 or 600 mg/kg/day 10 days | 3 | 0.3 | | −2.71 | Negative.
Yu et al. (2008) | Dominant lethal mutation assay | Mouse (ICR) 20 males/exposure group, mated with 40 unexposed females (2 females/week/male) for 6 weeks; examined vital status of fetuses at 15 to 17 days gestation | Gavage Males exposed to 300 or 600 mg/kg/day 10 days | 4 | 3.14 | | −2.03 | Negative.
Yu et al. (2008) | Dominant lethal mutation assay | Mouse (ICR) 20 males/exposure group, mated with 40 unexposed females (2 females/week/male) for 6 weeks; examined vital status of fetuses at 15 to 17 days gestation | Gavage Males exposed to 300 or 600 mg/kg/day 10 days | 5 | 2.98 | | −4.66 | Negative.
Yu et al. (2008) | Dominant lethal mutation assay | Mouse (ICR) 20 males/exposure group, mated with 40 unexposed females (2 females/week/male) for 6 weeks; examined vital status of fetuses at 15 to 17 days gestation | Gavage Males exposed to 300 or 600 mg/kg/day 10 days | 6 | 3.68 | | 0.27 | Negative.

DLMI = Dominant Lethal Mutation Index, DLMR = Dominant Lethal Mutation Rate, NCE = normochromatic erythrocytes.

^a^ Evaluations of some studies (as indicated) presented here are limited by the information provided in the cited review paper.

^b^ Micronucleated NCEs/1000.

^c^ (1-live embryos per test female/live embryos per control female) × 100.

^d^ (1-[{mean of live fetuses in treated group/mean of implants in treated group} × {mean of implants in controls/mean of live fetuses in controls}]) 100.

Table D-4 In Vivo Studies of 1-Bromopropane in Humans

Reference | Effect | Population and Analyses | Exposure | | | | Results | | | Evaluation: Limitations and Conclusions
Toraason et al. (2006) | DNA damage Comet assay: Tail moment and dispersion coefficients^a^; 100 leukocytes per sample | Population 64 workers (18 males and 46 females) at two spray adhesive facilities (A and B) [underlined: Facility A (42]) 29 non-sprayers 13 sprayers [underlined: Facility B (22)] 16 non-sprayers 6 sprayers Analyses Exposure to 1-bromopropane and DNA damage were evaluated by analyses involving (1) facility and job type, and (2) exposure indices (workplace air, urine, and serum) in multivariate models controlling for age, gender, facility, cigarette smoking and GSTM1 and GSTT1 polymorphisms. | Exposure assessed by TWA (ppm) and bromide serum (mg/dL) and urine levels (mg/dL). | | | | Analysis by work type and facility | | | End-of-the-workweek DNA damage (TMD) was higher, albeit not statistically significant, among workers (sprayers and non-sprayers) at both facilities with GSTM1-positive genotypes. In multivariate analysis, GSTM1 had a significant effect in models of end-of-workweek DNA damage (TMD) and 1-bromopropane TWA log-transformed levels. The exposure quartile analyses might have had greater statistical power than the models using log-transformed values since participants with missing data for one exposure indices could be included in the analyses based on their ranking for another exposure indices. Strengths: Wide range of exposures allowed for evaluation of exposure response. Assessment of 1-bromopropane exposure was at the individual level. Multivariate analyses were considered to be more informative than the analysis by job and facility Limitations: Small numbers of subjects, no unexposed controls, multiple comparisons. Conclusion: Limited evidence that exposure to 1-bromopropane causes DNA damage in leukocytes from workers.
Toraason et al. (2006) | DNA damage Comet assay: Tail moment and dispersion coefficients^a^; 100 leukocytes per sample | | [underlined: Facility/] [underlined: worker] | [underlined: TWA] | [underlined: Urine^b^] | [underlined: Serum^b^] | [underlined: Facility A]
Toraason et al. (2006) | DNA damage Comet assay: Tail moment and dispersion coefficients^a^; 100 leukocytes per sample | | A/NS | 2 ± 2 | 28 ± 9 | 2.6 ± 0.7 | | NS | SP
Toraason et al. (2006) | DNA damage Comet assay: Tail moment and dispersion coefficients^a^; 100 leukocytes per sample | | A/SP | 83 ± 85 | 238 ± 17 | 19.5 ± 11.4 | TM/Start | 2,517 | 2,867
Toraason et al. (2006) | DNA damage Comet assay: Tail moment and dispersion coefficients^a^; 100 leukocytes per sample | | B/NS | 5 ± 1 | 2 ± 2 | 0.3 ± 0.1 | TM/End | 3,080* | 3,178
Toraason et al. (2006) | DNA damage Comet assay: Tail moment and dispersion coefficients^a^; 100 leukocytes per sample | | B/SP | 21 ± 5 | 10 ± 14 | 0.9 ± 0.3 | TMD/Start | 562 | 496
Toraason et al. (2006) | DNA damage Comet assay: Tail moment and dispersion coefficients^a^; 100 leukocytes per sample | | TWA significantly correlated with both start-of-week and end-of-week urine and serum bromide concentrations | | | | TMD/End | 678 | 752*
Toraason et al. (2006) | DNA damage Comet assay: Tail moment and dispersion coefficients^a^; 100 leukocytes per sample | | TWA significantly correlated with both start-of-week and end-of-week urine and serum bromide concentrations | | | | [underlined: Facility B]
Toraason et al. (2006) | DNA damage Comet assay: Tail moment and dispersion coefficients^a^; 100 leukocytes per sample | | TWA significantly correlated with both start-of-week and end-of-week urine and serum bromide concentrations | | | | | NS | SP
Toraason et al. (2006) | DNA damage Comet assay: Tail moment and dispersion coefficients^a^; 100 leukocytes per sample | | TWA significantly correlated with both start-of-week and end-of-week urine and serum bromide concentrations | | | | TM/Start | 2,856 | 3,430
Toraason et al. (2006) | DNA damage Comet assay: Tail moment and dispersion coefficients^a^; 100 leukocytes per sample | | TWA significantly correlated with both start-of-week and end-of-week urine and serum bromide concentrations | | | | TM/End | 2,770 | 2,974
Toraason et al. (2006) | DNA damage Comet assay: Tail moment and dispersion coefficients^a^; 100 leukocytes per sample | | TWA significantly correlated with both start-of-week and end-of-week urine and serum bromide concentrations | | | | TMD/Start | 580 | 596
Toraason et al. (2006) | DNA damage Comet assay: Tail moment and dispersion coefficients^a^; 100 leukocytes per sample | | TWA significantly correlated with both start-of-week and end-of-week urine and serum bromide concentrations | | | | TMD/End | 653 | 616
Toraason et al. (2006) | DNA damage Comet assay: Tail moment and dispersion coefficients^a^; 100 leukocytes per sample | | TWA significantly correlated with both start-of-week and end-of-week urine and serum bromide concentrations | | | | Analysis by exposure indices Tail moment – P values
Toraason et al. (2006) | DNA damage Comet assay: Tail moment and dispersion coefficients^a^; 100 leukocytes per sample | | TWA significantly correlated with both start-of-week and end-of-week urine and serum bromide concentrations | | | | | Start | End
Toraason et al. (2006) | DNA damage Comet assay: Tail moment and dispersion coefficients^a^; 100 leukocytes per sample | | TWA significantly correlated with both start-of-week and end-of-week urine and serum bromide concentrations | | | | TWA (log) | 0.654 | 0.148^d^
Toraason et al. (2006) | DNA damage Comet assay: Tail moment and dispersion coefficients^a^; 100 leukocytes per sample | | TWA significantly correlated with both start-of-week and end-of-week urine and serum bromide concentrations | | | | Urine (log) | 0.075^c^ | 0.108^d^
Toraason et al. (2006) | DNA damage Comet assay: Tail moment and dispersion coefficients^a^; 100 leukocytes per sample | | TWA significantly correlated with both start-of-week and end-of-week urine and serum bromide concentrations | | | | Serum (log) | 0.191 | 0.171^d^
Toraason et al. (2006) | DNA damage Comet assay: Tail moment and dispersion coefficients^a^; 100 leukocytes per sample | | TWA significantly correlated with both start-of-week and end-of-week urine and serum bromide concentrations | | | | TWA (EQ) | 0.567 | 0.016^d^
Toraason et al. (2006) | DNA damage Comet assay: Tail moment and dispersion coefficients^a^; 100 leukocytes per sample | | TWA significantly correlated with both start-of-week and end-of-week urine and serum bromide concentrations | | | | Urine (EQ) | 0.106^c^ | 0.141
Toraason et al. (2006) | DNA damage Comet assay: Tail moment and dispersion coefficients^a^; 100 leukocytes per sample | | TWA significantly correlated with both start-of-week and end-of-week urine and serum bromide concentrations | | | | Serum (EQ) | 0.007^c^ | 0.049^d^
Toraason et al. (2006) | DNA damage Comet assay: Tail moment and dispersion coefficients^a^; 100 leukocytes per sample | | TWA significantly correlated with both start-of-week and end-of-week urine and serum bromide concentrations | | | | Dispersion coefficient – no statistically significant associations observed between DNA damage and exposure to 1-bromopropane in any of the models.

EQ = exposure quartiles model, ppm = parts per million, NS = non-sprayer, SP = sprayer, TWA = time-weighted average, TM = tail moment, TMD = tail moment dispersion coefficient.

* End-of-the-workweek measures significantly higher than start-of-the-workweek measures for the same individual (paired t-test, p < 0.05).

^a^ Dispersion coefficient = variance divided by mean of tail moment from 100 leukocytes.

^b^ End of week measure.

^c^ Significant association of facility in model.

^d^ Significant association of gender in model.

Table D-5 Summary of In Vitro and In Vivo Studies of 1-Bromopropane Metabolites

Test System | Effect | Glycidol | | Propylene Oxide | | α-Bromohydrin | | 3-Bromo-1-propanol | | 1-Bromo-2-propanol
Test System | Effect | −S9 | +S9 | −S9 | +S9 | −S9 | +S9 | −S9 | +S9 | −S9 | +S9
In Vitro
Bacteria | Mutation^#^ | +^a^ | +^a^ | +^b^ | +^b^ | +^c,d^ | +^c,d^ | +^*,d^ | +^*,d^
Bacteria | DNA damage | +^a^ | | +^*b^ | +^*,b^ | | | +^*,e^ | | +^*,e^
Bacteria | DNA adducts | | | +^f,g^
Yeast | Mutation | +^a^ | +^*,a^ | +^b^ | +^*,b^
Yeast | Gene conversion | | | +^*,b^
Insects | Mutation | +^*,a^ | | +^b,h,i^
Insects | Heritable translocation | +^*,a^
Insects | DNA adducts | | | +^*,h^
Mammalian Cells (other than human) | Mutation | +^a^ | +^*,a^ | +^b^
Mammalian Cells (other than human) | Chromosomal damage | +^a^ | +^a^ | +^b^ | +^*,b^
Mammalian Cells (other than human) | DNA damage | +^a,j^ | +^*,a^ | +^b^ | +^*,b^
Mammalian Cells (other than human) | DNA adducts | +^*,a^ | | +^*,k^
Human Cells | Chromosomal damage | +^*,a^ | | +^b^
Human Cells | DNA damage | ±^a^ | +^*,a^ | +^b,l,m,n^
In Vivo
Mammals (rodents, dogs, monkeys) | Mutation (germ cell) | | | −^b^
Mammals (rodents, dogs, monkeys) | Chromosomal damage | ±^a^ | | ±^b^
Mammals (rodents, dogs, monkeys) | DNA adducts | | | +^b,k,o,p,q^
Mammals (rodents, dogs, monkeys) | Binding to protein | | | +^b,p,r^
Human: Exposed Workers | Chromosomal damage | | | ?^b^
Human: Exposed Workers | DNA damage | | | +^*,s^
Human: Exposed Workers | DNA adducts | | | +^b,s^
Human: Exposed Workers | Binding to protein | | | +^b,s^

^#^ Mutation test results were positive for multiple bacterial strains, except for α-bromohydrin, which was positive for S. typhimurium TA100 but not TA98, and for 3-bromo-1-propanol, which was only tested in TA100.

* Result is based on one study.

+ = positive in all or most of available studies; − = negative in all or most of available studies; ± = available studies are mixed positive and negative, ? = inconclusive (variable response in adequate study).

^a^ IARC (2000).

^b^ IARC (1994).

^c^ Stolzenberg and Hine (1979).

^d^ Stolzenberg and Hine (1980).

^e^ Hyman et al. (1980).

^f^ Mazon et al. (2009).

^g^ Snow et al. (1994).

^h^ Nivard et al. (2003).

^i^ Vogel and Nivard (1997).

^j^ El Ramy et al. (2007).

^k^ Plna et al. (1999).

^l^ Chovanec et al. (2001).

^m^ Kolman et al. (1997).

^n^ Fabiani et al. (2012).

^o^ Segerbäck et al. (1998).

^p^ Ríos-Blanco et al. (2000).

^q^ Ríos-Blanco et al. (2003).

^r^ Couch et al. (1996).

^s^ Czene et al. (2002).