# Appendix C Assessment of the Quality of the Individual Animal Cancer Studies

Only two studies were identified that met the inclusion criteria and these studies was evaluated for study quality. Because similar protocols were used for the NTP 2-year bioassays in rats and mice and results of assessments were similar, the studies are considered together in the table below. Each primary study was systematically evaluated to determine whether it is informative for a cancer assessment. Studies that were given the most weight in the evaluation are those that were of sufficiently long duration to identify a cancer endpoint (ideally an exposure approaching the lifetime of the animal) and provided a detailed account of the study design and data collection. Ideally, studies should use an exposure route comparable to human exposure and appropriate statistical methods in reporting of results. Comparison with historical control values is sometimes helpful in assessing the significance of a finding, especially in the case of rare tumors, lower powered studies, or assessment of background tumor incidences. The number of animals used in a study, the incidence of tumors in control vs. treated group, and the rarity of a tumor influence the statistical power of a study to detect an effect and are parameters that need to be taken into account in study design and results assessment. Post hoc power calculations can be performed. However, rare tumors will be considered in the assessment even if their incidence does not reach significance. Study performance elements for evaluating the different components of study quality are described below.

Table C-1 NTP TR 564 Inhalation Toxicology and Carcinogenesis Studies of 1-Bromopropane (CAS No. 106-94-5) in Rats and Mice

| Question | Answer
Substance Characterization | Is the chemistry of the substance well characterized? Are the purity, solubility, and stability adequate for attributing any adverse effects to the substance? | Yes. Overall purity of the chemical was determined by gas chromatography and three impurities were identified as 1-propanol (0.03%), 2-bromopropane (0.02%), and di-n-propylether (0.02%); stability of bulk chemical, and vapor concentration throughout the experiment monitored against a standard by gas chromatography.
Animal Husbandry | Are the source, species, and strain of the animals adequately described? | Yes. Rats (F344/N) and mice (B6C3F_1_) were from Taconic Laboratory Animals and Services (Germantown, NY).
| Are the care, diet, housing, and maintenance of the animals adequate for attributing any adverse effects to the substance? | Yes. The studies were conducted in and Association for Assessment and Accreditation of Laboratory Animal Care (AAALAC) inspected and approved facility; testing was also done on bedding, water, and diet for possible chemical contamination; sentinel animals were used and sera tested for subclinical disease.
| Were control animals housed in the same room, and tested at the same time under the same conditions as the dosed groups? | Yes. Each animal was housed individually. Animal care and maintenance were described.
Study Design | Animal model: Are the species and sex appropriate for determination of any exposure-related effect? Were the dose groups randomized? | Yes. Rats and mice of both sexes were tested; there is an adequate historical control database on these species and strains for inhalation studies from this laboratory.
| Dosing and observation conditions: Are the study period, dosing period, route of exposure, and doses used adequate for determination of any adverse effect? | Yes. The animals were exposed throughout most of their lifespan (2 yr) by inhalation at a route relevant to human exposure.
| Statistical Power: Does the study have adequate number of animals per group to detect an adverse effect, if present? | These studies follow NCI/NTP guidelines with respect to number of animals (Haseman JK. 1984. Environ Health Perspect, 58: 385-392). Whether the adverse effect is statistically significant will depend on 1) what the tumor endpoint is and 2) the incidence of spontaneous tumors for that endpoint. Based on available historical NTP control data, skin tumors and intestinal adenomas in rats and the lung tumors in mice were were detected at approximately 70% power; mesotheliomas and pancreatic islet-cell tumors in rats were below 50% power.
Clinical Observations, Necropsy, and Pathology | Were clinical observations performed? | Yes. A timetable of clinical observations was reported.
| Was a full necropsy done on these animals and was histopathology done on tissues from at least all major organs? | Yes. Complete necropsies were done on all animals. All organs and tissues were examined for gross lesions and complete histopathology was performed on all major organs.
| Are pathology procedures well described and adequate for determination for any exposure-related effect? | Yes, tissue fixation method, microscopic evaluations and quality assessment of the data are presented.
Data Reporting and Statistical Methods | Is data reporting well characterized? | Yes. Data are presented in a tabular format; individual animal data are provided in appendices.
| Have tumors (benign/malignant) from the same organ been appropriately combined? If so, do they originate from the same cell type? e.g., fibrosarcoma would not be combined with adenoma. | Yes (Rats) Yes (Mice)
| Were statistical analyses performed on the data and adequately described? | Yes (Rats) Yes (Mice)
| Are appropriate historical control data available? | Historical control values for studies by inhalation and by all routes are reported.
Are These Studies Informative for Cancer Assessment? | Yes (Rats) Yes (Mice) No major limitations on cancer study quality were found.

Independent experiments were conducted in rats and mice at Battelle Toxicology Northwest (Richland, WA).