# Appendix B Human Exposure Tables and Regulations and Guidelines

## B.1 Human Exposure Tables

The eight tables on the following pages contain data discussed in the “Properties and Human Exposure” section (Section 1) for the potential for occupational exposure (Section 1.4).

Data for 1-bromopropane exposure are reported for personal (Table B-1) and area samples (Table B-2) during adhesives applications, personal (Table B-3) and area samples (Table B-4) during bromopropane manufacturing, personal (Table B-5) and area samples (Table B-6) during dry-cleaning applications, and personal (Table B-7) and area samples (Table B-8) during vapor degreasing applications. The symbol “–” shown before a range of concentration values in the tables denotes “data for mean not reported.”

Table B-1 Adhesives Applications – Personal Samples of 1-Bromopropane in Air, Urinary Biomarkers (AcPrCys and Br), and 1-Bromopropane in Blood and Exhaled Air

Location (Source) | Type of Job | Number of Workers | 1-Bromopropane in Air | | Urinary Biomarkers | | 1-BP in Blood, Mean Conc. (Range), mg/L | 1-BP in Exhaled Air, Mean Conc. (Range), ppm
Location (Source) | Type of Job | Number of Workers | TWA (Range), ppm | Short-term Conc. (Range), ppm | AcPrCys, Mean Conc. (Range), mg/(g – Cr) | Bromide, Mean Conc. (Range), mg/(g – Cr) | 1-BP in Blood, Mean Conc. (Range), mg/L | 1-BP in Exhaled Air, Mean Conc. (Range), ppm
Polyurethane seat cushion mfr. – NC (Hanley et al. 2005; Hanley and Dunn 2006; Hanley et al. 2009) | Sprayers | 13^a^ | 92^b^ (45–200) | – | 41.1^b^ (14.3–127)^d^ | 195^b^ (119–250)^e^ | – | 10.4 (3.2–20.6)^f^
Polyurethane seat cushion mfr. – NC (Hanley et al. 2005; Hanley and Dunn 2006; Hanley et al. 2009) | Non-sprayers | 17^a^ | 11^b^ (0.6–60) | – | 10.2^b^ (0.373– 1.5)^d^ | 42.9^b^ (5.5–149)^e^ | – | 5.8 (0.13–12.9)^f^
Furniture factory – UT (Majersik et al. 2007) | Cushion gluer | 6 | 108^g^ (92–127^g^) | – | – | – | [– (440–1,700)] (values reported in mg/dL) | –
Furniture foam cushion mfr. – NC (Harney et al. 2003; Toraason et al. 2006)^h^ | Exposed workers (1999 HHE) | 16 | 81.2^b^ (18.1–253.9) | – | – | – | – | –
Furniture foam cushion mfr. – NC (Harney et al. 2003; Toraason et al. 2006)^h^ | All workers (2001 HHE) | 40 | 3.7^b^ (0.1–280.5) | – | – | [465 mg/L^i^ (150–5,950)] | [48^i^ (17–435)] | –
Furniture foam cushion mfr. – NC (Harney et al. 2003; Toraason et al. 2006)^h^ | Unexposed workers (2001 HHE) | 27 | 1.1^b^ (0.1–4.9) | – | – | [285 mg/L^i^ (150–1,510)] | [27^i^ (17–110)] | –
Furniture foam cushion mfr. – NC (Harney et al. 2003; Toraason et al. 2006)^h^ | Exposed workers (2001 HHE) | 13^i^ | 45.7^b^ (7.2–280.5) | – | – | [1,518 mg/L^i^ (270–5,950)] | [149^i^ (30–435)] | –
Furniture foam cushion mfr. – NC (Harney et al. 2003; Toraason et al. 2006)^h^ | All sprayers (1999 HHE) | 12 | 107.6^b^ (57.7–253.9) | – | – | – | – | –
Furniture foam cushion mfr. – NC (Harney et al. 2003; Toraason et al. 2006)^h^ | All sprayers (2001 HHE) | 8 | 101.4^b^ (38.0–280.5) | – | – | – | – | –
Commercial aircraft industry seat cushion mfr. – NC (Reh et al. 2002) | All workers (1998 HHE) | 69 | 168.9 (60.0–381.2) | – | – | – | – | –
Commercial aircraft industry seat cushion mfr. – NC (Reh et al. 2002) | All workers (2000 HHE) | 30 | 19.0 (1.2–58.0) | – | – | – | – | –
Commercial aircraft industry seat cushion mfr. – NC (Reh et al. 2002) | Assembly workers^k^ (1998 HHE) | 36 | 169.8 (60–250.7) | – | – | – | – | –
Commercial aircraft industry seat cushion mfr. – NC (Reh et al. 2002) | Assembly workers (2000 HHE) | 11 | 18.8 (6.1–32.0) | – | – | – | – | –
Commercial aircraft industry seat cushion mfr. – NC (Reh et al. 2002) | Sprayers (1998 HHE) | 15 | 193 (115.3–250.7) | – | – | – | – | –
Commercial aircraft industry seat cushion mfr. – NC (Reh et al. 2002) | Sprayers (2000 HHE) | 12 | – | – (12.3–95.8) | – | – | – | –
Commercial aircraft industry seat cushion mfr. – NC (Reh et al. 2002) | Assemblers (1998 HHE) | 20 | 154.7 (60.0–234.9) | – | – | – | – | –
Commercial aircraft industry seat cushion mfr. – NC (Reh et al. 2002) | Cover workers (1998 HHE) | 21 | 197.0 (117.3–381.2) | – | – | – | – | –
Commercial aircraft industry seat cushion mfr. – NC (Reh et al. 2002) | Cover workers (2000 HHE) | 12 | 29.2 (2.8–58.0) | – | – | – | – | –
Commercial aircraft industry seat cushion mfr. – NC (Reh et al. 2002) | Saw workers (1998 HHE) | 12 | 117.1 (85.1–59.2) | – | – | – | – | –
Commercial aircraft industry seat cushion mfr. – NC (Reh et al. 2002) | Saw workers (2000 HHE) | 6 | 1.8 (1.6–2.0) | – | – | – | – | –
Commercial aircraft industry seat cushion mfr. – NC (Reh et al. 2002) | Sew worker (2000 HHE) | 1 | 1.2 (–) | – | – | – | – | –
Furniture company sofa cushion mfr. – NC (Harney et al. 2002; Toraason et al. 2006)^m^ | Sprayers (2000 HHE) | 12 (TWA), 9 (Short-term) | 65.9 (41.3–143.0) | – (33.7–173.9) | – | – | – | –
Furniture company sofa cushion mfr. – NC (Harney et al. 2002; Toraason et al. 2006)^m^ | Sprayers^l^ (2001 HHE) | 12 (TWA), 10 (Short-term) | 16.6 (8.8–31.9) | – (0.2–56) | – | – | – | –
Furniture company sofa cushion mfr. – NC (Harney et al. 2002; Toraason et al. 2006)^m^ | Non-sprayers (2001 HHE) | 10 | – (1.1–5.8) | – | – | – | – | –
Furniture company sofa cushion mfr. – NC (Harney et al. 2002; Toraason et al. 2006)^m^ | Floaters (2000 HHE) | 2 | – (6.3–14.1) | – | – | – | – | –
Furniture company sofa cushion mfr. – NC (Harney et al. 2002; Toraason et al. 2006)^m^ | Exposed workers (2001 HHE) | 7 | – | – | – | 7.7^n^ (2.5–38.0) | – | –
Furniture company sofa cushion mfr. – NC (Harney et al. 2002; Toraason et al. 2006)^m^ | Sprayers (2000 HHE) | 11 (TWA), 1 (Short-term ceiling) | – | – (39.5–151.9)
Furniture company sofa cushion mfr. – NC (Harney et al. 2002; Toraason et al. 2006)^m^ | Sprayers (2001 HHE) | 10 | – | – (<0.14–8)
Furniture company sofa cushion mfr. – NC (Ichihara et al. 2002) | Sprayers | 11 | 133 (60–261) | – | – | – | – | –
Furniture foam cushion mfr. – NC (Raymond and Ford 2007) | Gluers | 4 | – | – | – | – | [– (240–1,000)]^o^ | –
Unidentified foam cushion fabricators (Raymond and Ford 2007) | Gluers | 5 | – (52–137) | – | – | – | – | –
Adhesives mfr. – OH (Hanley et al. 2007; Hanley et al. 2010) | Exposed workers | 3^a,p^ | 3.79^b^ (0.264–18.9) | – | 0.485^b^ (0.111–1.22) | 4.51^b^ (1.87–12.4) | – | 0.10^q^ (ND–0.18)
Adhesives mfr. – OH (Hanley et al. 2007; Hanley et al. 2010) | Unexposed workers | 8^a,p^ | 0.325^b^ (0.072–1.59) | – | 0.128^b^ (ND–1.33) | 2.01^b^ (0.90–3.55) | – | –

^a^ Workers in this study were sampled on two consecutive days so the total number of samples is twice; e.g., for sprayers in Hanley et al. (2009), N = 13 × 2 = 26.

^b^ Geometric mean.

^c^ Raw data from Hanley et al. (2005) field study were used for analysis in Hanley et al. (2006a) and Hanley et al. (2009).

^d^ As cited in Hanley et al. (2009). Forty-eight-hour composite urinary AcPrCys concentrations, adjusted for creatinine.

^e^ As cited in Hanley et al. (2006a). Forty-eight-hour composite urinary bromide concentrations, adjusted for creatinine.

^f^ Combined mean, calculated from raw data reported for Day 1 post-shift sampling for 2 plants in Hanley et al. (2005) field study. Day 2 sampling data were mostly similar to Day 1 data.

^g^ Seven hour time-weighted average and range; mean ambient air concentration = 130 ppm (range = 91–176 ppm).

^h^ Toraason et al. (2006) study conducted on a subpopulation of 42 workers from Marx Industries NIOSH HHE who consented to participate in the study.

^i^ End-of-week concentration in mg/L; geometric mean. Values reported in mg/dL.

^j^ Exposed workers included 8 sprayers and 5 other workers who were not actively spraying.

^k^ As noted per Reh et al. 2002, data from 1 supervisor omitted.

^l^ Day 2 sampling results: 11 samples, mean = 16.8 ppm, range = 7.7–29 ppm. Day 3 sampling results: 11 samples, mean = 23.3 ppm, range = 14.3–34.9 ppm. Day 1 sampling results are shown in the table.

^m^ Toraason et al. (2006) study conducted on a subpopulation of 22 workers from STN Cushion Company NIOSH HHE who consented to participate in the study.

^n^ End-of-week concentration in mg/L; geometric mean.

^o^ Values reported as 3–12.5 mEq/L. Conversion factor: 8 mg/dL = 1 mEq/L, Golomb (1999).

^p^ As cited in Hanley et al. (2010).

^q^ As cited in Hanley et al. (2007) for Day 1 post-shift sampling for 11 total workers. Day 2 sampling data were mostly similar to Day 1 data.

Table B-2 Adhesives Applications – Area Samples

Location (Source) | Type of Job/Area | Number of Samples | Mean Conc. (Range), ppm
Polyurethane seat cushion manufacturer, Plant A – NC (Hanley et al. 2005)^a^ | Cloth cutting | 2 | 0.9^b^
Polyurethane seat cushion manufacturer, Plant A – NC (Hanley et al. 2005)^a^ | Sewing, south | 2 | 14.1^b^
Polyurethane seat cushion manufacturer, Plant A – NC (Hanley et al. 2005)^a^ | Sewing, north | 2 | 20.4^b^
Polyurethane seat cushion manufacturer, Plant A – NC (Hanley et al. 2005)^a^ | Spray table 1, farthest north | 2 | 68^b^
Polyurethane seat cushion manufacturer, Plant A – NC (Hanley et al. 2005)^a^ | Pillow fill | 2 | 16.7^b^
Polyurethane seat cushion manufacturer, Plant B – NC (Hanley et al. 2005)^a^ | Main glue, south of glue lines | 1 | 36.9
Polyurethane seat cushion manufacturer, Plant B – NC (Hanley et al. 2005)^a^ | Main glue, between glue lines | 1 | 59.4
Polyurethane seat cushion manufacturer, Plant B – NC (Hanley et al. 2005)^a^ | Cutting machine cage | 1 | 1.0
Polyurethane seat cushion manufacturer, Plant B – NC (Hanley et al. 2005)^a^ | Cutting table, near auxiliary glue line | 1 | 10.5
Polyurethane seat cushion manufacturer, Plant B – NC (Hanley et al. 2005)^a^ | Sewing table, near auxiliary glue line | 1 | 2.7
Furniture foam cushion manufacturer – NC (Harney et al. 2003) | Focus saw area near springs line (1999 HHE^b^) | 1 | 8.7
Furniture foam cushion manufacturer – NC (Harney et al. 2003) | Cutting area adjacent to glue line (1999 HHE) | 1 | 5.3
Commercial aircraft industry seat cushion manufacturer – NC (Reh et al. 2002) | Sew department, randomly selected stations (1998 HHE) | 11 | 128.1 (107.3–160.9)
Commercial aircraft industry seat cushion manufacturer – NC (Reh et al. 2002) | Sew department, randomly selected stations (2000 HHE) | 5 | – (1.1–1.9)
Furniture company sofa cushion manufacturer – NC (Harney et al. 2002) | Middle of the saw room (2000 HHE) | 1 | 7.7
Furniture company sofa cushion manufacturer – NC (Harney et al. 2002) | Middle of the fabrication room (2000 HHE) | 1 | 7.2
Furniture company sofa cushion manufacturer – NC (Harney et al. 2002) | Middle of the poly cut room (2000 HHE) | 1 | 1.7
Furniture company sofa cushion manufacturer – NC (Harney et al. 2002) | Non-sprayers (2001 HHE) | 7 | – (0.01–6.1)
Furniture factory – UT (Majersik et al. 2007) | Cushion gluing | 6 | 130 (91–176)

^a^ Sampling conducted on two days; data shown for Day 1 sampling. Day 2 sampling data were mostly similar to Day 1 data.

^b^ Time-weighted average; two samples were collected at each location for approximately four hours each. For cloth cutting, the morning (AM) sample was 0.8 ppm and the afternoon (PM) sample was 1.0 ppm.

For sewing, south, AM sample = 6.4 ppm, PM sample = 22.1 ppm; for sewing, north, AM sample = 12.3 ppm, PM sample = 28.8 ppm; for spray table 1, farthest north, AM sample = 43.2 ppm, PM sample = 94.0 ppm; for pillow fill, AM sample = 9.6 ppm, PM sample = 23.9 ppm.

^c^ HHE = Health Hazard Evaluation. NIOSH conducted health hazard evaluation surveys at three facilities in the adhesives use sector (Harney et al. 2002; Reh et al. 2002).

Table B-3 1-Bromopropane Manufacturing – Personal Samples

Location (Source) | Type of Job | Number of Samples | Air
Location (Source) | Type of Job | Number of Samples | TWA (Range), ppm | Short-term Conc. (Range), ppm
Mfg. plant, China (Ichihara et al. 2004a) | Operators (Female workers) | 24 | – (0.9–170.5) | –
Mfg. plant, China (Ichihara et al. 2004a) | Various (Male workers) | 13 | – (ND^a^–43.3) | –
Mfg. plant, China (Ichihara et al. 2004b) | Material/Product handlers (Female workers) | 23 | 2.92^b^ (0.34–49.2) | –
Mfg. plants, China (Li et al. 2010c) | Material/Product handlers (Female workers) | 60 | 6.6^c^ (0.07–106.4) | –
Mfg. plants, China (Li et al. 2010c) | Material/Product handlers (Male workers) | 26 | 4.6^c^ (0.06–114.8) | –
Mfg. plant, unspecified location (Ichihara et al. 2006) | Not reported | 40 | 15.3 (0.65–73.7) | –

^a^ Not detectable; detection limit = 0.13 ppm.

^b^ Geometric mean.

^c^ Median.

Table B-4 1-Bromopropane Manufacturing – Area Samples

Location (Source) | Type of Job/Area | Number of Samples | Mean Conc. (Range), ppm
Mfg. plant, China (Ichihara et al. 2004a) | Various; in front of reaction pot, in front of stock vessel, above bottle when pouring solution into bottles, product analysis room, site outside plant for washing vessel | Not reported | – (1.1–90.2)
Mfg. plants, China (Li et al. 2010c) | Various; reaction pot, distillation pot, raw product collection | 30 | – (2.2–22)
Mfg. plants, China (Li et al. 2010c) | Various; reaction pot, distillation pot, recording spot | 9 | – (ND–16.5)
Mfg. plants, China (Li et al. 2010c) | Various; reaction pot, distillation pot, raw product collection | 64 | – (ND–88)
Mfg. plants, China (Li et al. 2010c) | Various; reaction pot, operation desk, aisle | 72 | – (ND–22)

ND = not detected.

Table B-5 Dry-cleaning Applications – Personal Samples of 1-Bromopropane

Location (Source) | Type of Job | Number of Samples | Air
Location (Source) | Type of Job | Number of Samples | TWA (Range), ppm | Partial Shift Conc., ppm (Minutes)
Dry-cleaning facility 1 (Eisenberg and Ramsey 2010) | Operator | 2 | 40 (23–56) | –
Dry-cleaning facility 1 (Eisenberg and Ramsey 2010) | Cashier | 2 | 17 (10–24) | –
Dry-cleaning shops (Blando et al. 2010)^a^ | Operator, shop A | NR | – (12.7–54.55) | –
Dry-cleaning shops (Blando et al. 2010)^a^ | Operator, shop B | NR | 41.64 | –
Dry-cleaning shops (Blando et al. 2010)^a^ | Operator, shop C | NR | – (<0.004–0.35) | –
Dry-cleaning shops (Blando et al. 2010)^a^ | Clerk, shop A | NR | – (8.31–21.85) | –
Dry-cleaning shops (Blando et al. 2010)^a^ | Clerk, shop B | NR | 0.65 | –
Dry-cleaning shops (Blando et al. 2010)^a^ | Seamstress, shop C | NR | <0.004 | –
Dry-cleaning facility 2 (Eisenberg and Ramsey 2010) | Operator | 1 | – | 7.2 (209 min)
Dry-cleaning facility 2 (Eisenberg and Ramsey 2010) | Cashier | 1 | – | 1.5 (212 min)
Dry-cleaning facility 3 (Eisenberg and Ramsey 2010) | Operator | 1 | – | 11 (163 min)
Dry-cleaning facility 4 (Eisenberg and Ramsey 2010) | Operator | 1 | – | 160 (241 min)
Dry-cleaning facility 4 (Eisenberg and Ramsey 2010) | Cashier | 1 | – | 2.4 (246 min)

NR = not reported.

^a^ Ranges are reported because data points were collected over a 4-day period depending on the shop owner’s willingness to participate in the study (i.e., Shop A has sampling data for all 4 days, Shop B for only 1 day, and Shop C for 3 days).

Table B-6 Dry-cleaning Applications – Area Samples of 1-Bromopropane in Air

Location (Source) | Type of Job/Area | Air Concentration, ppm^a^
Dry-cleaning facility 1 (Eisenberg and Ramsey 2010) | Behind dry-cleaning machine, morning | 103
Dry-cleaning facility 1 (Eisenberg and Ramsey 2010) | Behind dry-cleaning machine, afternoon | 48
Dry-cleaning facility 1 (Eisenberg and Ramsey 2010) | In front of dry-cleaning machine, morning | 66
Dry-cleaning facility 1 (Eisenberg and Ramsey 2010) | In front of dry-cleaning machine, afternoon | 36
Dry-cleaning facility 2 (Eisenberg and Ramsey 2010) | Behind dry-cleaning machine | 1.5
Dry-cleaning facility 2 (Eisenberg and Ramsey 2010) | In front of dry-cleaning machine | 6.4
Dry-cleaning facility 3 (Eisenberg and Ramsey 2010) | Front counter | 8.6
Dry-cleaning facility 4 (Eisenberg and Ramsey 2010) | Behind dry-cleaning machine | 170
Dry-cleaning facility 4 (Eisenberg and Ramsey 2010) | In front of dry-cleaning machine | 33
Dry-cleaning shops (Blando et al. 2010) | Rear left of shop by machine, shop A | 17.66
Dry-cleaning shops (Blando et al. 2010) | Front right of shop by customer counter, shop B | 3.8
Dry-cleaning shops (Blando et al. 2010) | Front left of shop by customer counter, shop B | 2.67
Dry-cleaning shops (Blando et al. 2010) | Rear right of shop, shop B | 3.17
Dry-cleaning shops (Blando et al. 2010) | Rear left of shop by machine, shop B | 5.4
Dry-cleaning shops (Blando et al. 2010) | Rear right of shop, shop C | <0.004
Dry-cleaning shops (Blando et al. 2010) | Rear left of shop by machine, shop C | <0.004
Dry-cleaning shops (Blando et al. 2010) | Rear left of shop by machine, shop D | 20.47
Unidentified New Jersey dry-cleaning facility (MMWR 2008) | During handling of clothes | 75–250 times background levels

^a^ One measurement per location was reported.

Table B-7 Vapor Degreasing Applications – Personal Samples of 1-Bromopropane in Air, of Urinary Biomarkers (AcPrCys and Br^-^), and of 1-Bromopropane in Exhaled Air

Location (Source) | Type of Job | Number of TWA Samples | 1-BP in Air | Urine | | 1-BP in Exhaled Air, Mean Conc. (Range), ppm
Location (Source) | Type of Job | Number of TWA Samples | Mean TWA (Range), ppm | AcPrCys, Mean Conc. (Range), mg/L | Bromide, Mean Conc. (Range), mg/L | 1-BP in Exhaled Air, Mean Conc. (Range), ppm
Helicopter transmission factory (Hanley and Dunn 2006)^b^ | Plating (Day 1) | 5^a^ | 1.55 (0.077–3.23) | [2.134 (0.028–7.551)]^c^ | 8.5 (4.7–12.5) | 0.17 (0.12–0.22)
Aerospace components mfr., Plant A, Plant B, (Hanley et al. 2006b)^b^ | Cell/corrosion treatment, non-destructive testing, paint and wire dept. (Plant A) (Day 1) | 7^a^ | 0.69 (0.19–1.1) | [0.25 (0.0156–0.883)]^c^ | 4.1 (1.9–8.1) | 0.23 (0.12–0.38)
Aerospace components mfr., Plant A, Plant B, (Hanley et al. 2006b)^b^ | Assembly prep, repair-overhaul, paint and wire dept. (Plant B) (Day 1) | 4^a^ | 1.5 (0.82–2.1) | [1.35 (0.607–2.390)]^c^ | 14 (7.6–21) | 0.23 (0.11–0.33)
Hydraulic power control component mfr. (Hanley and Johnson 2007b)^b^ | Assembly dept. (Day 1) | 4^a^ | 0.85 (0.22–1.4) | [1.01 (0.15–3.21)]^c^ | 3.9 (1.1–7.9) | – (ND–0.20^d^)
Optical prism and assemblies mfr. (Hanley and Dunn 2007)^b^ | Milling and maintenance workers (Day 1) | 7^a^ | 5.1 (0.52–9.8) | [2.52 (0.289–5.92)]^c^ | 13 (3.7–23) | 0.90 (0.10–2.5)
Printed electronics circuit assembly mfr. (Hanley and Johnson 2007a)^b^ | Assembly dept. (Day 1) | 5^a^ | 7.0 (1.3–14) | [5.54 (0.351–13.3)]^c^ | 34 (8.6–67) | 2.9 (0.30–6.1)
Facilities in the five rows shown above, near degreasers and away from degreasers (Hanley et al. 2010)^b^ | Near degreasers (Day 1) | 22^a^ | 2.63^e^ (0.078–21.4) | 1.33^f^ (0.0108–24.2) | 8.94^f^ (1.69–115) | –
Facilities in the five rows shown above, near degreasers and away from degreasers (Hanley et al. 2010)^b^ | Away from degreasers (Day 1) | 9^a^ | 0.308^e^ (0.077–1.69) | 0.115^f^ (0.00512–0.726) | 3.74^f^ (1.69–15.6) | –
Below-boiling vapor degreaser (Reh and Nemhauser 2001) | Assembler | 20 | – (0.01–0.63) | – | – | –

^a^ Number of workers is reported; note that each worker was sampled on two consecutive days so the total number of samples is × 2; e.g., for Hanley and Dunn 2006, N = 5 × 2 = 10.

^b^ Raw data for TWA air concentrations and urinary bromide and AcPrCys concentrations from Hanley and Dunn (2006); Hanley et al. (2006b); Hanley and Dunn (2007); Hanley and Johnson (2007a; 2007b) field studies were used for summary analysis presented in Hanley et al. (2010). Data categorized by workers “near degreasers” and “away from degreasers” not presented in Hanley and Dunn (2006); Hanley et al. (2006b); Hanley and Dunn (2007); Hanley and Johnson (2007a; 2007b) field studies.

^c^ Data reported in µg/L.

^d^ ND = not detected. 1-Bromopropane was only detected in one sample for this collection period.

^e^ Geometric mean.

^f^ Geometric mean. Forty-eight-hour composite concentration, adjusted for creatinine; units are mg/(g-Cr).

Table B-8 Vapor Degreasing Applications – Area Samples

Location (Source) | Type of Job/Area | Air Concentration, ppm^a^
Vapor degreaser (Reh and Nemhauser 2001) | On exhaust duct above degreaser | 4.42
Vapor degreaser (Reh and Nemhauser 2001) | On cart, 5 feet from degreaser | 1.70
Vapor degreaser (Reh and Nemhauser 2001) | Outside of cleaning room (5 samples) | 0.02–0.03
Vapor degreaser (Reh and Nemhauser 2001) | On metal rack, near degreaser room door | 0.02
Vapor degreaser (Reh and Nemhauser 2001) | Near degreaser room window | 0.02
Vapor degreaser (Reh and Nemhauser 2001) | Five feet from degreaser room window | 0.02
Vapor degreaser (Reh and Nemhauser 2001) | Office next to degreaser room | 0.02

^a^ One measurement per location was reported.

## B.2 Regulations and Guidelines

Table B-9 Existing U.S. Standards and Guidelines with Exposure Limits for 1-Bromopropane (ppm)^a^

Type of Guideline | Duration of Exposure
Type of Guideline | 8 Hours
Threshold Limit Value − Time-Weighted Average (ACGIH) | 10
Permissible Exposure Limit (PEL) – Time-Weighted Average (California OSHSB) | 5
Acceptable Exposure Limit – Time-Weighted Average (EPA)^b^ | 25

^a^ As cited in CDC (2008); US EPA (2003).

^b^ The EPA acceptable exposure limit is a non-binding, recommended, voluntary workplace exposure limit. Because there is currently no OSHA PEL for 1-bromopropane, EPA—under the Significant New Alternatives Policy (SNAP) program—determined a safe workplace exposure to evaluate whether the use of 1-bromopropane would pose significantly greater risk than the use of other substitutes available in the same end uses, US EPA (2007b).

Note: The EPA SNAP program reviews alternatives to ozone-depleting substances and approves the use of alternatives that do not present substantially greater risk to the public health and environment than the substance they replace or other available substitutes. Table B-10 lists EPA SNAP program determinations regarding different end uses of 1-bromopropane (US EPA 2007a; 2007b).

Table B-10 EPA SNAP Program Determinations Regarding Different End Uses of 1-Bromopropane

1-Bromopropane End Use | Substitute | EPA SNAP Program Determination
Solvent in industrial equipment for metals cleaning, electronics cleaning, or precision cleaning | 1-bromopropane as a substitute for CFC-113 and methyl chloroform | Acceptable^a^
Coatings | 1-bromopropane as a substitute for CFC-113, HCFC-141b, and methyl chloroform | Acceptable subject to the use condition that use is limited to coatings facilities that have provided EPA data which demonstrates their ability to maintain acceptable workplace exposures^b^
Aerosol solvents | 1-bromopropane as a substitute for CFC-113, HCFC-141b, and methyl chloroform | Unacceptable^b^
Adhesives | 1-bromopropane as a substitute for CFC-113, HCFC-141b, and methyl chloroform | Unacceptable^b^

^a^ EPA final rule, (US EPA 2007b).

^b^ EPA proposed rule, (US EPA 2007a).

Note: The American Conference of Governmental Industrial Hygienists (ACGIH) threshold limit value (TLV) of an 8-hr time-weighted average of 10 ppm is being considered for a change to 0.1 ppm in the Notices of Intended Changes (NIC) for the 2013 TLVs (EHL 2012). Exposure limits proposed by vendors of 1-bromopropane-based products range from 5 to 100 ppm (US EPA 2007b).