# Appendix A Literature Search Strategy

This document identifies the data sources, search terms, and search strategies that were used to identify literature for the monograph on 1-bromopropane (CASRN 106-94-5). The literature search strategy used for 1-bromopropane involved several approaches designed to identify potentially useful information for the broad range of topics covered by a Report on Carcinogens (RoC) monograph, as listed below.

- Properties and Human Exposure (focusing on the U.S. population)
- Disposition (ADME) and Toxicokinetics
- Human Cancer Studies (if available)
- Cancer Studies in Experimental Animals
- Mechanisms and Other Relevant Effects
- Genotoxicity
- Toxicity as It Relates to Mechanisms
- Mechanisms of Carcinogenicity

The methods for identifying the relevant literature for the 1-bromopropane monograph including (1) the search strategy, (2) updating the literature search, and (3) review of citations using web-based systematic review software are illustrated in Figure A-1 and discussed below.

Figure A-1

Literature Search Strategy and Review

## A.1 Search Strategies

Relevant literature is identified using search terms, data sources, and strategies as discussed below.

1. General data search: This search covers a broad range of general data sources (see Table A-1) for information relevant to many or all of the wide range of monograph topics pertaining to 1-bromopropane.
2. Exposure-related data search: This search covers a broad range of potential sources (see Table A-2) for exposure-related information and physical-chemical properties.
3. Database searches in PubMed, Scopus, and Web of Science: The majority of the primary literature used to draft the 1-bromopropane monograph was identified from searches of these three extensive databases available through the NIEHS Library. Synonyms, metabolites (both Phase I and Phase II), and the chemical class for 1-bromopropane were identified from the sources listed in Table A-3 and the search terms are listed in Table A-4. Information on metabolites and structurally related chemicals may be important for evaluating potential mechanisms of carcinogenicity. Initial literature searches were conducted to obtain all literature (not restricted to topic) on 1-bromopropane, its metabolites and chemical class. The searches for the four debrominated Phase I metabolites of 1-bromopropane and the relevant chemical class brought up several thousand references and thus subsequent topic-specific searches were conducted to focus the search on identifying mechanistic information for these chemicals. See Table A-4 for details on this approach and Table A-5 for topic-specific search terms.
  Searches for human cancer studies are unique because they involve the identification of search terms for exposure scenarios that might result in exposure of people to 1-bromopropane. The major uses of 1-bromopropane are as a cleaner/degreaser, as an adhesive for manufacture of foam cushions, and as a solvent in dry cleaning. The use of 1-bromopropane in dry cleaning is more recent, since 2006. Because the expansion in the use of 1-bromopropane has been fairly recent, epidemiologic studies of workers may not be able to evaluate potential risks for cancer, which is associated with long latency periods. Formal searches were not conducted for epidemiologic studies of dry cleaners because these workers would most likely have been exposed to other solvents such as tetrachloroethylene. Literature searches conducted using search terms for spray adhesive and degreaser industries were combined with search terms for cancer epidemiologic studies (see Table A-4 and Table A-5).
4. QUOSA library of occupational case-control studies: A search of the QUOSA-based library of approximately 6,000 occupational case-control studies, approximately 60% of which are currently available as searchable full-text PDFs, was conducted using the synonyms “1-bromopropane,” “propyl bromide,” and the CASRN number (106-94-5).
5. Special topic-focused search: One of the key questions in the concept document on 1-bromopropane was whether the reported alterations in immune surveillance in rodents lead to an increased incidence of tumors. An additional literature search of the three databases was conducted to identify information on immunosuppression and chemically induced cancer using the following search terms: (cancer OR tumor OR neoplasm) AND (immune suppression OR immunosuppression) AND (skin OR dermal) AND (chemically induced). The review of these citations was limited to review articles.
6. Secondary sources: Citations identified from authoritative reviews or from primary references located by literature search, together with publications citing key papers identified using the Web of Science “Cited Reference Search,” were also added.

## A.2 Updating the Literature Search

The literature search was updated prior to submitting the draft monograph for peer review and was updated prior to finalizing the monograph. Monthly search alerts for 1-bromopropane synonyms, metabolites, chemical class, exposure scenarios (human cancer), and topic-focused searches were created in PubMed, Scopus, and Web of Science, and the results of these searches from the closing date of the initial search were downloaded for review.

## A.3 Review of Citations Using Web-based Systematic Review Software

Citations retrieved from literature searches were uploaded to web-based systematic review software and screened using inclusion and exclusion criteria. Multi-level reviews of the literature were conducted, with initial reviews (Level 1) based on titles and abstracts only to identify citations that could be excluded and to assign the included literature to one or more monograph topics; subsequent reviews (Level 2) for literature assigned to the various monograph topics were based on full-text (i.e., PDFs) of the papers and were carried out by the writer and scientific reviewer for each monograph section. Two reviewers, at least one of whom is a member of the ORoC at NIEHS, participated at each level of review.

Inclusion/exclusion questions for literature

Level 1:

1. Should we obtain a PDF of this article?
  - Yes
  - No
2. If yes, for which sections of the monograph does this article contain useful information? Check all that apply.
  - Properties and Human Exposure
  - Toxicokinetics (also includes ADME, i.e., absorption, distribution, metabolism, and excretion)
  - Human Cancer Studies
  - Studies of Cancer in Experimental Animals
  - Mechanisms–Genetic Toxicology
  - Mechanisms–Toxicity
  - Mechanisms of Carcinogenicity
3. If no, check the reason that applies below or enter a reason in the textbox for “Other.”
  - It does not contain relevant information on 1-bromopropane or any related substance (metabolite or structural analogues).
  - It is related to 1-bromopropane but does not contain information relevant to any topic covered by the monograph.
  - Other:

Note: In the context of the systematic review of literature used for 1-bromopropane, “useful” or “relevant” information as it applies to primary screening can include any of the following:

- The article specifically mentions 1-bromopropane, a metabolite, or structural analogue and reports information on one of the topics included in a cancer hazard evaluation (see Question #1 above for a list of topics)
- The article does not specifically mention 1-bromopropane, or any related substance, but it does one of the following:
  - It reports information on one of the topics included in a cancer hazard evaluation with potential for exposure to 1-bromopropane and should be included until full-text review, which would provide more information if the study is specific for exposure to 1-bromopropane or a related substance.
  - It reports information on an exposure scenario that could include exposure to the 1-bromopropane.
  - It reports information on methodology that is potentially informative for evaluating cancer or mechanistic studies on exposure to 1-bromopropane.

It reports information on a potential mode of action that may be informative for 1-bromopropane.

Level 2:

Exposure

1. Does this paper contain information that could be useful in answering the key questions about exposure?
  - Yes
  - No
2. If the answer to Question #1 is “No” select the reason below for excluding it from review.
  - It does not contain relevant information on the candidate substance (or one of its metabolites or analogues).
  - It is related to the candidate substance (or one of its metabolites or analogues), but the paper does not contain information that will help answer the key questions about exposure.
  - Other:

Note: In the context of the systematic review of literature used for 1-bromopropane, “useful” or “relevant” information as it applies to screening for the exposure section can include information, from either primary research papers, review articles, databases, or other published sources, on any of the following topics: occupational exposure, environmental occurrence, occurrence in consumer products, food, cigarette smoke, or other sources, biological indices of exposure, and Federal regulations or guidelines to reduce exposure.

Toxicokinetics

1. Does this paper contain information that could be useful in answering the key questions about toxicokinetics?
  - Yes
  - No
2. If the answer to Question #1 is “No” select the reason below for excluding it from review.
  - It does not contain relevant information on the candidate substance (or one of its metabolites or analogues).
  - It is related to the candidate substance (or one of its metabolites or analogues), but the paper does not contain information that will help answer the key questions about toxicokinetics.
  - Other:

Note: In the context of the systematic review of literature used for 1-bromopropane, “useful” or “relevant” information as it applies to screening for the toxicokinetics (and ADME) section can include (but is not limited to) information from primary research papers or review articles on any of the following topics: absorption, distribution, metabolism, excretion (ADME), toxicokinetics, and physiologically based pharmacokinetic models (PBPK).

Human Cancer

1. Does this paper contain information that could be useful in answering the key questions about human cancer?
  - Yes
  - No
2. If the answer to Question #1 is “No” select the reason below for excluding it from review.
  - It does not contain relevant information on the candidate substance (or one of its metabolites or analogues).
  - It is related to the candidate substance (or one of its metabolites or analogues), but the paper does not contain information that will help answer the key questions about human cancer.
  - Other

Note: In the context of the systematic review of literature used for 1-bromopropane, “useful” or “relevant” information as it applies to screening for the human cancer section can include, but is not limited to, epidemiologic studies, descriptive studies, pooled analyses, meta-analyses, case reports, reviews, letters to editors, exposure-assessment studies (for use in epidemiologic studies) and information on co-exposures or potential confounders and other special topics of relevance to the evaluation.

Animal Tumors

1. Does this paper contain information that could be useful in answering the key questions about animal tumors?
  - Yes
  - No
2. If the answer to Question #1 is “No” select the reason below for excluding it from review.
  - It does not contain relevant information on the candidate substance (or one of its metabolites or analogues).
  - It is related to the candidate substance (or one of its metabolites or analogues), but the paper does not contain information that will help answer the key questions about animal tumors.
  - Other:

Note: In the context of the systematic review of literature used for 1-bromopropane, “useful information” as it applies to screening for the animal tumors section can include, but is not limited to, information from primary research papers or review articles on (1) chronic studies (ideally for lifetime of the animal) in experimental animals that are assessing neoplastic endpoints, non-cancer data important for cancer assessment, such as preneoplastic lesions that are considered part of a morphologic continuum to neoplasia, or (2) subchronic studies in experimental animals that provide information on preneoplastic lesions, neoplastic lesions, or on dose setting for chronic studies.

Genetic Toxicology

1. Does this paper contain information that could be useful in answering the key questions about genetic toxicology?
  - Yes
  - No
2. If the answer to Question #1 is “No” select the reason below for excluding if from review.
  - It does not contain relevant information on the candidate substance (or one of its metabolites or analogues).
  - It is related to the candidate substance (or one of its metabolites or analogues), but the paper does not contain information that will help answer the key questions about genetic toxicology.
  - Other:

Note: In the context of the systematic review of literature used for 1-bromopropane, “useful” or “relevant” information as it applies to screening for the genetic toxicology section can include, information from primary research papers or review articles on studies in experimental systems (both in vitro and in vivo) and in exposed humans assessing the following endpoints: both direct and indirect DNA or chromosomal damage, events associated with mutagenesis, cellular transformation or other related effects.

Toxicity

1. Does this paper contain information that could be useful in answering the key questions about toxicity?
  - Yes
  - No
2. If the answer to Question #1 is “No” select the reason below for excluding if from review.
  - It does not contain relevant information on the candidate substance (or one of its metabolites or analogues).
  - It is related to the candidate substance (or one of its metabolites or analogues), but the paper does not contain information that will help answer the key questions about toxicity.
  - Other:

Note: In the context of the systematic review of literature used for 1-bromopropane, “useful” or “relevant” information as it applies to screening for the toxicity section can include any of the following: information from primary research papers or review articles on toxicity of 1-bromopropane to organs or tissues that were identified as tumor sites from studies in experimental animals.

Mechanisms of Action

1. Does this paper contain information that could be useful in answering the key questions about mechanisms of action?
  - Yes
  - No
2. If the answer to Question #1 is “No” select the reason below for excluding if from review.
  - It does not contain relevant information on the candidate substance (or one of its metabolites or analogues).
  - It is related to the candidate substance (or one of its metabolites or analogues), but the paper does not contain information that will help answer the key questions about mechanisms of action.
  - Other:

Note: In the context of the systematic review of literature used for 1-bromopropane, “useful” or “relevant” information as it applies to screening for the mechanism data section can include information from primary research papers or review articles on data related to molecular alterations associated with carcinogenicity or potential modes of action, such as genotoxicity, epigenetics, gene expression, immune-response modulation, inflammation, cytotoxicity and compensatory cell proliferation, mitogenicity, chronic metabolic or physiologic overload, nutrient deficiency, and interference with intercellular communication, for 1-bromopropane, its metabolites and analogues.

Table A-1 General Sources Checklist for 1-Bromopropane

Source | Name of Document
A) Comprehensive Sources or Reviews
1) NTP technical reports | NTP2011
2) NTP nomination for toxicological evaluation documents | NTP1999
3) OHAT (formerly CERHR) | NTP2003a (1BP) NTP2003b (2BP)
Public comments to CERHR- 10 listed on NTP website | Albemarle2001a Albemarle2001b Atofina2001 BSC2000 BSC2001a BSC2001b Envirotech2001 IRTA2001 EPA2002 Envirotech2002
4) IARC monographs | –
5) ATSDR Toxicological Profiles | –
6) EPA IRIS | –
7) NAS Reports and Publications | NAS2007 (Climate Change) NAS2008 (Review of NIOSH HHE Program)
8) WHO (IPCS) INCHEM-related documents (a-k below) | –
a) CICADS | –
b) EHC | –
c) HSGs | –
d) ICSCs | IPCS2004
e) JECFA | –
f) JMPR | –
g) KemI-Riskline | –
h) PDs | –
i) PIMS | –
j) SIDS | –
k) UKPID | –
9) California EPA Prop 65 hazard identification documents | CAEPA2004​ CAEPA2008
10) Health Canada | HealthCanada2009a HealthCanada2009b​
11) New York State Department of Health- Health Topics A to Z | –
B) General Information Sources
1) U.S. National Library of Medicine (NLM)- TOXNET | –
a) HSDB | HSDB2006
b) CCRIS | CCRIS2008
c) GENETOX | –
d) ITER | –
e) LactMed | –
f) CPD | –
g) CTD | CTD2012
2) PubChem | PubChem2012
3) Kirk-Othmer Encyclopedia | Wypych2006 Pocius&Campbell2009 Suh2000
4) USGS (Minerals) | –
C) European Union–Sources to Search
1) International Uniform Chemical Information Database (IUCLID) | –
2) European Chemicals Agency | –
3) The International Portal on Food Safety, Animal and Plant Health (IPFSAPH) | –
4) The European Food Safety Authority | –
5) European Centre for Disease Prevention and Control (ECDC) | –
6) European Monitoring Centre for Drugs and Drug Addiction | –
7) International Labour Organization (ILO) | ILO2005
8) United Nations Environment Programme (UNEP) | –

Table A-2 Exposure-related Sources Checklist for 1-Bromopropane

Source | Name of Document
Exposure- and Properties-Specific Sources
1) U.S. National Library of Medicine (NLM)–TOXNET | –
a) ChemIDplus | ChemIDplus2012
b) Haz-Map | Haz-Map2012
c) HPD | –
d) TOXMAP | –
2) Akron database | Akron2012
3) SRI Directory of Chemical Producers | SRI2012
4) Chem Sources Suppliers | ChemSources2012
5) National Health and Nutrition Examination Survey (NHANES) data studies | –
6) National Occupational Exposure Survey (NOES) (1981–1983) | –
7) National Institute for Occupational Safety and Health (NIOSH)–Health Hazard Evaluations | 5 HHE: Eisenberg2010 Harney2002 Harney2003 Reh2001 Reh2002
8) National Response Center (NRC) Database | NRC2012a NRC2012b
9) U.S. International Trade Commission (USITC)–Import/Export data | USITC2012
10) EPA Toxics Release Inventory (TRI) | –
11) Environmental Protection Agency (EPA) AP-42, Compilation of Air Pollutant Emission Factors | –
12) EPA EJView Database | –
13) EPA High Production Volume Chemicals (HPV Challenge Program Chemical List) | –
14) EPA Inventory Update Rule (IUR) | EPA2012
15) EPA Locating and Estimating (L&E) documents | –
16) EPA/Office of Pesticide Programs (OPP) Chemical Ingredients Database | –
17) Food and Drug Administration (FDA) Pesticide Monitoring Database | –
18) FDA Orange Book | –
19) FDA Total Diet Study | –
20) Medline Plus | MedlinePlus2012
21) United States Patent Office | USPTO2011 USPTO2012a USPTO2012b
22) Trademark Electronic Search System (TESS) | –
23) Material Safety Data Sheets (MSDS) | Multiple found Sigma-Aldrich2011
24) Dow Chemical Product Safety Assessments | –

Table A-3 Data Sources for 1-Bromopropane Searches

Information Type | Data Sources
Synonyms | National Library of Medicine databases (e.g., ChemIDplus, Hazardous Substances Data Base)
Metabolites | Cheever et al. (2009), Garner et al. (2006), Ghanayem and Hoffler (2007), Ishidao et al. (2002), Jones and Walsh (1979).

Table A-4 Literature Search Approach for 1-Bromopropane

Substance | Search Terms | Topics (Combined with)^a^
1-Bromopropane Synonyms | bromopropane, propyl bromide, and 106-94-5 | None
Chemical Class and Synonyms | bromoalkanes, alkyl bromides, haloalkanes, alkyl halides | Animal tumors Genotoxicity Toxicity Mechanism
1-Bromopropane Brominated Phase I Metabolites and their Synonyms | 3-bromopropanol, 3-bromopropionic acid, 1-bromo-2-propanol, bromoacetone, 2-oxo-1-bromopropane, and alpha-bromohydrin | None
1-Bromopropane Debrominated Phase I Metabolites and their Synonyms | propylene oxide, n-propanol, glycidol, and 3-hydroxypropionate | Animal tumors Genotoxicity Toxicity Mechanism
1-Bromopropane Phase II Metabolites | 1-bromo-2-hydroxypropane-O-glucuronide, N-acetyl-S-propylcysteine, N-acetyl-S-(2-hydroxypropyl)cysteine, N-acetyl-S-(3-hydroxypropyl)cysteine, N-acetyl-S-(2-carboxyethyl)cysteine, N-acetyl-S-(2-oxopropyl)cysteine, 2,3-dihydroxypropylmercapturic acid, N-acetyl-3-(propylsulfinyl)alanine, N-acetyl-3-[(2-hydroxypropyl)sulfinyl]alanine, N-acetyl-3-[(2-oxopropyl)sulfinyl]alanine, N-acetyl-3-[(2-propenol)sulfinyl]alanine | None
Exposure Scenario | (Spray* AND Adhes*) or Degreas* | Human cancer studies

^a^ Search terms for each of these topics were developed in consultation with an informational specialist and are listed in Table A-5.

Table A-5 Search Terms for Monograph Topics for 1-Bromopropane

Monograph Topic | Search Terms Used in PubMed, Scopus, and Web of Science | MeSH Terms Used in PubMed
Human Cancer Studies | Cancer search terms – cancer* OR neoplas* OR carcinogen* OR malignan* OR oncogene* OR tumor* OR tumour* OR adenoma* OR carcinoma* OR adenocarcinoma* OR sarcoma* OR precancer* OR preneoplast* OR lesion* OR cyst* OR lymphoma* OR leukemia* OR metastas* OR cell transform* OR cell proliferat* Combine with AND Epidemiologic study search terms - person* OR people OR individual* OR subject* OR participant* OR worker* OR employee* OR staff OR human OR woman OR women OR man OR men OR epidemiolog* OR case report* OR case control OR cohort OR case-referent OR registry OR prevalen* OR inciden* | Cancer search terms - “neoplasms”[Mesh] OR “carcinogens”[Mesh] Combine with AND Epidemiologic study search terms - “epidemiology”[Subheading] OR “epidemiologic studies”[Mesh] OR “case reports”[publication type] OR “epidemiologic factors”[mh] OR “epidemiologic methods”[mh] OR “persons”[mh] OR “occupational diseases”[mh] OR “occupational exposure”[mh] OR “vital statistics”[mh]
Animal Tumors | Cancer search terms- cancer OR neoplasm* OR carcinogen* OR malignan* OR oncogene* OR tumor* OR tumour* Combine with AND Animal study search terms- animal* OR mouse OR mice OR rat OR hamster OR “guinea pig” OR rabbit OR monkey OR dog | Cancer search terms- “neoplasms”[Mesh]) OR “carcinogens”[Mesh]
Genotoxicity | General search terms - “genetic toxicology” OR genotoxic*^a^ Endpoint-specific search terms - clastogen* OR “DNA strand break*” OR “unscheduled DNA synthesis” OR “UDS” OR aneuploid OR aneuploid* OR polyploid OR polyploid* OR “neoplastic cell transformation” OR “chromosom* aberration*” OR cytogenetic OR cytogenetic* OR “DNA adduct*” OR “DNA damage” OR “DNA repair” OR crosslink* OR “germ-line mutation” OR micronucle* OR mutagen OR mutagen* OR mutation OR mutation* OR oncogen* OR “sister chromatid exchange” OR “SCE” OR “SOS response*” OR “Ames test” OR “gene expression” OR “cell proliferation” OR cytotoxic OR cytotoxic* OR “comet assay” | “DNA Damage”[Mesh] OR “DNA Repair”[Mesh] OR “Mutagens”[Mesh] OR “Mutation”[Mesh] OR “Cytogenetic Analysis”[Mesh] OR “Oncogenes”[Mesh] OR “Mutagenicity Tests”[Mesh]^a^
Toxicity | toxic* OR toxin*OR cytotoxic* OR (nephrotoxic* OR hepatotoxic* OR pneumotoxic* OR thyrotoxic* | “Toxic Actions”[Mesh]) OR “Toxicity Tests”[Mesh]) OR “adverse effects” [Subheading]
Mode of Action | (mode* AND “of action”) OR (mechanism* AND “of action”) OR genetic OR epigenetic OR inhibit* OR promot* OR interact* OR activate* OR detoxific* OR “oxidative damage” OR cytotoxicity

^a^ Only the MeSH terms (or their equivalents (i.e., “genetic toxicology” OR genotoxic* OR “DNA Damage” OR “DNA Repair” OR mutagens OR mutation OR “cytogenetic analysis” OR oncogenes OR “mutagenicity tests”) were used in the searches for debrominated metabolites.