# Publication Details

Publisher: National Institute of Environmental Health Sciences

Publishing Location: Research Triangle Park, NC

ISSN: 2768-5632

DOI: https://doi.org/10.22427/NIEHS-13

Report Series: NIEHS Report Series

Report Series Number: 13

Official citation: Auerbach SS, Cora MC, Liu YF, Luh J, Prince LM, Roberts GK, Shipkowski KA, Waidyanatha S. 2026. NIEHS report on the in vivo repeat dose biological potency studies of 1,4-dichlorobenzene (CASRN 106-46-7) in female Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) rats and B6D2F1/Crl mice (whole-body inhalation studies). Research Triangle Park, NC: National Institute of Environmental Health Sciences. NIEHS Report 13.