# References

1 National Information Standards Organization (NISO). CRediT (Contributor Roles Taxonomy). Baltimore, MD: National Information Standards Organization; 2024. [Accessed: July 26, 2024]. https://credit.niso.org/
2 Agency for Toxic Substances and Disease Registry (ATSDR). Toxicological profile for dichlorobenzenes. Atlanta, GA: U.S. Department of Health and Human Services, Public Health Service, Agency for Toxic Substances and Disease Registry; 2006. [Accessed: April 29, 2025]. https://www.atsdr.cdc.gov/ToxProfiles/tp10.pdf
3 National Center for Biotechnology Information (NCBI). PubChem compound summary for CID 4685, 1,4-dichlorobenzene. Bethesda, MD: U.S. Department of Health and Human Services, National Institutes of Health, National Library of Medicine, National Center for Biotechnology Information; 2025. [Accessed: April 29, 2025]. https://pubchem.ncbi.nlm.nih.gov/compound/1_4-Dichlorobenzene
4 U.S. Environmental Protection Agency (USEPA). Notice of pesticide reregistration: Paradichlorobenzene. Washington, DC: U.S. Environmental Protection Agency, Office of Pesticide Programs; 2014. EPA Reg. No. 81433-1. [Accessed: September 16, 2025]. https://www3.epa.gov/pesticides/chem_search/ppls/081433-00001-20140828.pdf
5 Occupational Safety and Health Administration (OSHA). 29 CFR § 1910.1000: Table Z-1 limits for air contaminants. Washington, DC: U.S. Department of Labor, Occupational Safety and Health Administration; 2025. [Accessed: April 29, 2025]. https://www.osha.gov/laws-regs/regulations/standardnumber/1910/1910.1000TABLEZ1
6 American Conference of Governmental Industrial Hygienists (ACGIH). ACGIH Data Hub: p-Dichlorobenzene. Cincinnati, OH: American Conference of Governmental Industrial Hygienists; 2025. [Accessed: September 16, 2025]. https://www.acgih.org/p-dichlorobenzene/
7 U.S. Environmental Protection Agency (USEPA). National Primary Drinking Water Regulations. Washington, DC: U.S. Environmental Protection Agency; 2024. [Accessed: September 16, 2025]. https://www.epa.gov/ground-water-and-drinking-water/national-primary-drinking-water-regulations
8 Office of Environmental Health Hazard Assessment (OEHHA). Air Toxics Hot Spots Program: 1,4-Dichlorobenzene Reference Exposure Levels: Technical support document for the derivation of noncancer Reference Exposure Levels: Appendix D1. Sacramento, CA: California Environmental Protection Agency, Office of Environmental Health Hazard Assessment, Air and Site Assessment and Climate Indicators Branch; 2025. [Accessed: September 16, 2025]. https://oehha.ca.gov/sites/default/files/media/2025-07/1%2C4-DCB%20REL071825_2.pdf
9 National Toxicology Program (NTP). 1,4-Dichlorobenzene. In: 15th Report on Carcinogens. Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Toxicology Program; 2021. [Accessed: April 29, 2025]. https://ntp.niehs.nih.gov/sites/default/files/ntp/roc/content/profiles/dichlorobenzene.pdf
10 International Agency for Research on Cancer (IARC). Some chemicals that cause tumours of the kidney or urinary bladder in rodents and some other substances. (IARC monographs on the evaluation of carcinogenic risks to humans; vol. 73). Lyon, France: International Agency for Research on Cancer; 1999. [Accessed: April 29, 2025]. https://publications.iarc.who.int/91
11 European Commission (EC). Commission Regulation (EU) No 474/2014 of 8 May 2014 amending Annex XVII to Regulation (EC) No 1907/2006 of the European Parliament and of the Council on the Registration, Evaluation, Authorisation and Restriction of Chemicals ('REACH') as regards 1,4-dichlorobenzene (text with EEA relevance). OJ L 136, p. 19–22. 2014. [Accessed: October 6, 2025]. https://data.europa.eu/eli/reg/2014/474/oj
12 Hissink E, van Ommen B, Bogaards JJ, van Bladeren PJ. Hepatic epoxide concentrations during biotransformation of 1,2- and 1,4-dichlorobenzene: The use of in vitro and in vivo metabolism, kinetics and PB-PK modeling. In: Snyder R, Kocsis JJ, Sipes IG, Kalf GF, Jollow DJ, Greim H, Monks TJ, Witmer CM, editors. Biological Reactive Intermediates V: Basic Mechanistic Research in Toxicology and Human Risk Assessment. New York, NY: Springer; 1996. p. 129-133. 10.1007/978-1-4757-9480-9_18
13 Aiso S, Takeuchi T, Arito H, Nagano K, Yamamoto S, Matsushima T. Carcinogenicity and chronic toxicity in mice and rats exposed by inhalation to para-dichlorobenzene for two years. J Vet Med Sci. 2005; 67(10):1019–1029. 10.1292/jvms.67.1019 16276058
14 BioSpyder. TempO-Seq® assay user guide. Carlsbad, CA: BioSpyder Technologies, Inc.; 2022. Document 100802 rev C. [Accessed: August 25, 2025]. https://www.biospyder.com/s/100802-TempO-Seq-User-Guide-rev-C-r8r7.pdf
15 Langmead B, Trapnell C, Pop M, Salzberg SL. Ultrafast and memory-efficient alignment of short DNA sequences to the human genome. Genome Biol. 2009; 10(3):R25. 10.1186/gb-2009-10-3-r25 19261174
16 Williams DA. A test for differences between treatment means when several dose levels are compared with a zero dose control. Biometrics. 1971; 27(1):103–117. 10.2307/2528930 5547548
17 Williams DA. The comparison of several dose levels with a zero dose control. Biometrics. 1972; 28(2):519–531. 10.2307/2556164 5037867
18 Dunnett CW. A multiple comparison procedure for comparing several treatments with a control. J Am Stat Assoc. 1955; 50(272):1096–1121. 10.1080/01621459.1955.10501294
19 Shirley E. A non-parametric equivalent of Williams’ test for contrasting increasing dose levels of a treatment. Biometrics. 1977; 33(2):386–389. 10.2307/2529789 884197
20 Dunn OJ. Multiple comparisons using rank sums. Technometrics. 1964; 6(3):241–252. 10.1080/00401706.1964.10490181
21 Jonckheere AR. A distribution-free k-sample test against ordered alternatives. Biometrika. 1954; 41(1-2):133–145. 10.1093/biomet/41.1-2.133
22 Dixon WJ, Massey FJ. Introduction to statistical analysis. 2nd ed. New York, NY: McGraw-Hill; 1957.
23 National Toxicology Program (NTP). NTP research report on National Toxicology Program approach to genomic dose-response modeling. Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Toxicology Program; 2018. NTP Research Report No. 5. 10.22427/NTP-RR-5
24 Yang L, Allen BC, Thomas RS. BMDExpress: A software tool for the benchmark dose analyses of genomic data. BMC Genomics. 2007;8:387. 10.1186/1471-2164-8-387 17961223
25 Gwinn WM, Auerbach SS, Parham F, Stout MD, Waidyanatha S, Mutlu E, Collins B, Paules RS, Merrick BA, Ferguson S, et al. Evaluation of 5-day in vivo rat liver and kidney with high-throughput transcriptomics for estimating benchmark doses of apical outcomes. Toxicol Sci. 2020; 176(2):343–354. 10.1093/toxsci/kfaa081 32492150
26 Brennan A, Chang D, Cowden J, Davidson-Fritz S, Dean J, Devito M, Ford J, Everett L, Harrill A, Hester S, et al. Standard methods for development of EPA Transcriptomic Assessment Products (ETAPs). Research Triangle Park, NC: U.S. Environmental Protection Agency, Office of Research and Development, Center for Public Health and Environmental Assessment, Center for Computational Toxicology and Exposure; 2024. EPA Report No. EPA/600/X-23/083. [Accessed: February 10, 2026]. 10.23645/epacomptox.25365496
27 Auerbach SS, Ballin JD, Blake JC, Browning DB, Collins BJ, Cora MC, Fernando RA, Fostel JM, Liu YF, Luh J, et al. NIEHS report on the in vivo repeat dose biological potency study of perfluorohexanesulfonamide (CASRN 41997-13-1) in Sprague Dawley (Hsd:Sprague Dawley® SD®) rats (gavage studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institute of Environmental Health Sciences; 2023. NIEHS Report 10. 10.22427/niehs-10
28 National Toxicology Program (NTP). NIEHS 13: Chemical Effects in Biological Systems (CEBS) data repository. Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Toxicology Program; 2025. 10.22427/NIEHS-DATA-NIEHS-13
29 U.S. Environmental Protection Agency (USEPA). Methods for derivation of inhalation reference concentrations and application of inhalation dosimetry. Research Triangle Park, NC: U.S. Environmental Protection Agency, Office of Research and Development, Office of Health and Environmental Assessment, Environmental Criteria and Assessment Office; 1994. EPA Report No. EPA/600/8-90/066F. [Accessed: October 21, 2025]. https://www.epa.gov/risk/methods-derivation-inhalation-reference-concentrations-and-application-inhalation-dosimetry
30 U.S. Environmental Protection Agency (USEPA). Recommendations for and documentation of biological values for use in risk assessment. Cincinnati, OH: U.S. Environmental Protection Agency, Office of Research and Development, Office of Health and Environmental Assessment, Environmental Criteria and Assessment Office; 1988. EPA Report No. EPA/600/6-87/008. [Accessed: October 6, 2025]. https://assessments.epa.gov/risk/document/&deid%3D34855
31 Liu J, Hara K, Kashimura S, Hamanaka T, Tomojiri S, Tanaka K. Gas chromatographic-mass spectrometric analysis of dichlorobenzene isomers in human blood with headspace solid-phase microextraction. J Chromatogr B Biomed Sci Appl. 1999; 731(2):217–221. 10.1016/S0378-4347(99)00226-1 10510774
32 Watanabe K, Hasegawa K, Yamagishi I, Nozawa H, Takaba M, Suzuki O. Simple isotope dilution headspace-GC-MS analysis of naphthalene and p-dichlorobenzene in whole blood and urine. Anal Sci. 2009; 25(11):1301–1305. 10.2116/analsci.25.1301 19907086
33 Gene Ontology Consortium (GOC). Geneontology: The gene ontology resource. 2025. [Accessed: October 17, 2025]. https://geneontology.org/
34 Medical College of Wisconsin. Rat Genome Database. Milwaukee, WI: Medical College of Wisconsin; 2025. [Accessed: October 17, 2025]. https://rgd.mcw.edu/
35 UniProt Consortium. UniProtKB. 2025. [Accessed: October 17, 2025]. https://www.uniprot.org/uniprotkb/
36 National Center for Biotechnology Information (NCBI). Entrez Gene. Bethesda, MD: U.S. Department of Health and Human Services, National Institutes of Health, National Library of Medicine, National Center for Biotechnology Information; 2025. [Accessed: October 17, 2025]. https://www.ncbi.nlm.nih.gov/gene/